# Discussion

Gum guggul extracts (GGEs) are substances commonly used in traditional Ayurvedic medicine for the treatment of hyperlipidemia, obesity, diabetes, atherosclerosis, and inflammatory conditions such as arthritis.^1,12,87-90^ In the United States, GGEs are marketed as dietary supplements that will help control serum lipid and cholesterol concentrations and stimulate the thyroid gland. GGE was nominated for study by the National Institute of Environmental Health Sciences for toxicological characterization because of its expanding use as a dietary supplement and a lack of available information to adequately assess safe use in humans. In alignment with the National Toxicology Program’s (NTP) Dietary Supplements research program, 28-day and 3-month studies were conducted to evaluate the subchronic toxicity of a GGE formulation.

Gugulipid^®^ 2.5% granules formulation was procured as a representative GGE formulation due to its commercial availability and standardized phytochemical profile, which is labeled to contain 2.5% of the presumed active constituents, Z- and E-guggulsterone. After sieving, the tested GGE formulation contained only 1.46% guggulsterone content and significant levels of excipients (approximately 62.2%), including magnesium carbonate and corn starch, among others. These excipient levels were not controlled for in the vehicle groups and therefore should be a consideration in the toxicological interpretations of these studies.

In the current 28-day and 3-month gavage studies, no treatment-related effects on survival, body weight, or gross or microscopic pathology findings were observed following administration of the tested GGE formulation up to 1,000 mg/kg/day in Hsd:Sprague Dawley^®^ SD^®^ rats and up to 250 mg/kg/day in B6C3F1/N mice.

Increases in globulin concentrations were observed in rats at both day 28 (males and females) and day 92 (females only). Globulins are a heterogeneous population of proteins that include immunoglobulins, transport proteins, and acute phase proteins, among others, and are produced by lymphocytes (immunoglobulins) or the liver. A common cause of increased globulins is inflammation, but no indications of inflammation were observed. An explanation for the increase in globulin concentrations in this study is not known.

A previous study suggested that GGEs increase total triiodothyronine (T_3_) serum concentrations.^46^ Thyroid-stimulatory activity—defined as increased thyroid tissue peroxidase and protease activities, and increased ^131^Iodine uptake by the thyroid gland—was observed in rats following administration of the individual gum guggul phytochemical constituent, Z-guggulsterone, suggesting it might be the active pharmacological agent inducing this effect.^37^ In the current study, serum thyroid stimulating hormone (TSH) concentrations were significantly increased in female rats dosed with 500 or 1,000 mg/kg/day for 28 days. Increased TSH is associated with decreased thyroid function; however, there was no correlative decrease in thyroxine (T_4_) or T_3_ concentrations, and these changes were not observed in the 3-month study. Other statistically significant changes in thyroid hormone concentrations were small and lacked a dose response in male and female rats and were not attributed to administration of the tested GGE formulation. Therefore, purported thyroid-stimulatory effects suggested by other studies were not found in this study.

Due to the reported pharmacological efficacy of GGE consumption for prevention of hypercholesterolemia and cardiovascular disease, additional measures of serum phospholipid, triglyceride, and cholesterol concentrations were assessed in 28-day and 3-month animal studies.^1,6,26^ In the current study, disparate effects on serum lipid concentrations were evident between different test species, sex, and duration of exposure. Small dose-related increases in serum cholesterol and phospholipid concentrations were observed in female mice administered a GGE formulation for 3 months. This observation coincides with a recent study that found consumption of a GGE to cause hypercholesterolemia and increased incidence of atherosclerosis in wildtype C57BL/6 and atherosclerosis-prone transgenic male mice.^91^ In the current studies, decreased serum cholesterol, phospholipid, and bile acid concentrations occurred in 28-day-treated male rats but were not observed following 3 months of treatment. Additionally, bile acid concentrations were significantly decreased in all dosed groups of female rats at day 92. The nuclear farnesoid X receptor (FXR), plays a major role in the formation of bile acids from cholesterol by regulation of bile salt export pump (BSEP) and cholesterol 7 alpha-hydroxylase (cytochrome P450 [CYP] 7A1) through a positive feed-forward and a negative feedback mechanism, respectively.^15^ Findings by Deng et al.^15^ demonstrated that although guggulsterone antagonizes FXR, it also up-regulates BSEP independent of FXR, demonstrating two opposite effects on BSEP. Guggulsterone’s direct up-regulation of BSEP is dominant over its FXR-mediated antagonism, and is a plausible mechanism for the hypolipidemic effect of GGEs.^15,92^ Increases in BSEP result in increased bile acid excretion, which might be reflected in lower serum bile acid concentrations.

In the 3-month studies, GGE formulation exposure via oral gavage exhibited the potential to be a reproductive toxicant in male mice, but not in rats, as evidenced by decreased testicular spermatid head counts and a corresponding decrease in testicular weights with increasing dose. In contrast, testicular spermatid head counts were significantly increased in male rats administered up to 1,000 mg/kg/day, fourfold higher than the highest dose administered to mice. No corresponding decreases in sperm motility or cauda epididymal sperm counts were noted in male mice. Additionally, no microscopic findings were noted in the male reproductive tract of mice or rats. Guggulsterone has been shown to bind to the androgen receptor, among other steroid binding receptors, and affects receptor activation in in vitro model systems.^93,94^ Further studies that examine functional effects on fertility are needed to definitively evaluate the potential reproductive toxicity of GGEs.

In the current studies, dose-related increases in hepatic CYP2B and CYP3A activity, indicative of constitutive androstane receptor (CAR) and pregnane X receptor (PXR) activation, occurred in treated male and female rats and mice at both 28-day and 3-month time points. Length of exposure was considered a determinant for the magnitude of GGE-associated increases in CYP2B activity observed in 1,000 mg/kg/day male and female rats. However, low basal CYP3A activity and a lower overall magnitude of induction were evident in dosed female rats (3-month study). The tested GGE formulation increased liver weights in male and female rats (28-day and 3-month studies); however, no histologic lesions of the liver were observed. Apparent liver weight increases likely represent an adaptive response due to increased expression of xenobiotic metabolism enzymes. Liver weight effects were more pronounced in rats, which could be attributed to the rats’ receiving a higher dose on a mg/kg/day basis. Neither sex nor length of exposure was considered a determinant for the magnitude of GGE-associated increases in CYP2B or CYP3A activity in mice.

In vitro incubations of human hepatic microsomes with the procured GGE formulation normalized to 10 μM guggulsterones resulted in significant inhibition of CYP2C9, CYP3A4-mediated testosterone 6β-hydroxylase, and CYP2C19 metabolic activity. However, treatments of Z- or E-guggulsterone constituents in isolation did not demonstrate a similar level of CYP inhibition, suggesting that other formulation constituents likely contribute to observed activities. Both the tested GGE formulation and individual guggulsterone isomers increased human Pgp ATPase activity, suggesting that guggulsterone constituents may be substrates for the human Pgp transporter. GGE formulation treatment also significantly attenuated taurocholate uptake in hNTCP assays, suggesting effects on bile acid uptake/excretion pathways. These results indicate that GGE constituents can influence the activity of multiple endogenous enzymes and transporters and suggest a potential for botanical-drug interactions that could alter bioavailability, efficacy, or toxicity of prescription drugs when taken concomitantly with products containing GGE. Prescription drugs targeted by these enzymes/transporters include the anticoagulant warfarin, nonsteroidal anti-inflammatory drugs, cholesterol-lowering statins, and rosuvastatin.^95,96^ Recent studies report increasing use of botanical supplements in combination with prescribed and over-the-counter medication among U.S. adults aged 57–85 years.^97^ Combinatorial use of dietary supplements with marketed pharmaceuticals can lead to pharmacokinetic interactions, which can have dire influences on the efficacy of a drug or result in significant toxicity. Given the purported clinical indications for GGEs to reduce serum total cholesterol, low-density lipoprotein, and triglycerides, and to increase high-density lipoprotein concentrations, it is plausible that individuals may consume GGE-containing products in combination with clinically prescribed or over-the-counter medications. CYP enzymes are involved in the metabolism of roughly 75% of marketed drugs.^98^ Induction of CYP2 and CYP3 family enzymes by PXR and CAR constitute two major xenobiotic metabolism pathways involved in drug bioactivation or removal. Therefore, observed alterations in drug metabolism and excretion pathways following the administration of the GGE formulation support increased potential for altered pharmacokinetic/pharmacodynamic parameters of pharmaceuticals subject to metabolism by these enzymatic pathways. This explanation is supported by the observation that the beta blocker propranolol and the antihypertensive drug diltiazem show decreased bioavailability when taken concurrently with gum guggul.^43^

The tested GGE formulation did not induce bone marrow toxicity or alter erythropoiesis as evidenced by no increases in the frequency of micronucleated reticulocytes or erythrocytes in peripheral blood of male or female rats or mice after 3 months of exposure.

In the 3-month studies, the most sensitive measures of GGE formulation administration in each species and sex were increased hepatic CYP2B activity in male rats (lowest-observed-effect level [LOEL] = 125 mg/kg/day), decreased serum bile acid concentrations in female rats (LOEL = 62.5 mg/kg/day), decreased testicular spermatid head counts in male mice (LOEL = 62.5 mg/kg/day), and increased serum cholesterol concentrations in female mice (LOEL = 62.5 mg/kg/day).

The recommended daily intake of GGE formulations is highly variable among different manufacturers. The Indian Pharmacopeia bases its recommended daily intake levels of GGEs on the concentration of guggulsterones, such that consumption equates to 75 mg guggulsterones (25 mg, three times a day).^28^ Assuming a daily intake of 75 mg of guggulsterones and an adult weight of 60 kg, average human daily consumption would equate to 1.25 mg guggulsterones/kg/day or 85.6 mg GGE formulation/kg/day based on the 1.46% guggulsterone content of the tested formulation. Interspecies differences in guggulsterone isomer metabolism have not been reported. In a previously conducted clinical trial, individuals were treated with a guggulipid formulation at doses of up to 150 mg guggulsterones/day for 8 weeks, with adverse reports limited to low incidences of diarrhea and the development of a hypersensitivity skin rash.^36^