# Materials and Methods

## Procurement and Characterization

### Gum Guggul Extract Formulation

Gugulipid^®^, a marketed gum guggul extract (GGE) formulation, was obtained from Sabinsa Corporation (Piscataway, NJ) in two lots (G51177/H and G60493/H). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO) and by the study laboratory at Battelle (Columbus, OH) (Appendix C). Reports on analyses performed in support of these GGE formulation studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Gugulipid^®^ is a cream-to-pale yellow granular powder. Analysis of lots G51177/H and G60493/H by high-performance liquid chromatography (HPLC) with ultraviolet detection (UV) showed the levels of Z- and E-guggulsterone, respectively, to be 0.85% and 1.30% in lot G60493/H and 1.14% and 1.31% in lot G51177/H. These were similar to the manufacturer-reported guggulsterone values of 2.53% (lot G60493/H) and 2.7% (lot G51177/H). The lots were combined by Battelle (Columbus, OH) to create lot 04172009 and were subjected to gravity sieve using an 80-mesh sieve. The material that passed through was assigned lot 07172009. Sieving was done to remove large clumps/particles to enhance the homogeneity of the material and subsequently to aid in the gavagability of the dose formulations.

Lots 04172009 and 07172009 were analyzed by the study laboratory using infrared (IR) spectroscopy, nuclear magnetic resonance (NMR) spectroscopy, weight loss by drying, water content by Karl Fischer analysis, scanning electron microscopy (SEM) with energy dispersive X-ray spectroscopy (EDS), magnesium content by inductively coupled plasma-atomic emission mass spectrometry, X-ray diffraction (XRD), and mass spectrometry. The purity determination and quantitation of Z- and E-guggulsterone content were conducted by HPLC/UV detection. An aliquot of lots 04172009 and 07172009 was submitted to Covance Laboratories, Inc. (Madison, WI) for nutritional and contaminant analyses.

Both IR and NMR spectra were complex, and signatures of gum guggul-specific constituents could not be confirmed (data not shown). XRD analysis showed the presence of magnesium oxide, hydrated magnesium carbonate, and talc as excipients. HPLC/UV analysis detected 79 peaks with areas greater than or equal to 0.05% for both lots. The levels of Z- and E-guggulsterone, respectively, were 0.87% and 1.22% in lot 04172009 and 0.65% and 0.82% in lot 07172009. Mass spectrometric analyses (lot 04172009 only) confirmed the presence of Z- and E-guggulsterone, isomers of Z-guggulsterol, 20-β-hydroxy-4-pregnen-3-one, 20-α-hydroxy-4-pregnen-3-one, guggulsterol VI, and guggulsterol V. Contaminant analyses showed the presence of low levels of lead, antimony, molybdenum. Arsenic, aflatoxins (B1, B2, G1, G2), ochratoxin, and zearalenone could not be determined due to matrix interferences. Pesticide levels were below the limits of quantitation of 0.01 or 0.02 ppm. Detectable contaminant levels were below the threshold limits accepted for drug products and dietary supplements by the International Council for Harmonisation of Technical Requirements for Pharmaceuticals for Human Use and the American Herbal Products Association.^59,60^ Summary results of these analyses are shown in Table 1.

Table 1 Summary of Results of Test Article Characterization

Percent (Weight/Weight) | Lot 04172009^a^ (Combined Lot) | Lot 07172009^b^ (Sieved Lot)
Carbon^c^ | 30.9 | 26.9
Oxygen^c^ | 48.4 | 48.6
Magnesium^c,d^ | 18.3, 18.1 | 20.7
Silicon^c^ | 2.3 | 3.8
Water^e^ | 3.2 | ND^f^
Weight Loss by Drying^g^ | 2.1 | ND
Constituents Identified^h^ | E-guggulsterone Z-guggulsterone Isomers of Z-guggulsterol 20-β-hydroxy-4-pregnen-3-one 20-α-hydroxy-4-pregnen-3-one Guggulsterol VI Guggulsterol V | ND
E-Guggulsterone^i^ | 1.22 | 0.82
Z-Guggulsterone^i^ | 0.87 | 0.65
Excipients^j^ | 78.7 | 62.2
Contaminant Analysis (ppm)^k^
Lead | 0.44 | 0.41
Antimony | 0.057 | 0.058
Molybdenum | 0.18 | 0.18

^a^ Lot was prepared by combining lots G51177/H and G60493/H from Sabinsa Corporation (Piscataway, NJ).

^b^ Lot was prepared by sieving lot 04172009 through an 80-mesh sieve.

^c^ Estimated by energy dispersive X-ray spectroscopy (EDS).

^d^ Estimated by inductively coupled plasma-atomic emission spectroscopy.

^e^ Estimated by Karl Fischer analysis.

^f^ Not determined.

^g^ Based on drying at 50°C.

^h^ Mass spectrometry analysis by positive atmospheric pressure chemical ionization.

^i^ Estimated by high-performance liquid chromatography–ultraviolet detection.

^j^ Estimated based on combined EDS and X-ray powder diffraction data; includes magnesium oxide (14.2–17.0%), hydrated magnesium carbonate (20.5–26.4%), and talc (18.8–21.7%).

^k^ Arsenic, aflatoxins (B1, B2, G1, G2), ochratoxin, and zearalenone could not be determined due to matrix interferences. Pesticide levels were below the limits of quantitation, which is typically 0.01 or 0.02 ppm.

Individual aliquots of lot 07172009 were removed for use as frozen reference standards and archive samples. The remaining material of lot 07172009 was stored in large, amber plastic bags at room temperature.

### Corn Oil

Corn oil was obtained from Sigma-Aldrich (St. Louis, MO) in a single lot (128K0040), and used as the vehicle in the 3-month studies. Twice during the study period, potentiometric titration was used to determine the peroxide content, which was below the rejection level of 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

Dose formulations were prepared three times over the course of the study using the selected GGE formulation (lot 07172009) and corn oil (Table C-2). Formulations were prepared at concentrations of 12.5, 25, 50, 100, and 200 mg/mL (rats) and 1.55, 3.1, 6.25, 12.5, and 25 mg/mL (mice). Formulations were analyzed by quantitating combined Z- and E-guggulsterone isomers using a validated HPLC/UV method. All pre- and postadministration samples were within 10% of the target concentrations and had relative standard deviations (RSDs) within 5% (Table C-3).

Homogeneity studies of the 1.55, 12.5, 25, and 200 mg/mL formulations were also performed using HPLC/UV. RSDs were within 5% of target for each concentration, and thus homogeneity was deemed sufficient. As the formulas were suspensions, continuous stirring was required to ensure homogeneity. Gavagability was confirmed using 25 and 200 mg/mL GGE formulations (lot 04172009) in corn oil.

Formulations were stored in sealed glass containers at concentrations of 1.55 mg/mL or higher at room temperature for up to 42 days. Stability of Z- and E-guggulsterone isomers was confirmed for these conditions up to 42 days.

## Animal Source

Male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Harlan Laboratories, Inc. (now Envigo; Indianapolis, IN). B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained at Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use were in accordance with Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Dose Selection Rationale

Initial dose selection for studies was confounded by the limited availability of toxicity studies in the literature and the inherent chemical variability among previously tested GGEs relative to the tested formulation. Dose concentrations selected for this study were limited to GGE formulation preparations that demonstrated adequate syringability and gavagability. For rat studies, concentrations of up to 200 mg/mL to be administered at 5 mL/kg were passable through an 18-gauge gavage needle. Therefore, rats received the selected GGE formulation (lot 07172009) in corn oil vehicle via gavage at 0, 62.5, 125, 250, 500, and 1,000 mg/kg/day, corresponding to 0, 0.91,1.8, 3.7, 7.4, and 14.7 mg guggulsterones/kg/day, respectively. Lower relative doses were selected for the mouse studies due to syringability issues related to the use of a smaller gauge gavage needle. For the mouse studies, concentrations of up to 25 mg/mL to be administered at 10 mL/kg were passable through a 20-gauge gavage needle. Mice received the selected GGE formulation (lot 07172009) in corn oil vehicle via gavage at 0, 15.5, 31.0, 62.5, 125, and 250 mg/kg/day, corresponding to 0, 0.23, 0.46, 0.92, 1.8, and 3.7 mg guggulsterones/kg/day, respectively. Maximum administered doses were lower than the previously reported LD_50_ of orally administered guggul essential oil at 1,700 mg/kg in mice.^45^ Moreover, the test formulation contained a limited fraction of gum guggul ethyl acetate extract (approximately 1.47% guggulsterone content), suggesting limited concern of potential lethality at the selected doses.

## Three-month and Twenty-eight-day Interim Studies

Rats and mice were approximately 4 to 5 weeks old on receipt. Animals were quarantined for 10 (rats) or 14 (mice) days, and both rats and mice were approximately 6 to 8 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Additionally, the health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix E). All test results were negative (Table E-1).

Groups of 10 male and 10 female core study rats and 15 male and 15 female core study mice were administered 0, 62.5, 125, 250, 500, or 1,000 mg GGE formulation/kg body weight/day (rats) and 0, 15.5, 31, 62.5, 125, or 250 mg GGE formulation/kg body weight/day (mice) in corn oil by gavage 5 days per week for 3 months. Vehicle control animals were administered the corn oil vehicle alone; dosing volumes were 5 mL/kg for rats and 10 mL/kg for mice. Additional groups of 10 male and 10 female interim study rats or mice were administered the same doses by gavage for 28 days. Feed and water were available ad libitum. Rats and mice were housed individually (male mice) or up to five per cage (male and female rats, female mice). Rats and mice were observed twice daily for signs of mortality or moribundity. Clinical findings and body weights were recorded initially, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 2.

Table 2 Experimental Design and Material and Methods in the Three-month and 28-day Interim Gavage Studies of a Gum Guggul Extract Formulation

Three-month and 28-day Interim Studies
Study Laboratory Battelle (Columbus, OH)
Strain and Species Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats B6C3F1/N mice
Animal Source Rats: Harlan Laboratories, Inc. (now Envigo, Indianapolis, IN) Mice: Taconic Biosciences, Inc. (Germantown, NY)
Time Held before Studies Rats: 10 days Mice: 14 days
Average Age When Studies Began 6 to 8 weeks
Date of First Dose Rats: July 23 (males) or 24 (females), 2009 Mice: July 30 (females) or 31 (males), 2009
Duration of Dosing 5 days a week for 4 (interim study) or 14 (core study) weeks
Date of Last Dose Rats: October 21 (males) or 22 (females), 2009 Mice: October 28 (females) or 29 (males), 2009
Necropsy Dates Interim study (day 28): Rats: August 19 (males) or 20 (females), 2009 Mice: August 26 (females) or 27 (males), 2009 Core study (day 92): Rats: October 22 (males) or 23 (females), 2009 Mice: October 29 (females) or 30 (males), 2009
Average Age at Necropsy Interim study (day 28): 10 to 12 weeks Core study (day 92): 19 to 21 weeks
Size of Study Groups Rats: 10 males and 10 females (interim study and core study) Mice: 10 males and 10 females (interim study), 15 males and 15 females (core study)
Method of Distribution Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage Rats: Up to 5 Mice: 1 (male), 5 (females)
Method of Animal Identification Tail tattoo
Diet Irradiated NTP-2000 open formula wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly
Water Tap water (City of Columbus, OH municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum
Cages Polycarbonate (Lab Products, Inc., Seaford, DE), changed at least twice (rats, female mice) or once (male mice) weekly
Bedding Heat-treated, irradiated hardwood Sani-Chips^®^ (P.J. Murphy Forest Products Corp., Montville, NJ), changed at least twice (rats, female mice) or once (male mice) weekly
Rack Filters Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed every 2 weeks
Racks Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks
Animal Room Environment Temperature: 70°F–76°F (rats), 69°F–74°F (mice) Relative humidity: 39%–58% (rats), 38%–89% (mice) Room fluorescent light:12 hours/day Room air changes: at least 10/hour
Doses Rats: 0 (vehicle control), 62.5, 125, 250, 500, 1,000 mg/kg/day Mice: 0 (vehicle control), 15.5, 31, 62.5, 125, 250 mg/kg/day
Type and Frequency of Observation Observed twice daily; animals were weighed, and clinical observations were recorded initially, weekly thereafter, and at the end of the studies.
Method of Euthanasia 100% carbon dioxide
Necropsy Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology Blood was collected from the retroorbital plexus and the retroorbital sinus, respectively, of the interim study rats and mice on day 28 and from the core study rats and mice at the end of the study for clinical chemistry, thyroid hormones, and hematology in rats and clinical chemistry in mice. Hematology: hematocrit, hemoglobin, erythrocyte, reticulocyte, platelet counts, mean cell volume, mean cell hemoglobin, mean cell hemoglobin concentration, and leukocyte count and differentials Clinical chemistry (rats): urea nitrogen, creatinine, glucose, total protein, albumin, globulin, A:G ratio, cholesterol, triglycerides, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, bile acids, and phospholipids Clinical chemistry (mice): glucose, cholesterol, triglycerides, and phospholipids Thyroid hormones: total and free thyroxine, thyroid stimulating hormone, and total triiodothyronine
Histopathology Complete histopathology was performed on rats in the vehicle control and 1,000 mg/kg/day groups and mice in the vehicle control and 250 mg/kg/day groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, bone (femur) with marrow, brain, carcass, clitoral glands, epididymides, esophagus, eyes, gallbladder (mice), heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver, lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland and adjacent (inguinal) skin, nasal cavity with turbinates, ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, spinal cord, spleen, stomach (forestomach and glandular), testes, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology At the end of the studies, sperm samples were collected from male rats in the vehicle control, 250, 500, and 1,000 mg/kg/day groups and male mice in the vehicle control, 62.5, 125, and 250 mg/kg/day groups for sperm motility evaluations. The following parameters were evaluated: spermatid heads per testis and per gram testis, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 16 consecutive days prior to the end of the studies from female rats in the vehicle control, 250, 500, and 1,000 mg/kg/day groups and female mice in the vehicle control, 62.5, 125, and 250 mg/kg/day groups for vaginal cytology evaluations.
Cytochrome P450 Studies At the day 28 interim and at study termination, a section of the left lateral lobe of the liver was collected for CYP evaluation. Microsomal suspensions were prepared and analyzed for the microsomal mixed-function oxidase activity of CYP2B and CYP3A.

Blood was collected from the retroorbital plexus (rats) or sinus (mice) of interim study animals on day 28 (interim study) and of core study animals at the end of the 3-month studies for hematology, clinical chemistry (rats only), and thyroid hormone (rats only) analyses. Animals were anesthetized with a carbon dioxide/oxygen mixture and bled in a random order. Blood was collected into tubes containing ethylenediaminetetraacetic acid (EDTA) for hematology or into serum separator tubes for clinical chemistry. Hematology parameters were analyzed using the Advia 120 (Bayer Diagnostics Division, Tarrytown, NY). Clinical chemistry parameters, including total thyroxine (T_4_), were analyzed using the Roche cobas c501 Chemistry Analyzer (Roche, Indianapolis, IN). Levels of serum thyroid stimulating hormone (TSH), total triiodothyronine (T_3_), and free T_4_ were determined by radioimmunoassay on a Packard cobra II gamma counter (Perkin Elmer, Waltham, MA). The parameters measured are listed in Table 2.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats in the 0, 250, 500, and 1,000 mg/kg/day groups and mice in the 0, 62.5, 125, and 250 mg/kg/day groups. The parameters evaluated are listed in Table 2. For 16 consecutive days prior to scheduled study termination, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were collected and subsequently stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Due to low cellularity, estrous cyclicity could not be determined for female rats and mice. Estrous cyclicity was evaluated in female mice; however, missing values in the data set precluded conclusive interpretations regarding effects of the administered the GGE formulation. Measured parameters of cycle length, number of cycles, and time spent in any specific stage of the estrous cycle of female mice can be found in (Appendix A). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was determined microscopically with the aid of a hemocytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemocytometer.

At the 28-day interim and at study termination, a section of the left lateral lobe of the liver was collected from 10 rats/sex/dose group and 5 mice/sex/dose group, minced, frozen in liquid nitrogen, and stored frozen at −80°C to −60°C. Microsomal suspensions were prepared and the liver tissue was analyzed for the microsomal mixed-function oxidase activity of CYP3A and CYP2B.

Necropsies were performed on all core study animals, with the exception of the five mice/sex/dose group used for CYP evaluations. Organ weights were determined for the heart, right kidney, liver, lung, spleen, right testis, and thymus from 5 (interim study) or 10 (core study) mice/sex/dose group and all rats. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, which were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides, which were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on all vehicle control and 1,000 mg/kg/day rats and all vehicle control group and 250 mg/kg/day mice. Table 2 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to an NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer-review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^61^ and Boorman et al.^62^

## Statistical Methods

### Calculation and Analysis of Nonneoplastic Lesion Incidences

The incidences of nonneoplastic lesions are presented as numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^63^ a procedure based on the overall proportion of affected animals, was used to determine significance between exposed and vehicle control animals, and the Cochran-Armitage trend test was used to test for significant trends.^64^

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^65^ and Williams.^66,67^ Hematology, hormone data, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^68^ (as modified by Williams^69^) and Dunn.^70^ Jonckheere’s test^71^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (the Williams or Shirley tests) was more appropriate for pairwise comparisons than would be a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^72^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

For the human in vitro activity assays, the data were assumed to have a skewed distribution and were analyzed using Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests, as described above. For the pairwise comparisons of positive control to negative control for these data, Wilcoxon^73^ rank-sum tests were used.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with FDA Good Laboratory Practice Regulations.^74^ In addition, as records from the 3-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicity

### In Vivo Erythrocyte Micronucleus Assay

Peripheral blood samples collected in EDTA tubes from male and female B6C3F1/N mice and Sprague Dawley rats after 3 months of gavage exposure were shipped on ice packs by overnight courier to the analytical laboratory and processed for flow cytometric evaluation of micronucleated reticulocytes (RET; polychromatic erythrocytes, PCE) and mature erythrocytes (normochromatic erythrocytes; NCE) as described previously.^75^ Briefly, on arrival at the laboratory, cells were fixed in ultracold methanol and labeled using a MicroFlow^PLUS^ Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. For each blood sample, 20,000 immature reticulocytes (as determined by the presence of an active CD71 transferrin receptor on the cell surface) and approximately 10^6^ mature erythrocytes (CD71) were analyzed using a flow cytometer to determine the frequency of micronucleated cells of each type^76^; in addition, the percentage of reticulocytes among total erythrocytes was calculated as a measure of bone marrow toxicity.

### Data Analysis

Prior experience with the large number of cells scored using flow cytometric scoring techniques^76,77^ suggests it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. NTP uses Levene’s test at α = 0.05 to test for equal variances among the treatment groups. In the case of equal variances, linear regression was used to test for a dose-related trend, and the Williams test^66,67^ was used to test for pairwise differences between each treatment group and the vehicle control group. In the case of unequal variances, Jonckheere’s test^71^ was used to test for a linear trend and pairwise differences with the vehicle control group were tested using Dunn’s test.^70^ Trend tests and pairwise comparisons with the vehicle controls are considered statistically significant for PCEs and NCEs when the one-sided p value is less than 0.025, and for percent PCEs when the two-sided p value is less than 0.05. Bonferroni’s method was used to adjust for multiple comparisons.

## Human In Vitro Activity Assays

The effects of a GGE formulation (lot G51177/H), Z-guggulsterone, and E-guggulsterone on CYP enzyme activity, P-glycoprotein (Pgp), and human Na^+^ taurocholate cotransporting polypeptide (hNTCP) activity were evaluated using human in vitro activity assays. Z- and E-guggulsterones were acquired from ChromaDex (Santa Ana, CA). The guggulsterone content of the GGE formulation was determined using a previously established HPLC method.^8^ Guggulsterones were detected and quantified via measurement of UV absorbance at 248 nm.

### Cytochrome P450 Activity Assays

Human liver microsomes were acquired from CellzDirect (Pittsboro, NC). Microsomes were incubated with the GGE formulation, Z-guggulsterone, or E-guggulsterone, all normalized to 0.3, 1.0, or 10 μM guggulsterones. Following incubation, specific assay reaction mixtures were added for determination of CYP enzyme activity; details are provided in Table 3.

Table 3 Summary of Cytochrome P450 Activity Assays

CYP | Enzymatic Marker | Assay Reaction Mixture
CYP1A2^a^ | Phenacetin O-deethylase activity | Potassium phosphate buffer (0.1 M), NADPH (1 mM), microsomal protein (0.8 mg), phenacetin (50 μM)
CYP2A6^b^ | Coumarin-7-hydroxylation | Potassium phosphate buffer (100 mM), EDTA (1 mM), NADPH (10 mM), microsomal protein (0.01 mg), coumarin (5 μM)
CYP2C8^c^ | Paclitaxel 6α-hydroxylation | Potassium phosphate buffer (100 mM), MgCl_2_ (3.3 mM), NADPH (1 mM), microsomal protein (0.2 mg), paclitaxel (20 μM)
CYP2C9^d^ | Tolbutamide hydroxylation | Phosphate buffer (0.1 M), NADPH (1 mM), microsomal protein (0.2 mg), tolbutamide (240 μM)
CYP2C19^b^ | Mephenytoin-4-hydroxylation | Potassium phosphate buffer (100 mM), EDTA (1 mM), NADPH (1 mM), microsomal protein (0.08 mg), (S)-mephenytoin (0.1 mM)
CYP2E1^e^ | p-Nitrophenol hydroxylation | Ascorbate (1 mM), NADPH (1 mM), microsomal protein (1 mg), p-nitrophenol (0.1 M)
CYP2D6^f^ | Dextromethorphan O-demethylation | Phosphate buffer (0.1 M), NADPH (1 mM), microsomal protein (0.02 mg), dextromethorphan hydrobromide (20 μM)
CYP4A11^g^ | Lauric acid ω-hydroxylation | Tris buffer (50 mM), NADPH (0.44 mM), microsomal protein (0.6 mg), [^14^C]lauric acid (0.1 μCi, 20 mM)
CYP3A4^h^ | Midazolam 1-hydroxylation | Phosphate buffer (50 mM), NADPH (1 mM), microsomal protein (0.06 mg), midazolam (6 μM)
CYP3A4^h^ | Testosterone 6β-hydroxylase activity | Potassium phosphate buffer (50 μmol), sucrose (25 μmol), MgCl_2_ (1.5 μmol), NADPH (0.5 μmol), microsomal protein (0.05 mg), testosterone (125 nmol)

NADPH = reduced nicotinamide adenine dinucleotide phosphate.

^a^ Activity measured as described by BD Biosciences (Woburn, MA).

^b^ Activity measured using the methods of Hickman et al.^78^

^c^ Activity measured using a modified method of Harris et al.^79^

^d^ Activity measured using the methods of Miners et al.^80^

^e^ Activity measured using the methods of Koop.^81^

^f^ Activity measured using the methods of Hickman et al.^78^ with a modification of the HPLC analysis method of Laurenzana et al.^82^

^g^ Activity measured using the methods of Clarke et al.^83^

^h^ Activity measured using the methods of Patki et al.^84^ (midazolam) or Wood et al.^85^ (testosterone).

### P-glycoprotein ATPase Assay

Human Pgp, expressed in a baculovirus expression system, was obtained from BD Biosciences (Woburn, MA) for evaluating ATPase activity. Pgp membranes were incubated with 0, 0.3, 1, or 10 μM of the GGE formulation, Z-guggulsterone, or E-guggulsterone, all normalized to 0.3, 1, or 10 μM guggulsterones; verapamil was used as a positive control. Additional control mixtures were prepared containing sodium orthovanadate, an inhibitor of Pgp, to determine non-Pgp mediated ATPase activity. Reactions were initiated via addition of MgATP and the liberation of inorganic phosphate was quantified by measuring absorbance at 630 nm.

### Na^+^-Taurocholate Cotransporting Polypeptide Activity Assay

Xenopus laevis oocytes expressing hNTCP were obtained from BD Biosciences (Woburn, MA) and used to evaluate the effects of a GGE formulation on human NTCP-mediated transporter activity. Oocytes were incubated with sodium uptake buffer, [^3^H]taurocholic acid, and the GGE formulation normalized to 0, 0.3, 1, or 10 μM guggulsterones. Radioactivity in oocytes was determined by liquid scintillation spectroscopy.