# Appendix F Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-99.

## F.1 Twenty-eight-day Interim Study in Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

PA49 – Cytochrome Activity Summary

R07 – Hormone Summary

## F.2 Twenty-eight-day Interim Study in Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA49 – Cytochrome Activity Summary

## F.3 Three-month Study in Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

PA49 – Cytochrome Activity Summary

R06 – Andrology Summary

R07 – Hormone Summary

## F.4 Three-month Study in Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA49 – Cytochrome Activity Summary

R06 – Andrology Summary

## F.5 Four-week Immunotoxicity Study

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## F.6 In Vitro Assays (Human)

### F.6.1 Gum Guggul Extract

PA49 – Cytochrome Activity

### F.6.2 E-guggulsterone

PA49 – Cytochrome Activity

### F.6.3 Z-guggulsterone

PA49 – Cytochrome Activity

## F.7 Genetic Toxicology

### F.7.1 Study G05066

G04 – In Vivo Micronucleus Summary Data

### F.7.2 Study G05066B

G04 – In Vivo Micronucleus Summary Data