# Appendix E Sentinel Animal Program

## E.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that could affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of chemical compounds. Under this program, the disease state of the rodents is monitored via serology on sera from extra (sentinel) animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected and allowed to clot, and the serum was separated. All samples were processed appropriately with serology performed by the Rodent Animal Diagnostic Laboratory, University of Missouri, (currently IDEXX BioResearch), Columbia, MO for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five rats and five mice per sex at 4 weeks after the start of dosing and at the end of the study (Table E-1).

Table E-1 Methods and Results for Sentinel Animal Testing in Three-month Study

Method and Test | Time of Collection
Rats
Multiplex Fluorescent Immunoassay
Kilham’s rat virus | 4 weeks, study termination
Mycoplasma pulmonis | 4 weeks, study termination
Parvo NS-1 | 4 weeks, study termination
Pneumonia virus of mice (PVM) | 4 weeks, study termination
Rat coronavirus/sialodacryoadenitis virus | 4 weeks, study termination
Rat minute virus | 4 weeks, study termination
Rat parvovirus | 4 weeks, study termination
Rat theilovirus | 4 weeks, study termination
Sendai | 4 weeks, study termination
Theiler’s murine encephalomyelitis virus strain GDVII (TMEV GDVII) | 4 weeks, study termination
Toolan’s H-1 | 4 weeks, study termination
Mice
Multiplex Fluorescent Immunoassay
Ectromelia virus | 4 weeks, study termination
Epizootic diarrhea of infant mice | 4 weeks, study termination
Lymphocytic choriomeningitis virus | 4 weeks, study termination
Minute virus of mice | 4 weeks, study termination
Mouse hepatitis virus | 4 weeks, study termination
Mouse norovirus | 4 weeks, study termination
Mouse parvovirus | 4 weeks, study termination
Mycoplasma pulmonis | 4 weeks, study termination
Parvo NS-1 | 4 weeks, study termination
PVM | 4 weeks, study termination
Reovirus | 4 weeks, study termination
Sendai | 4 weeks, study termination
TMEV GDVII | 4 weeks, study termination

## E.2 Results

All test results were negative.