# Appendix C Chemical Characterization and Dose Formulation Studies

## C.1 Procurement and Characterization

### C.1.1 Gum Guggul Extract Formulation

Gugulipid^®^ (gum guggul extract; GGE) was obtained from Sabinsa Corporation (Piscataway, NJ) in two lots (G51177/H and G60493/H). Preliminary characterization confirmed the two lots were similar. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO) and by the study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of these GGE studies are on file at the National Institute of Environmental Health Sciences.

Gugulipid^®^ is a cream-to-pale yellow granular powder. Analysis of lots G51177/H and G60493/H by high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection showed the levels of Z- and E-guggulsterone, respectively, to be 0.85% and 1.30% in lot G60493/H and 1.14% and 1.31% in lot G51177/H. These were similar to the manufacturer-reported guggulsterone values of 2.53% (lot G60493/H) and 2.7% (G51177/H).

The two lots were combined by Battelle (Columbus, OH) to create lot 04172009. To combine and homogenize the lots, one-third each of lots G51177/H and G60493/H was transferred, in alternating layers, to a 1-ft^3^ twin shell blender and blended for 15 minutes. The homogenized lot was repackaged into amber glass bottles and assigned lot 04172009

Lot 04172009 was subjected to gravity sieve in bulk using an 80-mesh sieve (Note: this was needed to ensure that the corn oil formulations could pass through the gavage needle). The material that passed through was assigned lot 07172009. The lot was transferred to a large plastic bag and mixed by kneading and rotating for approximately 15 minutes. Samples were removed from the top (left, middle, and right) and bottom (left, middle, and right) of the bag for homogeneity determination. Homogeneity of lot 07172009 was confirmed with respect to Z- and E-guggulsterone using HPLC/UV.

Lots 04172009 and 07172009 were analyzed by the study laboratory using infrared (IR) spectroscopy, nuclear magnetic resonance (NMR) spectroscopy, weight loss by drying, water content by Karl Fischer analysis, scanning electron microscopy (SEM) with energy dispersive X-ray spectroscopy (EDS), magnesium content by inductively coupled plasma-atomic emission mass spectrometry, X-ray diffraction (XRD), and mass spectrometry (MS). The purity determination and quantitation of Z- and E-guggulsterone content were conducted by HPLC-UV detection (system A). Additional details on the chromatography systems used are presented in Table C-1. One aliquot of lots 04172009 and 07172009 was submitted to Covance Laboratories, Inc. (Madison, WI) for nutritional and contaminant analyses.

IR spectra showed the presence of the excipients magnesium carbonate and corn starch. Both IR and NMR spectra were complex, and signatures of gum guggul-specific constituents could not be confirmed (data not shown). XRD analysis showed the presence of magnesium oxide, hydrated magnesium carbonate, and talc as excipients. HPLC/UV analysis by system A detected 79 peaks with areas greater than or equal to 0.05% for both lots. The levels of Z- and E-guggulsterone, respectively, were 0.87% and 1.22% in lot 04172009 and 0.65% and 0.82% in lot 07172009. Mass spectrometric analyses (lot 04172009 only) confirmed the presence of Z- and E-guggulsterone, isomers of Z-guggulsterol, 20-β-hydroxy-4-pregnen-3-one, 20-α-hydroxy-4-pregnen-3-one, guggulsterol VI, and guggulsterol V. Contaminant analyses showed the presence of low levels of lead, antimony, and molybdenum. Arsenic, aflatoxins (B1, B2, G1, G2), ochratoxin, and zearalenone could not be determined due to matrix interferences. Pesticide levels were below the limits of quantitation of 0.01 or 0.02 ppm. Summary results of these analyses are shown in Table 1. Additionally, nutritional assessments identified total fat levels of 5.61% and 3.63%, carbohydrate levels of 55.5% and 57.3%, and protein levels of <0.100% and <0.100%, in lots 04172009 and 07172009, respectively. Therefore, it was concluded that sieving of the test formulation caused minimal alteration of the assessed nutritional content.

Individual aliquots of lot 07172009 were removed for use as frozen reference standards and archive samples. The remaining was stored in large, amber plastic bags at room temperature. Frozen reference standards were stored at −20°C. Lot 07172009 was used in the 3-month studies.

### C.1.2 Corn Oil

Corn oil was obtained from Sigma-Aldrich (St. Louis, MO) in a single lot (128K0040) and used as the vehicle in the 3-month studies. Twice during the study period, potentiometric titration was used to determine the peroxide content, which was below the rejection level of 3 mEq/kg.

## C.2 Preparation and Analysis of Dose Formulations

Dose formulations were prepared three times over the course of the study using the GGE formulation (lot 07172009) and corn oil (Table C-2). Formulations were prepared at concentrations of 12.5, 25, 50, 100, and 200 mg/mL (rats) or 1.55, 3.1, 6.25, 12.5, and 25 mg/mL (mice). Quantification stock solutions used Z- and E-guggulsterone isomers at target concentrations of 0.8654 and 0.4808 mg/mL in tetrahydrofuran. Quantification of these isomers using HPLC/UV (system B) showed the dosing formulations were within 10% of expected values.

Homogeneity studies of the 1.55, 12.5, 25, and 200 mg/mL formulations were also performed using HPLC/UV (system B). Relative standard deviations (RSDs) were within 5% of target for each concentration, and thus homogeneity was deemed sufficient. Because the formulas were suspensions, continuous stirring was required to ensure homogeneity. Gavagability was confirmed using 25 and 200 mg/mL formulations of GGE (lot 04172009) in corn oil. Dispensing the aliquots occurred in approximately 5 seconds for a 1 mL dose using a 20- or 18-gauge needle, with an RSD within 5% of the target dose.

Each preadministration and postadministration (animal room) dose formulation of GGE was analyzed three times (July 20, August 17, and September 18, 2009). All preadministration formulations were within 10% of the target concentration. Animal room samples were determined to be within 10% of the target (Table C-3).

GGE formulations were stored in sealed glass containers at concentrations of 1.55 mg/mL or higher at room temperature for up to 42 days. Stability was confirmed for these conditions up to 42 days.

Table C-1 Chromatography Systems Used in the Three-month Gavage Studies of Gum Guggul Extract

Chromatography | Detection System | Column | Mobile Phase
System A
HPLC | UV (245 nm) | Alltech, Adsorbosphere HS; 150 x 4.6 mm, 5 μm | 30/70 acetonitrile: ASTM Type I water; flow rate 1 mL/min
System B
HPLC | UV (254 nm) | Zorbax, Eclipse XDB; 150 x 4.6 mm, 3.5 μm | 45/55 acetonitrile:0.1% formic acid in water; flow rate 1.0 mL/min

Table C-2 Preparation and Storage of Dose Formulations in the Three-month Gavage Studies of Gum Guggul Extract

Three-month Studies
Preparation Prior to use in the dose formulation, approximately 1,325 grams of the Gugulipid^®^ extract was sieved through an 80-mesh sieve. An appropriate amount of the sieved GGE formulation was weighed, then transferred into a calibrated mixing container with a stir bar. The weighing container was rinsed with the corn oil vehicle three times and transferred to the mixing container. The vehicle was transferred in increments while stirring to ensure the GGE formulation was wetted until the mixing container was diluted to the final volume with corn oil. The formulation was mixed for approximately 15 minutes at a rate that produced a vigorous vortex without creating excess foam. Dose formulations were prepared four times.
Chemical Lot Number 07172009
Maximum Storage Time 42 days
Storage Conditions Stored in sealed clear glass bottles at room temperature (17–25°C).
Study Laboratory Battelle (Columbus, OH)

Table C-3 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Gavage Studies of Gum Guggul Extract^a^

Date Prepared | Date Analyzed | Target Concentration (mg/mL)^b,c^ | Determined Concentration (mg/mL) | Difference from Target (%)
Mice
July 20, 2009 | July 21, 2009 | 0 | BLOQ | NA
July 20, 2009 | July 21, 2009 | 1.55 | 1.43 ± 0.05 | −8.5
July 20, 2009 | July 21, 2009 | 3.1 | 2.95 ± 0.02 | −5.1
July 20, 2009 | July 21, 2009 | 6.25 | 6.02 ± 0.11 | −3.8
July 20, 2009 | July 21, 2009 | 12.5 | 12.0 ± 0.2 | −3.9
July 20, 2009 | July 21, 2009 | 25 | 23.8 ± 0.1 | −4.9
August 17, 2009 | August 18, 2009 | 0 | BLOQ | NA
August 17, 2009 | August 18, 2009 | 1.55 | 1.62 ± 0.04 | 4.5
August 17, 2009 | August 18, 2009 | 3.1 | 3.15 ± 0.03 | 1.5
August 17, 2009 | August 18, 2009 | 6.25 | 6.34 ± 0.02 | 1.5
August 17, 2009 | August 18, 2009 | 12.5 | 12.9 ± 0.1 | 2.8
August 17, 2009 | August 18, 2009 | 25 | 26.1 ± 0.2 | 4.3
September 18, 2009 | September 23, 2009 | 0 | BLOQ | NA
September 18, 2009 | September 23, 2009 | 1.55 | 1.64 ± 0.02 | 5.7
September 18, 2009 | September 23, 2009 | 3.1 | 3.07 ± 0.03 | −0.9
September 18, 2009 | September 23, 2009 | 6.25 | 6.26 ± 0.03 | 0.2
September 18, 2009 | September 23, 2009 | 12.5 | 12.6 ± 0.1 | 1.0
September 18, 2009 | September 23, 2009 | 25 | 25.4 ± 0.1 | 1.6
Rats
July 20, 2009 | July 20, 2009 | 0 | BLOQ | NA
July 20, 2009 | July 20, 2009 | 12.5 | 12.0 ± 0.2 | −3.9
July 20, 2009 | July 20, 2009 | 25 | 23.8 ± 0.1 | −4.9
July 20, 2009 | July 20, 2009 | 50 | 47.0 ± 0.2 | −6.3
July 20, 2009 | July 20, 2009 | 100 | 93.7 ± 0.6 | −6.7
July 20, 2009 | July 20, 2009 | 200 | 190 ± 2 | −5.5
August 17, 2009 | August 18, 2009 | 0 | BLOQ | NA
August 17, 2009 | August 18, 2009 | 12.5 | 12.9 ± 0.1 | 2.8
August 17, 2009 | August 18, 2009 | 25 | 26.1 ± 0.2 | 4.3
August 17, 2009 | August 18, 2009 | 50 | 48.6 ± 2.8 | −3.2
August 17, 2009 | August 18, 2009 | 100 | 93.1 ± 0.4 | −7.5
August 17, 2009 | August 18, 2009 | 200 | 195 ± 2 | −2.7
September 18, 2009 | September 23, 2009 | 0 | BLOQ | NA
September 18, 2009 | September 23, 2009 | 12.5 | 12.6 ± 0.1 | 1.0
September 18, 2009 | September 23, 2009 | 25 | 25.4 ± 0.1 | 1.6
September 18, 2009 | September 23, 2009 | 50 | 55.3 ± 0.5 | 9.6
September 18, 2009 | September 23, 2009 | 100 | 101 ± 1 | 1.2
September 18, 2009 | September 23, 2009 | 200 | 216 ± 5 | 7.3
Animal Room Samples
Mice
July 20, 2009 | August 25, 2009 | 0 | BLOQ | NA
July 20, 2009 | August 25, 2009 | 1.55 | 1.47 ± 0.01 | −5.2
July 20, 2009 | August 25, 2009 | 3.1 | 2.96 ± 0.01 | −4.6
July 20, 2009 | August 25, 2009 | 6.25 | 6.15 ± 0.21 | −1.7
July 20, 2009 | August 25, 2009 | 12.5 | 12.4 ± 0.1 | −1.1
July 20, 2009 | August 25, 2009 | 25 | 24.3 ± 0.2 | −2.9
August 17, 2009 | September 30, 2009 | 0 | BLOQ | NA
August 17, 2009 | September 30, 2009 | 1.55 | 1.63 ± 0.03 | 4.7
August 17, 2009 | September 30, 2009 | 3.1 | 3.37 ± 0.03 | 8.1
August 17, 2009 | September 30, 2009 | 6.25 | 5.99 ± 0.05 | −4.3
August 17, 2009 | September 30, 2009 | 12.5 | 11.7 ± 0.3 | −6.9
August 17, 2009 | September 30, 2009 | 25 | 23.7 ± 0.1 | −5.5
September 18, 2009 | October 30, 2009 | 0 | BLOQ | NA
September 18, 2009 | October 30, 2009 | 6.25 | 6.65 ± 0.07 | 6.4
September 18, 2009 | October 30, 2009 | 12.5 | 12.3 ± 0.1 | −1.3
September 18, 2009 | October 30, 2009 | 25 | 24.0 ± 0.1 | −4.0
September 18, 2009 | November 12, 2009 | 1.55 | 1.65 ± 0.04 | 6.5
September 18, 2009 | November 12, 2009 | 3.1 | 3.10 ± 0.06 | −1.1
Rats
July 20, 2009 | August 25, 2009 | 0 | BLOQ | NA
July 20, 2009 | August 25, 2009 | 12.5 | 12.2 ± 0.2 | −2.8
July 20, 2009 | August 25, 2009 | 25 | 24.7 ± 0.1 | −1.2
July 20, 2009 | August 25, 2009 | 50 | 49.0 ± 0.2 | −2.0
July 20, 2009 | August 25, 2009 | 100 | 99.6 ±1.5 | −0.5
July 20, 2009 | August 25, 2009 | 200 | 201 ± 4 | 0.6
August 17, 2009 | September 30, 2009 | 0 | BLOQ | NA
August 17, 2009 | September 30, 2009 | 12.5 | 12.5 ± 0.3 | 0.0
August 17, 2009 | September 30, 2009 | 25 | 23.5 ± 0.0 | −6.4
August 17, 2009 | September 30, 2009 | 50 | 47.8 ± 0.5 | −4.6
August 17, 2009 | September 30, 2009 | 100 | 96.6 ± 1.2 | −3.5
August 17, 2009 | September 30, 2009 | 200 | 193 ± 4 | −3.5
September 18, 2009 | October 30, 2009 | 0 | BLOQ | NA
September 18, 2009 | October 30, 2009 | 12.5 | 12.5 ± 0.1 | 0.3
September 18, 2009 | October 30, 2009 | 25 | 24.1 ± 0.1 | −3.7
September 18, 2009 | October 30, 2009 | 50 | 48.7 ± 0.7 | −2.6
September 18, 2009 | October 30, 2009 | 100 | 97.8 ± 0.5 | −2.2
September 18, 2009 | October 30, 2009 | 200 | 195 ± 1 | −2.6

BLOQ = below the limit of quantification; GGE = gum guggul extract; NA = not applicable.

^a^ Data shown as mean ± standard deviation.

^b^ For rats, dosing volume = 5 mL/kg. 12.5 mg/L = 62.5 mg/kg/day; 25 mg/L = 125 mg/kg/day; 50 mg/L = 250 mg/kg/day; 100 mg/L = 500 mg/kg/day; 200 mg/L = 1,000 mg/kg/day.

^c^ For mice, dosing volume = 10 mL/kg. 1.55 mg/L = 15.5 mg/kg/day; 3.1 mg/L = 31 mg/kg/day; 6.25 mg/L = 62.5 mg/kg/day; 12.5 mg/L = 125 mg/kg/day; 25 mg/L = 250 mg/kg/day.