# Appendix B Genetic Toxicology

## B.1 Peripheral Blood Micronucleus Test Protocol

At termination of the 3-month toxicity studies of GGE, blood samples (approximately 200 μL) were collected from male and female rats and mice, placed in EDTA-coated tubes, and shipped overnight to the testing laboratory. On arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (polychromatic erythrocytes, PCEs, reticulocytes) and mature erythrocytes (normochromatic erythrocytes, NCEs) using a flow cytometer^75^; both the mature and the immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte subpopulation (CD71-positive cells) can be targeted using this technique, rat blood samples can be analyzed for damage that occurred in the bone marrow within the past 24 to 48 hours, before the rat spleen appreciably alters the percentage of micronucleated reticulocytes in circulation.^99^ In mice, both the immature and mature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice following 4 weeks of continuous exposure. Approximately 20,000 reticulocytes and 1 x 10^6^ erythrocytes were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from chemical exposure.

Prior experience with the large number of cells scored using flow cytometric scoring techniques^76^ suggests it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the vehicle control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances and for which linear regression is used to test for a linear trend with dose; the Williams test is used to test for pairwise differences between each treatment group and the vehicle control group. In the case of unequal variances, Jonckheere’s test is used to test for linear trend and Dunn’s test is used for pairwise comparisons of each treatment group with the vehicle control group. To correct for multiple pairwise comparisons, the p value for each comparison with the vehicle control group is multiplied by the number of comparisons made. In the event that this product is greater than 1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the vehicle controls are considered statistically significant at p ≤ 0.025.

In the micronucleus test, a positive result is based, preferably, on the presence of both a significant trend and at least one significantly elevated dose group compared to the corresponding control group. In addition, historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. The presence of either a significant trend or a single significant dose group generally results in an equivocal call. The absence of both a trend and a significant dose group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

## B.2 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by NTP. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## B.3 Results

Administration of the GGE formulation for 3 months by gavage did not increase the frequencies of micronucleated reticulocytes (immature erythrocytes) or mature erythrocytes in peripheral blood samples obtained from male and female Sprague Dawley rats (dose range 62.5–1,000 mg/kg/day) and B6C3F1/N mice (dose range 15.5–250 mg/kg/day) (Table B-1, Table B-2). In addition, no significant changes in the percentage of immature erythrocytes were seen in mice, suggesting that exposure to the GGE formulation did not induce bone marrow toxicity or alter erythropoiesis in these animals. Small increases in %PCE were observed in rats, but due to the magnitude of the responses, which fell within the laboratory historical control ranges, the increases were not considered biologically significant.

Table B-1 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats in the Three-month Gavage Study of Gum Guggul Extract^a^

| Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
n | 5 | 5 | 5 | 5 | 5 | 5
Male
GGE (mg/kg/day)
0 | 0.690 ± 0.117 | – | 0.113 ± 0.019 | – | 0.960 ± 0.033 | –
62.5 | 0.390 ± 0.100 | 0.9406 | 0.072 ± 0.012 | 1.0000 | 0.955 ± 0.032 | 1.0000
125 | 0.460 ± 0.070 | 0.9730 | 0.108 ± 0.030 | 1.0000 | 0.992 ± 0.094 | 1.0000
250 | 0.500 ± 0.084 | 0.9811 | 0.182 ± 0.021 | 0.2461 | 1.035 ± 0.018 | 1.0000
500 | 0.430 ± 0.056 | 0.9852 | 0.100 ± 0.015 | 1.0000 | 0.973 ± 0.081 | 1.0000
1,000 | 0.600 ± 0.076 | 0.8951 | 0.245 ± 0.065 | 0.2117 | 1.453 ± 0.129 | 0.0317
Trend^d^ | p = 0.3490 | – | p = 0.0117 | – | p = 0.0069 | –
Female
GGE (mg/kg/day)
0 | 0.770 ± 0.090 | – | 0.188 ± 0.037 | – | 0.583 ± 0.054 | –
62.5 | 0.540 ± 0.114 | 0.9489 | 0.198 ± 0.019 | 0.6847 | 0.874 ± 0.062 | 0.0156
125 | 0.410 ± 0.070 | 0.9774 | 0.120 ± 0.014 | 0.7699 | 0.898 ± 0.114 | 0.0162
250 | 0.480 ± 0.093 | 0.9846 | 0.164 ± 0.027 | 0.8034 | 0.922 ± 0.131 | 0.0138
500 | 0.630 ± 0.102 | 0.9798 | 0.225 ± 0.045 | 0.6390 | 0.917 ± 0.129 | 0.0124
1,000 | 0.520 ± 0.075 | 0.9829 | 0.151 ± 0.028 | 0.6516 | 1.033 ± 0.040 | 0.0014
Trend^d^ | p = 0.6883 | – | p = 0.5877 | – | p = 0.0181 | –

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented in Witt et al.^75^

^b^ Data presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn tests (p ≤ 0.025).

^d^ Dose-related trends evaluated by linear regression of Jonckheere's test (p ≤ 0.025).

Table B-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice in the Three-month Gavage Study of Gum Guggul Extract^a^

| Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
n | 5 | 5 | 5 | 5 | 5 | 5
Male
GGE (mg/kg/day)
0 | 2.340 ± 0.185 | – | 1.482 ± 0.019 | – | 1.285 ± 0.039 | –
15.5 | 2.070 ± 0.200 | 0.7310 | 1.469 ± 0.033 | 0.8250 | 1.425 ± 0.062 | 0.2337
31 | 2.320 ± 0.110 | 0.6531 | 1.484 ± 0.022 | 0.8940 | 1.323 ± 0.040 | 0.2774
62.5 | 2.355 ± 0.112 | 0.6871 | 1.428 ± 0.015 | 0.9157 | 1.363 ± 0.050 | 0.2982
125 | 2.370 ± 0.178 | 0.7063 | 1.398 ± 0.032 | 0.9265 | 1.437 ± 0.052 | 0.0690
250 | 2.170 ± 0.096 | 0.7201 | 1.431 ± 0.022 | 0.9335 | 1.415 ± 0.055 | 0.0706
Trend^d^ | p = 0.6130 | – | p = 0.9716 | – | p = 0.1369 | –
Female
GGE (mg/kg/day)
0 | 1.910 ± 0.196 | – | 0.994 ± 0.033 | – | 1.216 ± 0.092 | –
15.5 | 2.235 ± 0.135 | 0.4860 | 1.089 ± 0.027 | 0.0603 | 1.345 ± 0.137 | 0.5908
31 | 1.763 ± 0.085 | 0.5663 | 1.090 ± 0.023 | 0.0718 | 1.398 ± 0.152 | 0.6575
62.5 | 1.910 ± 0.154 | 0.5994 | 1.019 ± 0.031 | 0.0763 | 1.348 ± 0.091 | 0.7019
125 | 2.070 ± 0.090 | 0.6194 | 1.036 ± 0.014 | 0.0775 | 1.431 ± 0.140 | 0.7233
250 | 1.610 ± 0.108 | 0.6316 | 1.020 ± 0.016 | 0.0779 | 1.296 ± 0.249 | 0.7365
Trend^d^ | p = 0.9643 | – | p = 0.8025 | – | p = 0.7869 | –

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented in Witt et al.^75^

^b^ Data presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn tests (p ≤ 0.025).

^d^ Dose-related trends evaluated by linear regression of Jonckheere's test (p ≤ 0.025).