# Appendix A Estrous Cycle Characterization

Table A-1 Estrous Cycle Characterization for Female Mice in the Three-month Gavage Study of Gum Guggul Extract

| 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day
n | 10 | 10 | 10 | 9
Number of Estrous Cycles^a^ | 2.2 ± 0.25 | 2.4 ± 0.16 | 1.8 ± 0.20 | 2.1 ± 0.26
Estrous Cycle Length (days)^a^ | 4.5 ± 0.32 | 4.6 ± 0.28 | 4.4 ± 0.26 | 4.1 ± 0.18
Estrous Stages (% of cycle)
Diestrus | 38.1 | 31.9 | 43.8 | 44.4
Proestrus | 0.0 | 0.6 | 0.0 | 0.6
Estrus | 45.6 | 49.4 | 40.0 | 43.8
Metestrus | 14.4 | 13.8 | 10.0 | 8.1
Not clear^b^ | 1.9 | 4.4 | 6.3 | 3.1

^a^ Each dose group was compared to the vehicle control group with Shirley’s test when a trend was present (p ≤ 0.01 from Jonckheere’s test), otherwise Dunn’s test was applied.

^b^ Not clear, poor quality, or insufficient number of cells.

Figure A-1

Vaginal Cytology Plots for Female Mice in the Three-month Gavage Study of Gum Guggul Extract

I = insufficient number of cells to determine stage; D = diestrus; P = proestrus; E = estrus; M = metestrus.