# Overview

Occupational exposure to volatile components of artificial butter flavoring (ABF) (including 2,3-butanedione [diacetyl]) via inhalation has been reported to be associated with airway fibrosis in the form of bronchiolitis obliterans, also known as obliterative bronchiolitis (OB), mostly in workers in the microwave popcorn packaging and flavoring industry^1-6^ but also in other food and beverage industries.^7^ OB is a potentially fatal lung disease that is frequently found in lung transplant patients and is characterized by bronchiolar wall inflammation and fibrosis resulting in constrictive bronchiolitis with restricted airflow.^8^ ABF was nominated to the National Toxicology Program (NTP) by The United Food and Commercial Workers International Union for inhalation studies. The nomination included a request to study potentially toxic and highly volatile compounds found in ABF, including 2,3-butanedione and acetoin.

Intratracheal instillation or oropharyngeal aspiration of 2,3-butanedione, or inhalation (whole-body) exposure to 2,3-butanedione vapors, has been shown to cause respiratory toxicity in rats and mice,^9-13^ including airway epithelial injury with OB-like fibrotic lesions in rats^12-14^ that are similar to the OB lesions observed in occupational exposures. Inhalation (whole-body) exposure to 150 or 200 ppm 2,3-butanedione vapors for 2 weeks, or via a single intratracheal instillation of 2,3-butanedione (125 mg/kg body weight), was shown to induce bronchial fibrosis in rats.^12,13^ Three-month and 2-year inhalation toxicity and carcinogenicity testing of 2,3-butanedione (using whole-body exposure) was also conducted in rats and mice.^15^

Due to concerns about the respiratory toxicity of inhaled 2,3-butanedione, 2,3-pentanedione has been used as a replacement in some ABF.^16^ However, 2,3-pentanedione is structurally similar to 2,3-butanedione (both are vicinal diketones) and has been shown to exhibit similar potency to 2,3-butanedione for airway toxicity following inhalation exposure. Inhalation of 2,3-pentanedione vapors by whole-body exposure has been shown to cause respiratory toxicity in rats similar to that of 2,3-butanedione,^13,17-19^ including OB-like airway (bronchial) fibrosis in rats exposed to 150 or 200 ppm for 2 weeks.^13,17,19^

To date, the inhalation toxicity of 2,3-pentanedione has been reported for 2-week and shorter whole-body exposure studies in rats with a main focus on adverse respiratory tract effects. The primary objective of the NTP study reported herein was to evaluate the 3-month inhalation toxicity of 2,3-pentanedione vapors within the respiratory tract, the eyes, and other target organs in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice, including airway/lung lesion formation following 3 months of whole-body exposure and the potential mechanism(s) of chemical-induced pathogenesis within the airways/lung. In addition, the 2-week and 3-month inhalation toxicity of acetoin—which, like 2,3-butanedione, was originally found to be a major volatile component of ABF^9^—was evaluated in Wistar Han rats and B6C3F1/N mice.