# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-98

Report Series: NTP Toxicity Report Series

Report Series Number: 98

Official citation: National Toxicology Program (NTP). 2023. NTP technical report on the toxicity studies of acetoin (CASRN 513-86-0) and 2,3-pentanedione (CASRN 600-14-6) administered by inhalation to Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 98.