# Collaborators

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  W.M. Gwinn, Ph.D., Study Scientist
  M.F. Cesta, D.V.M., Ph.D., Study Pathologist (2,3-pentanedione)
  A.R. Pandiri, B.V.Sc., Ph.D., Study Pathologist (acetoin)
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  G.P. Flake, M.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  B.S. McIntyre, Ph.D.
  D.L. Morgan, Ph.D. (Retired)
  G.K. Roberts, Ph.D.
  V.G. Robinson, M.S.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  G.L. Baker, Ph.D.
  S.L. Grumbein, D.V.M., Ph.D.
  S.J. Harbo, D.V.M.
  H.N. Moore, Ph.D.
  K.M. Patton, D.V.M., Ph.D.
  L.M. Staska, D.V.M., Ph.D.
- Conducted prestart and study-related chemistry and inhalation exposure activities
  A. Gupta, M.S.
  B.K. Hayden
  T.E. Lapainis, Ph.D.
  B.D. MacIsaac, B.S.
  Y.N. Savos, M.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  N. Allison, D.V.M., Ph.D.
  H. Kolenda-Roberts, D.V.M., Ph.D.
- Integrated Laboratory Systems, LLC, Research Triangle Park, North Carolina, USA
  Coordinated Pathology Peer Review on 3-month acetoin studies (April 19, 2011)
  G.D. Hill, D.V.M., Ph.D.
- Charles River Laboratories, Inc., Durham, North Carolina, USA
  Coordinated Pathology Working Groups on 3-month 2,3-pentanedione studies (November 8, 2012, and November 16, 2012)
  K.A. Szabo, D.V.M.
- ICF, Reston, Virginia, USA
  Contributed to technical writing and data integration and ensured report quality
  R.A. Silva, Ph.D.