# References

1 Kreiss K, Gomaa A, Kullman G, Fedan K, Simoes EJ, Enright PL. Clinical bronchiolitis obliterans in workers at a microwave-popcorn plant. N Engl J Med. 2002; 347(5):330–338. 10.1056/NEJMoa020300 12151470
2 Akpinar-Elci M, Travis WD, Lynch DA, Kreiss K. Bronchiolitis obliterans syndrome in popcorn production plant workers. Eur Respir J. 2004; 24(2):298–302. 10.1183/09031936.04.00013903 15332401
3 Kullman G, Boylstein R, Jones W, Piacitelli C, Pendergrass S, Kreiss K. Characterization of respiratory exposures at a microwave popcorn plant with cases of bronchiolitis obliterans. J Occup Environ Hyg. 2005; 2(3):169–178. 10.1080/15459620590923091 15764540
4 Kanwal R, Kullman G, Piacitelli C, Boylstein R, Sahakian N, Martin S, Fedan K, Kreiss K. Evaluation of flavorings-related lung disease risk at six microwave popcorn plants. J Occup Environ Med. 2006; 48(2):149–157. 10.1097/01.jom.0000194152.48728.fb 16474263
5 van Rooy FGBGJ, Rooyackers JM, Prokop M, Houba R, Smit LAM, Heederik DJJ. Bronchiolitis obliterans syndrome in chemical workers producing diacetyl for food flavorings. Am J Respir Crit Care Med. 2007; 176(5):498–504. 10.1164/rccm.200611-1620OC 17541015
6 Halldin CN, Suarthana E, Fedan KB, Lo YC, Turabelidze G, Kreiss K. Increased respiratory disease mortality at a microwave popcorn production facility with worker risk of bronchiolitis obliterans. PLoS One. 2013; 8(2):e57935. 10.1371/journal.pone.0057935 23469109
7 Cavalcanti ZR, Albuquerque Filho APL, Pereira CA, Coletta ENAM. Bronchiolitis associated with exposure to artificial butter flavoring in workers at a cookie factory in Brazil. J Bras Pneumol. 2012; 38(3):395–399. 10.1590/S1806-37132012000300016 22782611
8 Schlesinger C, Veeraraghavan S, Koss MN. Constrictive (obliterative) bronchiolitis. Curr Opin Pulm Med. 1998; 4(5):288–293. 10.1097/00063198-199809000-00008 10813204
9 Hubbs AF, Battelli LA, Goldsmith WT, Porter DW, Frazer D, Friend S, Schwegler-Berry D, Mercer RR, Reynolds JS, Grote A, et al. Necrosis of nasal and airway epithelium in rats inhaling vapors of artificial butter flavoring. Toxicol Appl Pharmacol. 2002; 185(2):128–135. 10.1006/taap.2002.9525 12490137
10 Hubbs AF, Goldsmith WT, Kashon ML, Frazer D, Mercer RR, Battelli LA, Kullman GJ, Schwegler-Berry D, Friend S, Castranova V. Respiratory toxicologic pathology of inhaled diacetyl in Sprague-Dawley rats. Toxicol Pathol. 2008; 36(2):330–344. 10.1177/0192623307312694 18474946
11 Morgan DL, Flake GP, Kirby PJ, Palmer SM. Respiratory toxicity of diacetyl in C57BL/6 mice. Toxicol Sci. 2008; 103(1):169–180. 10.1093/toxsci/kfn016 18227102
12 Palmer SM, Flake GP, Kelly FL, Zhang HL, Nugent JL, Kirby PJ, Foley JF, Gwinn WM, Morgan DL. Severe airway epithelial injury, aberrant repair and bronchiolitis obliterans develops after diacetyl instillation in rats. PLoS One. 2011; 6(3):e17644. 10.1371/journal.pone.0017644 21464978
13 Morgan DL, Jokinen MP, Johnson CL, Price HC, Gwinn WM, Bousquet RW, Flake GP. Chemical reactivity and respiratory toxicity of the α-diketone flavoring agents: 2,3-butanedione, 2,3-pentanedione, and 2,3-hexanedione. Toxicol Pathol. 2016; 44(5):763–783. 10.1177/0192623316638962 27025954
14 Flake GP, Morgan DL. Pathology of diacetyl and 2,3-pentanedione airway lesions in a rat model of obliterative bronchiolitis. Toxicology. 2017; 388:40–47. 10.1016/j.tox.2016.10.013 27984136
15 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,3-butanedione (CASRN 431-03-8) in Wistar Han [Crl:WI (Han)] rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2018. NTP Technical Report No. 593. 10.22427/NTP-TR-593
16 Curwin BD, Deddens JA, McKernan LT. Flavoring exposure in food manufacturing. J Expo Sci Environ Epidemiol. 2015; 25(3):324–333. 10.1038/jes.2014.52 25052692
17 Morgan DL, Jokinen MP, Price HC, Gwinn WM, Palmer SM, Flake GP. Bronchial and bronchiolar fibrosis in rats exposed to 2,3-pentanedione vapors: Implications for bronchiolitis obliterans in humans. Toxicol Pathol. 2012; 40(3):448–465. 10.1177/0192623311431946 22215510
18 Hubbs AF, Cumpston AM, Goldsmith WT, Battelli LA, Kashon ML, Jackson MC, Frazer DG, Fedan JS, Goravanahally MP, Castranova V, et al. Respiratory and olfactory cytotoxicity of inhaled 2,3-pentanedione in Sprague-Dawley rats. Am J Pathol. 2012; 181(3):829–844. 10.1016/j.ajpath.2012.05.021 22894831
19 Morgan DL, Merrick BA, Gerrish KE, Stockton PS, Wang Y, Foley JF, Gwinn WM, Kelly FL, Palmer SM, Ton TVT, et al. Gene expression in obliterative bronchiolitis-like lesions in 2,3-pentanedione-exposed rats. PLoS One. 2015; 10(2):e0118459. 10.1371/journal.pone.0118459 25710175
20 ChemSpider. Structure search. London, UK: Royal Society of Chemistry; 2021. https://www.chemspider.com/StructureSearch.aspx
21 National Toxicology Program (NTP). Chemical information review document for artificial butter flavoring and constituents diacetyl (CAS No. 431-08-8) and acetoin (CAS No. 513-86-0): Supporting nomination for toxicological evaluation by the National Toxicology Program. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Institute of Environmental Health Sciences, National Toxicology Program; 2007. https://ntp.niehs.nih.gov/ntp/htdocs/chem_background/exsumpdf/artificial_butter_flavoring_508be.pdf
22 Zviely M. Molecule of the month: 2,3-pentanedione. Perfum Flavor. 2009; 34:20–21.
23 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: Acetoin 513-86-0 | DTXSID0024399. Washington, DC: U.S. Environmental Protection Agency; 2021. https://comptox.epa.gov/dashboard/chemical/details/DTXSID0024399
24 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: 2,3-Pentanedione 600-14-6 | DTXSID6051435. Washington, DC: U.S. Environmental Protection Agency; 2021. https://comptox.epa.gov/dashboard/chemical/details/DTXSID6051435
25 Xiao Z, Lu JR. Generation of acetoin and its derivatives in foods. J Agric Food Chem. 2014; 62(28):6487–6497. 10.1021/jf5013902 25000216
26 Opdyke DLJ. Monographs on fragrance raw materials. Food Cosmet Toxicol. 1979; 17(5):509–533. 10.1016/0015-6264(79)90012-9 391674
27 Romano P, Suzzi G. Origin and production of acetoin during wine yeast fermentation. Appl Environ Microbiol. 1996; 62(2):309–315. 10.1128/aem.62.2.309-315.1996 16535224
28 Meijerink J, Braks MAH, Brack AA, Adam W, Dekker T, Posthumus MA, van Beek TA, van Loon JJA. Identification of olfactory stimulants for Anopheles gambiae from human sweat samples. J Chem Ecol. 2000; 26(6):1367–1382. 10.1023/A:1005475422978
29 Hallagan JB. The use of diacetyl (2,3-butanedione) and related flavoring substances as flavorings added to foods—Workplace safety issues. Toxicology. 2017; 388:1–6. 10.1016/j.tox.2017.05.010 28587783
30 Pejin J, Grujic O, Markov S, Kocic-Tanackov S, Tanackov I, Cvetkovic D, Djurendic M. Application of GC/MS method using SPE columns for quantitative determination of diacetyl and 2,3-pentanedione during beer fermentation. J Am Soc Brew Chem. 2006; 64(1):52–60. 10.1094/ASBCJ-64-0052
31 Tam MS, Gunter GC, Craciun R, Miller DJ, Jackson JE. Reaction and spectroscopic studies of sodium salt catalysts for lactic acid conversion. Ind Eng Chem Res. 1997; 36(9):3505–3512. 10.1021/ie970014m
32 Burdock GA. Encyclopedia of food and color additives. Boca Raton, FL: CRC Press; 1997.
33 Day G, LeBouf R, Grote A, Pendergrass S, Cummings K, Kreiss K, Kullman G. Identification and measurement of diacetyl substitutes in dry bakery mix production. J Occup Environ Hyg. 2011; 8(2):93–103. 10.1080/15459624.2011.547148 21253982
34 National Institute for Occupational Safety and Health (NIOSH). Criteria for a recommended standard: Occupational exposure to diacetyl and 2,3-pentanedione. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2016. DHHS (NIOSH) Publication No. 2016-111. https://www.cdc.gov/niosh/docs/2016-111/default.html
35 Allen JG, Flanigan SS, LeBlanc M, Vallarino J, MacNaughton P, Stewart JH, Christiani DC. Flavoring chemicals in E-cigarettes: Diacetyl, 2,3-pentanedione, and acetoin in a sample of 51 products, including fruit-, candy-, and cocktail-flavored E-cigarettes. Environ Health Perspect. 2016; 124(6):733–739. 10.1289/ehp.1510185 26642857
36 Farsalinos KE, Kistler KA, Gillman G, Voudris V. Evaluation of electronic cigarette liquids and aerosol for the presence of selected inhalation toxins. Nicotine Tob Res. 2015; 17(2):168–174. 10.1093/ntr/ntu176 25180080
37 Fujioka K, Shibamoto T. Determination of toxic carbonyl compounds in cigarette smoke. Environ Toxicol. 2006; 21(1):47–54. 10.1002/tox.20153 16463255
38 Pierce JS, Abelmann A. L.J. S, Adams RE, Finley BL. Diacetyl and 2,3-pentanedione exposures associated with cigarette smoking: Implications for risk assessment of food and flavoring workers. Crit Rev Toxicol. 2014; 44(5):420–435. 10.3109/10408444.2014.882292 24635357
39 Hubbs AF, Kreiss K, Cummings KJ, Fluharty KL, O’Connell R, Cole A, Dodd TM, Clingerman SM, Flesher JR, Lee R, et al. Flavorings-related lung disease: A brief review and new mechanistic data. Toxicol Pathol. 2019; 47(8):1012–1026. 10.1177/0192623319879906 31645208
40 Gaffney SH, Abelmann A, Pierce JS, Glynn ME, Henshaw JL, McCarthy LA, Lotter JT, Liong M, Finley BL. Naturally occurring diacetyl and 2,3-pentanedione concentrations associated with roasting and grinding unflavored coffee beans in a commercial setting. Toxicol Rep. 2015; 2:1171–1181. 10.1016/j.toxrep.2015.08.003 28962459
41 Duling MG, LeBouf RF, Cox-Ganser JM, Kreiss K, Martin SB Jr, Bailey RL. Environmental characterization of a coffee processing workplace with obliterative bronchiolitis in former workers. J Occup Environ Hyg. 2016; 13(10):770–781. 10.1080/15459624.2016.1177649 27105025
42 LeBouf RF, Blackley BH, Fortner AR, Stanton M, Martin SB, Groth CP, McClelland TL, Duling MG, Burns DA, Ranpara A, et al. Exposures and emissions in coffee roasting facilities and cafés: Diacetyl, 2,3-pentanedione, and other volatile organic compounds. Front Public Health. 2020; 8:561740. 10.3389/fpubh.2020.561740 33072698
43 U.S. Food and Drug Administration (FDA). 21 CFR Sect. 182.60. 2008. https://www.govinfo.gov/content/pkg/CFR-2008-title21-vol3/pdf/CFR-2008-title21-vol3-sec182-60.pdf
44 U.S. Food and Drug Administration (FDA). 21 CFR Sect. 582.60. 2008. https://www.govinfo.gov/content/pkg/CFR-2008-title21-vol6/pdf/CFR-2008-title21-vol6-sec582-60.pdf
45 U.S. Food and Drug Administration (FDA). 21 CFR Sect. 172.515. 2008. https://www.govinfo.gov/content/pkg/CFR-2008-title21-vol3/pdf/CFR-2008-title21-vol3-sec172-515.pdf
46 Greenberg LA. Acetoin: Polarographic determination and disappearance from the blood after administration. J Biol Chem. 1943; 147(1):11–17. 10.1016/S0021-9258(18)72405-8
47 Westerfeld WW, Berg RL. Observations on the metabolism of acetoin. J Biol Chem. 1943; 148(3):523–528. 10.1016/S0021-9258(18)72251-5
48 Doisy EA Jr, Westerfeld WW. The relationship of acetoin to metabolic acetylations. J Biol Chem. 1943; 149(1):229–236. 10.1016/S0021-9258(18)72233-3
49 Lipmann F. Acetylation of sulfanilamide by liver homogenates and extracts. J Biol Chem. 1945; 160(1):173–190. 10.1016/S0021-9258(18)43110-9
50 Gabriel MA, Jabara H, al-Khalidi UA. Metabolism of acetoin in mammalian liver slices and extracts. Interconversion with butane-2,3-diol and biacetyl. Biochem J. 1971; 124(4):793–800. 10.1042/bj1240793 4399820
51 Gabriel MA, Ilbawi M, al-Khalidi UA. The oxidation of acetoin to CO2 in intact animals and in liver mince preparation. Comp Biochem Physiol B. 1972; 41(3):493–502. 10.1016/0305-0491(72)90112-5 5029485
52 Nakagawa J, Ishikura S, Asami J, Isaji T, Usami N, Hara A, Sakurai T, Tsuritani K, Oda K, Takahashi M, et al. Molecular characterization of mammalian dicarbonyl/L-xylulose reductase and its localization in kidney. J Biol Chem. 2002; 277(20):17883–17891. 10.1074/jbc.M110703200 11882650
53 Ebert B, Kisiela M, Maser E. Human DCXR – another ‘moonlighting protein’ involved in sugar metabolism, carbonyl detoxification, cell adhesion and male fertility? Biol Rev Camb Philos Soc. 2015; 90(1):254–278. 10.1111/brv.12108 24720935
54 Zaccone EJ, Goldsmith WT, Shimko MJ, Wells JR, Schwegler-Berry D, Willard PA, Case SL, Thompson JA, Fedan JS. Diacetyl and 2,3-pentanedione exposure of human cultured airway epithelial cells: Ion transport effects and metabolism of butter flavoring agents. Toxicol Appl Pharmacol. 2015; 289(3):542–549. 10.1016/j.taap.2015.10.004 26454031
55 Gaunt IF, Brantom PG, Kiss IS, Grasso P, Gangolli SD. Short-term toxicity of acetoin (acetylmethylcarbinol) in rats. Food Cosmet Toxicol. 1972; 10(2):131–141. 10.1016/S0015-6264(72)80191-3 5072814
56 Holden VK, Hines SE. Update on flavoring-induced lung disease. Curr Opin Pulm Med. 2016; 22(2):158–164. 10.1097/MCP.0000000000000250 26761629
57 Day GA, Cummings KJ, Kullman GJ. Health hazard evaluation report: Report on an investigation of buttermilk flavoring exposures and respiratory health at a bakery mix production facility, General Mills, Los Angeles, CA. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2009. NIOSH HETA 2008-0230-3096. https://www.cdc.gov/niosh/hhe/reports/pdfs/2008-0230-3096.pdf
58 Harvey RR, Fechter-Leggett ED, Bailey RL, Edwards NT, Fedan KB, Virji MA, Nett RJ, Cox-Ganser JM, Cummings KJ. The burden of respiratory abnormalities among workers at coffee roasting and packaging facilities. Front Public Health. 2020; 8:5. 10.3389/fpubh.2020.00005 32083049
59 Cummings KJ, Boylstein RJ, Stanton ML, Piacitelli CA. Health hazard evaluation report: An evaluation of respiratory health at a flavoring manufacturing facility -- Kentucky. Morgantown, WV: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2013. NIOSH HHE Report No. 2012-0012-3192. https://www.cdc.gov/niosh/hhe/reports/pdfs/2012-0012-3192.pdf
60 Aeschbacher HU, Wolleb U, Löliger J, Spadone JC, Liardon R. Contribution of coffee aroma constituents to the mutagenicity of coffee. Food Chem Toxicol. 1989; 27(4):227–232. 10.1016/0278-6915(89)90160-9 2659457
61 Garst J, Stapleton P, Johnson J. Mutagenicity of alpha-hydroxy ketones may involve superoxide anion radical In: Greenwald RA, Cohen G, editors. Oxy Radicals and Their Scavenger Systems, Vol 2: Cellular and Medical Aspects. New York, NY: Elsevier Biomedical; 1983. p. 125-130.
62 Florin I, Rutberg L, Curvall M, Enzell CR. Screening of tobacco smoke constituents for mutagenicity using the Ames’ test. Toxicology. 1980; 15(3):219–232. 10.1016/0300-483X(80)90055-4 7008261
63 Tran YK, Buick JK, Keir JLA, Williams A, Swartz CD, Recio L, White PA, Lambert IB, Yauk CL. Integrated in silico and in vitro genotoxicity assessment of thirteen data-poor substances. Regul Toxicol Pharmacol. 2019; 107:104427. 10.1016/j.yrtph.2019.104427 31336127
64 Bjeldanes LF, Chew H. Mutagenicity of 1,2-dicarbonyl compounds: Maltol, kojic acid, diacetyl and related substances. Mutat Res. 1979; 67(4):367–371. 10.1016/0165-1218(79)90034-X 384239
65 Marnett LJ, Hurd HK, Hollstein MC, Levin DE, Esterbauer H, Ames BN. Naturally occurring carbonyl compounds are mutagens in Salmonella tester strain TA104. Mutat Res. 1985; 148(1-2):25–34. 10.1016/0027-5107(85)90204-0 3881660
66 King-Herbert A, Vasbinder MA. Chapter 22, Toxicology. In: Suckow MA, Hankenson FC, Wilson RP, Foley PL, editors. The Laboratory Rat. 3rd ed. London, UK: Academic Press; 2020. p. 849–862. 10.1016/B978-0-12-814338-4.00022-2
67 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
68 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
69 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
70 Armitage P. Statistical methods in medical research. Oxford, UK: Blackwell Scientific; 1971.
71 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
72 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
73 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
74 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
75 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
76 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
77 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
78 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill; 1957. 10.2307/2332898
79 U.S. Food and Drug Administration (FDA). 21 CFR Part 58. https://www.accessdata.fda.gov/scripts/cdrh/cfdocs/cfcfr/CFRSearch.cfm?CFRPart=58
80 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
81 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 7021938
82 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Flamm WG, Lorentzen RJ, editors. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing; 1985. p. 13–59.
83 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
84 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
85 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
86 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
87 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
88 Shelby MD, Witt KL. Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. 10.1002/em.2850250407 7607185
89 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163-194. 11044899 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
90 National Toxicology Program (NTP). TOX-98: Toxicity report tables & curves: Pathology tables, survival and growth curves from NTP short-term and genetic toxicology studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2020. 10.22427/NTP-DATA-TOX-98
91 Everds NE, Snyder PW, Bailey KL, Bolon B, Creasy DM, Foley GL, Rosol TJ, Sellers T. Interpreting stress responses during routine toxicity studies: A review of the biology, impact, and assessment. Toxicol Pathol. 2013; 41(4):560–614. 10.1177/0192623312466452 23475558
92 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
93 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. 10.1002/em.20075 15517570
94 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117