# Discussion

Occupational inhalation exposure to volatile components of artificial butter flavoring (ABF) (including 2,3-butanedione [diacetyl]) has been reported to be associated with airway fibrosis in the form of obliterative bronchiolitis (OB).^1-6^ ABF was subsequently nominated to the National Toxicology Program (NTP) by the United Food and Commercial Workers International Union for inhalation studies to assess the potentially toxic and highly volatile constituents of ABF, including 2,3-butanedione and acetoin. Due to concerns about the respiratory toxicity of inhaled 2,3-butanedione as indicated by workplace exposure assessments and in vivo studies showing the induction of OB-like fibrotic airway lesions (similar to those observed in occupational exposures)^14^ in exposed rats, 2,3-pentanedione has been used as a replacement for 2,3-butanedione in some ABF.^16^ However, 2,3-pentanedione is a vicinal diketone, like 2,3-butanedione, and has been shown to exhibit reactivity and toxicological potency that is similar to that of 2,3-butanedione.

The toxicity and fibrogenicity of inhaled 2,3-pentanedione has been reported for 2-week and shorter whole-body exposure studies in rats with a focus on adverse effects in the respiratory tract. The primary objective of this NTP study was to evaluate the 3-month inhalation toxicity of 2,3-pentanedione vapors within the respiratory tract, including airway lesion formation, and other target organs (including the eyes) in whole-body exposed rats and mice. The 2-week and 3-month inhalation toxicity of acetoin—which, like 2,3-butanedione, was originally found to be in ABF^9^—was also evaluated in rats and mice.

In the current studies, with the exception of a mild, but significant, effect on erythropoiesis observed in male rats exposed for 3 months, there were no significant exposure-related adverse effects in rats or mice exposed to acetoin vapor by whole-body inhalation for 2 weeks or 3 months at concentrations of up to 800 ppm in air for approximately 6 hours per day, 5 days per week.

In male and female rats exposed by whole body inhalation to 50 or 100 ppm 2,3-pentanedione vapor for up to 3 months (approximately 6 hours per day, 5 days per week), clinical observations included abnormal breathing, eye abnormalities (including unilateral or bilateral corneal opacities in some animals), and sneezing. Absolute and relative lung weights and relative heart weight were significantly increased in female rats exposed to 100 ppm for 3 months compared to those of the control group. A small exposure concentration-related increase in the percentage of immature erythrocytes (% PCE) was also observed in female rats exposed to 2,3-pentanedione.

Exposure to 2,3-pentanedione for 3 months caused significant adverse effects primarily in the respiratory tract (nose, larynx, trachea, and lung), but also in the eyes of rats. In the nose, suppurative inflammation, atrophy, and respiratory metaplasia of the olfactory epithelium and hyperplasia and squamous metaplasia of the respiratory epithelium were significantly increased in male and female rats exposed to 50 or 100 ppm. Lymphoid hyperplasia was significantly increased in male rats exposed to 50 or 100 ppm. Olfactory epithelial degeneration in the nose was significantly increased in male and female rats exposed to 50 ppm and female rats exposed to 100 ppm. Necrosis and regeneration of the respiratory epithelium and turbinate atrophy were also significantly increased in males and females exposed to 100 ppm. In the larynx, squamous metaplasia of the respiratory epithelium was significantly increased in males exposed to 50 or 100 ppm and females exposed to 25, 50, or 100 ppm. Hyperplasia of the squamous epithelium was significantly increased in male and female rats exposed to 100 ppm. Chronic active inflammation and necrosis and ulceration of the squamous epithelium were significantly increased in female rats exposed to 100 ppm; hyperplasia of the respiratory epithelium was significantly increased in male rats exposed to 50 ppm. In the trachea, regeneration of the epithelium was significantly increased in males and females exposed to 50 or 100 ppm relative to the control groups. Hyperplasia of the epithelium (and squamous metaplasia by positive trend only) was also increased in males and females exposed to 100 ppm. In the lung, (eosinophilic) inflammation, hyperplasia and regeneration of the bronchial epithelium, and hyperplasia of the bronchiolar epithelium were significantly increased in male and female rats exposed to 100 ppm (and squamous or goblet cell metaplasia of the bronchial epithelium by positive trend only). Focal fibrosis in the lung was also increased in female rats (by positive trend only).

In the eye, 2,3-pentanedione caused a significant increase in acute inflammation of the cornea (50 and 100 ppm) and ciliary body (50 ppm only) in female rats. The incidences of acute inflammation, neovascularization, and epithelial vacuolation of the cornea occurred with a positive trend in male rats. The increases in leukocyte counts (inflammatory leukogram) at day 23 and study termination in both male and female rats correlated with the observed histological changes in the respiratory tract.

In mice exposed to 50 or 100 ppm 2,3-pentanedione for 3 months, clinical observations included abnormal breathing and sneezing in males and females, as well as eye abnormalities in females. Terminal mean body weights were significantly decreased in male and female mice exposed for 3 months to 50 and 100 ppm. On day 8 after the start of exposure to 100 ppm, male and female mice exhibited dramatic body weight loss, but the exposure for this group was not stopped because the weight loss was <20% of the pre-exposure starting body weight and the body weights gradually increased thereafter for the duration of the study. Relative lung weights were significantly increased in male and female mice exposed to 100 ppm and in male mice exposed to 50 ppm. Absolute heart, kidney, and liver weights of male and female mice and absolute spleen weights of female mice exposed to ≥50 ppm 2,3-pentanedione, as well as absolute spleen weights of male mice and relative spleen weights of female mice exposed to 100 ppm, were significantly decreased. Relative heart and spleen weights of male mice and relative kidney weights of female mice exposed to 100 ppm 2,3-pentanedione were significantly increased.

Inhalation (whole-body) exposure to 2,3-pentanedione for 3 months caused significant adverse effects primarily in the respiratory tract (nose, larynx, trachea, and lung), but also in the eyes of mice. In the nose, suppurative inflammation and atrophy and respiratory metaplasia of the olfactory epithelium, regeneration and squamous metaplasia of the respiratory epithelium, and turbinate atrophy and necrosis were significantly increased in males and females exposed to 50 or 100 ppm. Olfactory and respiratory epithelial hyaline droplet formation, hyperplasia of the respiratory epithelium, and septum necrosis were significantly increased in male and female mice exposed to 100 ppm. Necrosis of the respiratory epithelium and perforation of the septum were also significantly increased in male mice exposed to 100 ppm. In the larynx, hyperplasia of the squamous epithelium and squamous metaplasia of the respiratory epithelium, which were considered atypical, were significantly increased in males and females exposed to 50 and 100 ppm. Chronic active inflammation was also significantly increased in males and females exposed to 100 ppm, as was regeneration of the respiratory epithelium in males and females exposed to 50 ppm. Squamous epithelial hyperplasia was also increased in females exposed to 25 ppm. In the trachea, inflammation and atypical squamous metaplasia of the epithelium were significantly increased in males and females exposed to 100 ppm (and atypical hyperplasia in females by positive trend only). Regeneration of the epithelium was also significantly increased in males and females exposed to 50 ppm. In the lung, hyperplasia and degeneration of the bronchiolar epithelium and polymorphonuclear cellular infiltration of the bronchiole were significantly increased in male mice exposed to 100 ppm. Chronic inflammation of the bronchi and degeneration and regeneration of the bronchial epithelium were significantly increased in male and female mice exposed to 50 and 100 ppm, and polymorphonuclear cellular infiltration of the bronchus was significantly increased in male and female mice exposed to 100 ppm. Atypical squamous metaplasia of the bronchial epithelium was also significantly increased in males and females exposed to 100 ppm as was atypical hyperplasia of the bronchial epithelium in males exposed to 50 ppm.

In the eye, acute inflammation, ulceration, and epithelial hyperplasia of the cornea were significantly increased in exposed female mice (by positive trend only), whereas cornea mineralization was significantly increased in female mice exposed to 100 ppm.

OB has been shown to be a significant clinical finding in occupational exposures to the volatile components of ABF including 2,3-butanedione.^39^ In this NTP study, 3-month inhalation (whole-body) exposure to 2,3-pentanedione caused significant adverse airway effects in mice and rats, including hyperplasia of the bronchial and (more distal) bronchiolar epithelium and squamous or goblet cell metaplasia of the bronchial epithelium, but no bronchial or bronchiolar fibrosis was observed. Two-week inhalation (whole-body) exposure to 2,3-pentanedione has been shown previously to cause bronchial fibrosis (OB-like lesions), similar to 2,3-butanedione, in rats exposed to 150 or 200 ppm (with higher morbidity/mortality and decreased pulmonary function at 200 ppm) but not at exposure levels <150 ppm.^13,17,19^ Therefore, despite 3 months of exposure, 100 ppm 2,3-pentanedione was probably not high enough to induce airway fibrosis in the rats. Regarding the mechanism(s) of OB-like fibrotic lesion formation, the data suggest that the initial injury to the airway epithelium is critical to damage the basement membrane and induce fibrosis^14^ (which might not occur at exposure concentrations <150 ppm, even after a prolonged (3-month) exposure period). Of note, this 3-month study was initiated before there was confidence that 2-week inhalation (whole-body) exposure to 2,3-pentanedione at concentrations >150 ppm induced airway fibrosis (OB-like effects) in rats. Therefore, the exposure concentrations for the 3-month study were matched to those tested for 2,3-butanedione.^15^

The absence of airway fibrosis in the mice exposed to 100 ppm 2,3-pentanedione for 3 months is not surprising considering that mice have been shown to be much less susceptible than rats to 2,3-pentanedione-induced airway fibrosis in prior 2-week inhalation (whole-body) exposure studies (unpublished data). Thus, the induction of fibrosis by 2,3-pentanedione might be a species-specific effect. In the 2-year bioassay with 2,3-butanedione, which has also been previously shown to induce OB-like airway fibrosis in rats, some tracheal and bronchial fibroses were observed in rats and mice exposed to the highest tested concentration of 50 ppm,^15^ suggesting that a much longer (chronic) exposure duration (of up to 2 years) to lower exposure concentrations may be sufficient to induce airway fibrosis. Interestingly, inhalation exposure of mice to 2,3-pentanedione vapors caused hyperplasia of the squamous epithelium and squamous metaplasia of the respiratory epithelium in the larynx and hyperplasia and squamous metaplasia of the tracheal and bronchial epithelium, which were considered atypical and therefore potentially preneoplastic.

In summary, due to concerns regarding the association between occupational exposure to highly volatile components (acetoin, 2,3-butanedione, and 2,3-pentanedione) of ABF and adverse fibrotic lung effects (specifically, OB in the distal airways), 3-month inhalation toxicity testing of acetoin and 2,3-pentanedione vapors was conducted in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice using whole-body exposure to evaluate the respiratory toxicity, as well as the toxicity to other target organs (including the eyes), of these compounds. A 2-week inhalation toxicity study was also performed for acetoin.

Under the conditions of this inhalation study, there were no significant exposure-related adverse effects in rats or mice exposed to acetoin for 2 weeks or 3 months. Exposure to 2,3-pentanedione via whole-body inhalation for 3 months caused significant adverse effects primarily in the respiratory tract, but also in the eyes, of rats and mice. These airway findings attributed to 2,3-pentanedione included exposure-related inflammation, injury (degeneration), regeneration, squamous metaplasia, and/or hyperplasia of the tracheal, bronchial, and bronchiolar epithelium. Interestingly, the hyperplasia and squamous metaplasia of the tracheal and bronchial epithelium observed in the mice were considered atypical and therefore potentially preneoplastic. The no-observed-effect level (NOEL) for the bronchial and bronchiolar adverse effects in the lung was 25 ppm in rats and 12.5 ppm in mice after 3 months of exposure to 2,3-pentanedione. These lesions are most relevant because the distal bronchi/bronchioles are the target sites for OB, and hyperplasia/squamous metaplasia could accompany or be precursors to fibrotic lesions (e.g., if the tested exposure concentration was higher) and the morphology of the bronchial/bronchiolar lesions is similar to OB. Regarding eye toxicity, inflammation and degenerative lesions of the cornea were observed, which extended into other ocular compartments in some animals, including the anterior chamber, ciliary body, sclera, conjunctiva, and iris. The NOEL of 2,3-pentanedione for this study overall was 12.5 ppm on the basis of adverse respiratory tract effects in rats and mice. These 3-month inhalation exposure data, including NOELs for adverse respiratory tract effects, can inform regulatory agencies to help mitigate exposure risks to 2,3-pentanedione vapors in the workplace.