# Results

## Data Availability

All study data were evaluated. Data relevant for evaluating toxicological findings are presented here. All study data are available in the National Toxicology Program (NTP) Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TOX-98.^90^

## Acetoin

### Two-week Studies in Rats and Mice

All rats and mice survived to the end of the 2-week studies, and mean body weights at study termination of animals exposed to acetoin remained within 5% of those of control animals for both rats and mice (Table 3). No histopathological changes related to acetoin exposure were observed (Appendix E).

Table 3 Summary of Survival and Mean Body Weights of Male and Female Rats and Mice in the Two-week Inhalation Studies of Acetoin

Study Day^a^ | 0 ppm | | 6.25 ppm | | | 25 ppm | | | 100 ppm | | | 400 ppm | | | 800 ppm
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Rats
Male
1 | 126.6 | 5 | 124.6 | 98.4 | 5 | 128.1 | 101.2 | 5 | 127.3 | 100.6 | 5 | 127.9 | 101.1 | 5 | 124.8 | 98.6 | 5
6 | 148.2 | 5 | 153.0 | 103.2 | 5 | 157.8 | 106.4 | 5 | 155.8 | 105.1 | 5 | 155.8 | 105.1 | 5 | 153.3 | 103.4 | 5
13 | 191.7 | 5 | 191.9 | 100.1 | 5 | 200.2 | 104.4 | 5 | 196.8 | 102.7 | 5 | 193.6 | 101.0 | 5 | 192.3 | 100.3 | 5
EOS | 215.9 | 5 | 216.0 | 100.1 | 5 | 224.9 | 104.2 | 5 | 224.1 | 103.8 | 5 | 217.3 | 100.7 | 5 | 217.7 | 100.8 | 5
Female
1 | 106.5 | 5 | 106.8 | 100.3 | 5 | 108.6 | 101.9 | 5 | 105.7 | 99.2 | 5 | 107.4 | 100.8 | 5 | 107.2 | 100.6 | 5
6 | 119.8 | 5 | 123.6 | 103.1 | 5 | 125.4 | 104.7 | 5 | 121.9 | 101.7 | 5 | 120.3 | 100.4 | 5 | 124.6 | 104.0 | 5
13 | 141.6 | 5 | 137.6 | 97.2 | 5 | 140.1 | 99.0 | 5 | 138.9 | 98.1 | 5 | 135.5 | 95.7 | 5 | 140.1 | 98.9 | 5
EOS | 151.3 | 5 | 148.2 | 97.9 | 5 | 151.1 | 99.9 | 5 | 149.3 | 98.7 | 5 | 144.5 | 95.5 | 5 | 151.4 | 100.1 | 5
Mice
Male
1 | 21.8 | 5 | 22.0 | 100.9 | 5 | 21.6 | 99.1 | 5 | 21.8 | 100.3 | 5 | 21.9 | 100.5 | 5 | 22.0 | 101.2 | 5
6 | 23.0 | 5 | 23.1 | 100.4 | 5 | 23.0 | 100.0 | 5 | 23.1 | 100.4 | 5 | 23.1 | 100.8 | 5 | 23.2 | 101.1 | 5
13 | 24.2 | 5 | 24.6 | 101.6 | 5 | 24.1 | 99.6 | 5 | 24.4 | 100.5 | 5 | 24.6 | 101.4 | 5 | 24.5 | 101.1 | 5
EOS | 25.2 | 5 | 25.6 | 101.6 | 5 | 25.4 | 100.6 | 5 | 25.5 | 101.2 | 5 | 25.4 | 100.7 | 5 | 25.6 | 101.4 | 5
Female
1 | 18.6 | 5 | 19.0 | 102.5 | 5 | 18.8 | 101.4 | 5 | 19.1 | 102.7 | 5 | 19.3 | 103.9 | 5 | 19.4 | 104.3 | 5
6 | 20.0 | 5 | 19.9 | 99.9 | 5 | 20.5 | 102.8 | 5 | 19.8 | 99.1 | 5 | 20.1 | 100.8 | 5 | 20.3 | 101.6 | 5
13 | 21.3 | 5 | 20.5 | 96.6 | 5 | 21.3 | 100.2 | 5 | 20.8 | 97.9 | 5 | 20.6 | 97.0 | 5 | 21.3 | 100.2 | 5
EOS | 22.1 | 5 | 21.7 | 98.0 | 5 | 22.3 | 101.0 | 5 | 21.1 | 95.7 | 5 | 21.5 | 97.4 | 5 | 22.0 | 99.6 | 5

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

### Three-month Study in Rats

All rats survived to the end of the 3-month study (Table 4), and there were no exposure-related clinical observations (Appendix E). Mean body weights of male and female rats exposed to acetoin were slightly lower but were within 7% of those of the respective control groups throughout the study (Table 4; Figure 1).

Table 4 Summary of Survival and Mean Body Weights of Male and Female Rats in the Three-month Inhalation Study of Acetoin

Study Day^a^ | 0 ppm | | 50 ppm | | | 100 ppm | | | 200 ppm | | | 400 ppm | | | 800 ppm
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 135.2 | 10 | 136.0 | 100.6 | 10 | 135.2 | 100.0 | 10 | 133.4 | 98.6 | 10 | 134.4 | 99.4 | 10 | 135.2 | 100.0 | 10
8 | 179.4 | 10 | 180.0 | 100.3 | 10 | 176.4 | 98.3 | 10 | 172.6 | 96.2 | 10 | 176.2 | 98.2 | 10 | 178.8 | 99.6 | 10
17 | 234.6 | 10 | 230.7 | 98.3 | 10 | 227.2 | 96.9 | 10 | 221.0 | 94.2 | 10 | 227.3 | 96.9 | 10 | 228.9 | 97.6 | 10
24 | 269.1 | 10 | 265.0 | 98.5 | 10 | 260.6 | 96.8 | 10 | 253.6 | 94.2 | 10 | 260.9 | 96.9 | 10 | 260.5 | 96.8 | 10
31 | 295.4 | 10 | 289.9 | 98.1 | 10 | 284.7 | 96.4 | 10 | 278.6 | 94.3 | 10 | 284.9 | 96.4 | 10 | 285.3 | 96.6 | 10
38 | 319.2 | 10 | 312.3 | 97.8 | 10 | 306.6 | 96.1 | 10 | 301.6 | 94.5 | 10 | 309.2 | 96.9 | 10 | 307.5 | 96.3 | 10
45 | 337.2 | 10 | 330.3 | 98.0 | 10 | 324.5 | 96.2 | 10 | 320.5 | 95.1 | 10 | 328.5 | 97.4 | 10 | 324.0 | 96.1 | 10
52 | 354.5 | 10 | 346.3 | 97.7 | 10 | 340.7 | 96.1 | 10 | 335.4 | 94.6 | 10 | 342.1 | 96.5 | 10 | 338.3 | 95.4 | 10
59 | 369.8 | 10 | 359.7 | 97.3 | 10 | 354.0 | 95.7 | 10 | 348.9 | 94.4 | 10 | 356.2 | 96.3 | 10 | 349.7 | 94.6 | 10
66 | 381.0 | 10 | 370.1 | 97.1 | 10 | 364.1 | 95.6 | 10 | 359.1 | 94.2 | 10 | 368.9 | 96.8 | 10 | 360.6 | 94.7 | 10
73 | 390.8 | 10 | 380.3 | 97.3 | 10 | 372.0 | 95.2 | 10 | 370.2 | 94.7 | 10 | 380.2 | 97.3 | 10 | 370.2 | 94.7 | 10
80 | 400.6 | 10 | 388.6 | 97.0 | 10 | 380.7 | 95.0 | 10 | 378.6 | 94.5 | 10 | 388.2 | 96.9 | 10 | 377.5 | 94.2 | 10
87 | 410.7 | 10 | 394.8 | 96.1 | 10 | 388.2 | 94.5 | 10 | 387.0 | 94.2 | 10 | 395.3 | 96.3 | 10 | 384.8 | 93.7 | 10
EOS | 415.5 | 10 | 400.9 | 96.5 | 10 | 395.2 | 95.1 | 10 | 391.2 | 94.2 | 10 | 403.2 | 97.0 | 10 | 389.7 | 93.8 | 10
Female
1 | 121.6 | 10 | 119.9 | 98.6 | 10 | 121.3 | 99.8 | 10 | 120.4 | 99.0 | 10 | 121.7 | 100.1 | 10 | 122.2 | 100.5 | 10
8 | 142.9 | 10 | 141.1 | 98.8 | 10 | 142.4 | 99.7 | 10 | 141.4 | 99.0 | 10 | 143.9 | 100.7 | 10 | 142.0 | 99.4 | 10
16 | 163.2 | 10 | 161.8 | 99.2 | 10 | 163.3 | 100.1 | 10 | 162.2 | 99.4 | 10 | 165.2 | 101.2 | 10 | 162.5 | 99.6 | 10
23 | 180.3 | 10 | 177.9 | 98.7 | 10 | 177.2 | 98.3 | 10 | 177.5 | 98.4 | 10 | 182.7 | 101.3 | 10 | 176.8 | 98.1 | 10
30 | 192.2 | 10 | 187.1 | 97.3 | 10 | 187.4 | 97.5 | 10 | 188.7 | 98.2 | 10 | 193.0 | 100.4 | 10 | 185.0 | 96.2 | 10
37 | 202.1 | 10 | 196.1 | 97.0 | 10 | 196.6 | 97.3 | 10 | 198.2 | 98.1 | 10 | 203.4 | 100.6 | 10 | 197.3 | 97.6 | 10
44 | 207.9 | 10 | 206.2 | 99.2 | 10 | 205.9 | 99.0 | 10 | 206.0 | 99.1 | 10 | 211.2 | 101.6 | 10 | 204.1 | 98.2 | 10
51 | 215.5 | 10 | 215.2 | 99.8 | 10 | 212.5 | 98.6 | 10 | 213.4 | 99.0 | 10 | 219.0 | 101.6 | 10 | 211.5 | 98.2 | 10
58 | 222.7 | 10 | 218.9 | 98.3 | 10 | 217.3 | 97.6 | 10 | 219.7 | 98.6 | 10 | 224.2 | 100.6 | 10 | 215.1 | 96.6 | 10
65 | 225.4 | 10 | 223.3 | 99.0 | 10 | 224.0 | 99.4 | 10 | 223.6 | 99.2 | 10 | 228.8 | 101.5 | 10 | 221.2 | 98.1 | 10
72 | 228.3 | 10 | 229.8 | 100.7 | 10 | 229.6 | 100.6 | 10 | 228.8 | 100.2 | 10 | 235.3 | 103.1 | 10 | 226.5 | 99.2 | 10
79 | 231.3 | 10 | 233.7 | 101.0 | 10 | 231.2 | 99.9 | 10 | 231.3 | 100.0 | 10 | 240.2 | 103.8 | 10 | 232.6 | 100.6 | 10
86 | 237.3 | 10 | 236.5 | 99.7 | 10 | 235.7 | 99.3 | 10 | 234.0 | 98.6 | 10 | 244.0 | 102.8 | 10 | 234.0 | 98.6 | 10
EOS | 238.5 | 10 | 239.6 | 100.5 | 10 | 238.3 | 99.9 | 10 | 234.0 | 98.1 | 10 | 244.5 | 102.5 | 10 | 237.1 | 99.4 | 10

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 1

Growth Curves for Male and Female Rats in the Three-month Inhalation Study of Acetoin

Growth curves are shown for (A) males and (B) females.

At necropsy, there were no noteworthy gross lesions observed in male or female rats exposed to acetoin for 3 months (Appendix E). There were no significant differences in relative organ weights at study termination relative to control animals (Appendix E). The only exceptions were a significant increase in relative heart weight of males exposed to 50 ppm and in relative liver weight of males exposed to 800 ppm. Those differences were considered sporadic (heart) with no effect noted at higher concentrations or secondary to marginal differences in body weight (liver) and not toxicologically significant.

On day 23, there was a mild (≤8%) but significant decrease in the hematocrit and hemoglobin concentration in the 100 ppm and higher male rats (Appendix E). This change, which ameliorated by day 93, indicated a transient mild suppression in erythropoiesis. In addition, on day 23, neutrophil counts were significantly decreased in most male exposed groups but were unchanged compared to those of the control group by day 93 (Appendix E). On day 93, the white blood cell and lymphocyte counts were significantly decreased (19%–30%) in male rats exposed to 200 ppm and higher, and the monocyte count was decreased (≤29%) in the 400 and 800 ppm male groups (Appendix E). The day 93 leukocyte changes were most consistent with a stress leukogram (i.e., effects of a chronic increase in endogenous glucocorticoids).^91^ All other statistically significant hematology changes were mild, inconsistent, and/or considered due to biological variability and, thus, not considered related to acetoin exposure.

On day 4, urea nitrogen (BUN) was significantly decreased (25%) in the 800 ppm male rats, and creatinine concentration was significantly increased in the 800 ppm male (194%) and female (55%) rats (Appendix E). The BUN remained mildly decreased in all male rats at day 23 with a significant increase in creatinine (47%) observed in the 800 ppm male rats. By day 93, the creatinine changes ameliorated, whereas the BUN was minimally increased (15%) in 800 ppm male rats. The combination of these changes most likely represented a physiological response related to decreased feed or water consumption as the animals adjusted to exposure. All other statistically significant changes were minimal, inconsistent, and/or not considered biologically relevant and, thus, not considered due to acetoin exposure.

#### Histopathology

There were no significant differences in exposure-related microscopic lesion incidences in male or female rats relative to control animals. A few microscopic lesions were observed in the heart, kidney, larynx, lymph nodes, lung, liver, pancreas, and preputial gland. Severity ranged from minimal to marked, and the lesions were present in both control and exposed animals. The microscopic lesions, therefore, were considered incidental findings and not related to exposure to acetoin (Appendix E).

### Three-month Study in Mice

All mice survived to scheduled termination (Table 5). Mean body weights of male and female mice exposed to acetoin were within 8% of those of the respective control groups throughout the study (Table 5; Figure 2).

Table 5 Summary of Survival and Mean Body Weights of Male and Female Mice in the Three-month Inhalation Study of Acetoin

Study Day^a^ | 0 ppm | | 50 ppm | | | 100 ppm | | | 200 ppm | | | 400 ppm | | | 800 ppm
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 23.6 | 10 | 23.7 | 100.5 | 10 | 23.7 | 100.5 | 10 | 23.7 | 100.5 | 10 | 23.3 | 98.7 | 10 | 23.5 | 99.7 | 10
8 | 25.4 | 10 | 25.5 | 100.3 | 10 | 25.0 | 98.2 | 10 | 25.3 | 99.6 | 10 | 24.6 | 96.9 | 10 | 24.9 | 98.2 | 10
17 | 27.1 | 10 | 26.9 | 99.5 | 10 | 26.6 | 98.3 | 10 | 26.8 | 99.1 | 10 | 26.6 | 98.0 | 10 | 27.0 | 99.6 | 10
24 | 28.2 | 10 | 27.9 | 98.8 | 10 | 27.5 | 97.5 | 10 | 27.9 | 98.9 | 10 | 27.2 | 96.5 | 10 | 28.0 | 99.1 | 10
31 | 28.7 | 10 | 28.7 | 100.0 | 10 | 28.3 | 98.6 | 10 | 28.7 | 99.9 | 10 | 28.2 | 98.3 | 10 | 28.8 | 100.2 | 10
38 | 30.1 | 10 | 29.8 | 98.8 | 10 | 29.1 | 96.7 | 10 | 29.6 | 98.4 | 10 | 29.1 | 96.5 | 10 | 29.8 | 99.0 | 10
45 | 31.1 | 10 | 30.3 | 97.5 | 10 | 30.2 | 97.1 | 10 | 30.4 | 97.7 | 10 | 29.9 | 96.3 | 10 | 30.5 | 98.3 | 10
52 | 31.9 | 10 | 31.4 | 98.5 | 10 | 30.9 | 96.9 | 10 | 31.3 | 98.3 | 10 | 30.5 | 95.7 | 10 | 31.6 | 99.1 | 10
59 | 32.8 | 10 | 32.0 | 97.5 | 10 | 31.8 | 97.0 | 10 | 32.3 | 98.4 | 10 | 31.6 | 96.4 | 10 | 32.6 | 99.6 | 10
66 | 33.9 | 10 | 33.1 | 97.6 | 10 | 32.5 | 96.0 | 10 | 32.8 | 96.9 | 10 | 32.4 | 95.6 | 10 | 33.6 | 99.2 | 10
73 | 34.8 | 10 | 34.1 | 97.9 | 10 | 33.3 | 95.5 | 10 | 33.3 | 95.5 | 10 | 33.7 | 96.9 | 10 | 34.4 | 98.7 | 10
80 | 35.6 | 10 | 35.1 | 98.6 | 10 | 33.9 | 95.3 | 10 | 34.6 | 97.1 | 10 | 34.4 | 96.5 | 10 | 35.5 | 99.7 | 10
87 | 36.7 | 10 | 36.0 | 98.3 | 10 | 34.8 | 94.8 | 10 | 35.7 | 97.3 | 10 | 35.2 | 96.0 | 10 | 36.4 | 99.2 | 10
EOS | 37.4 | 10 | 36.9 | 98.6 | 10 | 35.6 | 95.3 | 10 | 36.6 | 97.8 | 10 | 35.9 | 95.9 | 10 | 37.5 | 100.3 | 10
Female
1 | 20.1 | 10 | 19.9 | 99.1 | 10 | 19.8 | 98.4 | 10 | 19.7 | 98.1 | 10 | 19.6 | 97.8 | 10 | 19.5 | 97.2 | 10
8 | 21.7 | 10 | 21.9 | 100.9 | 10 | 20.8 | 95.9 | 10 | 21.1 | 97.5 | 10 | 21.3 | 98.5 | 10 | 21.2 | 97.7 | 10
17 | 22.6 | 10 | 22.4 | 99.1 | 10 | 22.3 | 98.6 | 10 | 22.7 | 100.2 | 10 | 22.6 | 100.0 | 10 | 22.6 | 99.8 | 10
24 | 23.6 | 10 | 23.4 | 99.0 | 10 | 23.5 | 99.3 | 10 | 23.6 | 99.7 | 10 | 23.9 | 101.3 | 10 | 23.9 | 101.2 | 10
31 | 24.6 | 10 | 24.0 | 97.6 | 10 | 24.2 | 98.3 | 10 | 25.1 | 102.0 | 10 | 24.7 | 100.4 | 10 | 25.0 | 101.6 | 10
38 | 25.3 | 10 | 24.8 | 98.0 | 10 | 24.9 | 98.4 | 10 | 26.0 | 102.8 | 10 | 25.6 | 101.1 | 10 | 25.5 | 100.8 | 10
45 | 26.1 | 10 | 25.2 | 96.7 | 10 | 25.8 | 99.0 | 10 | 26.7 | 102.5 | 10 | 26.4 | 101.2 | 10 | 26.1 | 100.0 | 10
52 | 26.4 | 10 | 26.2 | 99.1 | 10 | 26.3 | 99.4 | 10 | 27.1 | 102.5 | 10 | 27.3 | 103.3 | 10 | 27.9 | 105.6 | 10
59 | 28.0 | 10 | 26.4 | 94.0 | 10 | 27.5 | 98.1 | 10 | 28.3 | 100.9 | 10 | 28.3 | 100.8 | 10 | 28.1 | 100.4 | 10
66 | 28.6 | 10 | 27.1 | 94.5 | 10 | 28.0 | 97.6 | 10 | 29.2 | 102.0 | 10 | 29.1 | 101.6 | 10 | 29.1 | 101.6 | 10
73 | 29.7 | 10 | 27.7 | 93.1 | 10 | 28.5 | 96.0 | 10 | 29.6 | 99.7 | 10 | 30.0 | 100.8 | 10 | 29.2 | 98.2 | 10
80 | 30.2 | 10 | 28.6 | 94.6 | 10 | 29.2 | 96.7 | 10 | 30.8 | 101.8 | 10 | 30.5 | 101.0 | 10 | 30.7 | 101.7 | 10
87 | 31.5 | 10 | 29.8 | 94.5 | 10 | 30.2 | 95.7 | 10 | 30.7 | 97.5 | 10 | 31.9 | 101.1 | 10 | 31.7 | 100.5 | 10
EOS | 32.9 | 10 | 30.4 | 92.4 | 10 | 31.8 | 96.5 | 10 | 33.0 | 100.2 | 10 | 32.4 | 98.5 | 10 | 32.7 | 99.2 | 10

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 2

Growth Curves for Male and Female Mice in the Three-month Inhalation Study of Acetoin

Growth curves are shown for (A) males and (B) females.

There were no clinical observations or gross lesions associated with exposure to acetoin up to 800 ppm (Appendix E). There were no significant exposure concentration-response alterations associated with absolute or relative organ weights at study termination (Appendix E). The only exceptions were significant increases in relative kidney weight and relative lung weight of males exposed to 100 ppm, but these likely have no toxicological relevance because differences were not noted at higher exposure concentrations or at any exposure concentration for female mice.

There were no exposure-related changes in the hematology of the mice exposed to acetoin (Appendix E).

#### Histopathology

There were no significant exposure-related microscopic alterations in any of the tissues evaluated from mice (Appendix E).

## 2,3-Pentanedione

### Three-month Study in Rats

All rats exposed to 2,3-pentanedione for 3 months survived to study termination (Table 6). Exposure-related clinical observations in the 50 and 100 ppm groups of both sexes included abnormal breathing, eye abnormality, and sneezing (Table 7). The mean body weight of males exposed to 100 ppm was lower (up to 8% lower) than that of the control group beginning on day 8 (Table 6; Figure 3). Although terminal mean body weights were not significantly different from the control group, the mean body weight of the 100 ppm group remained lower (within 8%) than that of the control group for the duration of the study (Appendix E).

Table 6 Summary of Survival and Mean Body Weights of Male and Female Rats in the Three-month Inhalation Study of 2,3-Pentanedione

Study Day^a^ | 0 ppm | | 6.25 ppm | | | 12.5 ppm | | | 25 ppm | | | 50 ppm | | | 100 ppm
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 139.5 | 10 | 140.1 | 100.5 | 10 | 139.7 | 100.2 | 10 | 138.6 | 99.4 | 10 | 138.6 | 99.4 | 10 | 138.8 | 99.5 | 10
8 | 181.2 | 10 | 181.0 | 99.9 | 10 | 180.4 | 99.6 | 10 | 179.7 | 99.2 | 10 | 179.5 | 99.1 | 10 | 171.9 | 94.8
19 | 241.1 | 10 | 240.7 | 99.8 | 10 | 239.5 | 99.3 | 10 | 243.6 | 101.1 | 10 | 235.9 | 97.8 | 10 | 222.7 | 92.4
26 | 268.5 | 10 | 266.0 | 99.0 | 10 | 268.7 | 100.1 | 10 | 272.5 | 101.5 | 10 | 258.2 | 96.2 | 10 | 250.6 | 93.3 | 10
33 | 292.7 | 10 | 289.4 | 98.8 | 10 | 292.6 | 100.0 | 10 | 298.2 | 101.9 | 10 | 281.2 | 96.1 | 10 | 276.1 | 94.3 | 10
40 | 311.5 | 10 | 305.2 | 98.0 | 10 | 312.4 | 100.3 | 10 | 315.4 | 101.3 | 10 | 301.7 | 96.8 | 10 | 292.0 | 93.7 | 10
47 | 329.1 | 10 | 326.8 | 99.3 | 10 | 328.5 | 99.8 | 10 | 331.7 | 100.8 | 10 | 316.8 | 96.3 | 10 | 310.4 | 94.3 | 10
54 | 341.9 | 10 | 339.1 | 99.2 | 10 | 341.5 | 99.9 | 10 | 344.8 | 100.8 | 10 | 330.6 | 96.7 | 10 | 320.7 | 93.8 | 10
61 | 352.4 | 10 | 348.6 | 98.9 | 10 | 351.8 | 99.8 | 10 | 356.8 | 101.2 | 10 | 338.9 | 96.1 | 10 | 328.1 | 93.1 | 10
68 | 358.4 | 10 | 356.9 | 99.6 | 10 | 358.6 | 100.1 | 10 | 367.0 | 102.4 | 10 | 347.7 | 97.0 | 10 | 335.1 | 93.5 | 10
75 | 367.4 | 10 | 365.2 | 99.4 | 10 | 367.7 | 100.1 | 10 | 376.6 | 102.5 | 10 | 356.4 | 97.0 | 10 | 344.7 | 93.8 | 10
82 | 373.6 | 10 | 372.9 | 99.8 | 10 | 376.4 | 100.8 | 10 | 385.2 | 103.1 | 10 | 366.5 | 98.1 | 10 | 353.5 | 94.6 | 10
89 | 381.5 | 10 | 380.9 | 99.9 | 10 | 384.0 | 100.7 | 10 | 392.7 | 103.0 | 10 | 375.8 | 98.5 | 10 | 360.7 | 94.6 | 10
EOS | 383.8 | 10 | 383.2 | 99.8 | 10 | 386.5 | 100.7 | 10 | 396.1 | 103.2 | 10 | 378.6 | 98.6 | 10 | 363.7 | 94.8 | 10
Female
8 | 141.1 | 10 | 143.0 | 101.4 | 10 | 145.7 | 103.3 | 10 | 146.6 | 103.9 | 10 | 144.3 | 102.2 | 10 | 144.6 | 102.5 | 10
18 | 165.5 | 10 | 166.0 | 100.3 | 10 | 171.1 | 103.4 | 10 | 168.0 | 101.6 | 10 | 163.6 | 98.9 | 10 | 165.9 | 100.3 | 10
25 | 178.2 | 10 | 175.1 | 98.2 | 10 | 181.5 | 101.8 | 10 | 181.0 | 101.6 | 10 | 175.2 | 98.3 | 10 | 176.5 | 99.0 | 10
32 | 185.8 | 10 | 186.2 | 100.2 | 10 | 194.1 | 104.5 | 10 | 193.1 | 103.9 | 10 | 185.6 | 99.9 | 10 | 185.8 | 100.0 | 10
39 | 196.9 | 10 | 194.4 | 98.7 | 10 | 203.4 | 103.3 | 10 | 200.9 | 102.1 | 10 | 193.9 | 98.5 | 10 | 190.9 | 97.0 | 10
46 | 202.1 | 10 | 201.0 | 99.4 | 10 | 211.2 | 104.5 | 10 | 206.4 | 102.1 | 10 | 200.5 | 99.2 | 10 | 200.1 | 99.0 | 10
53 | 209.7 | 10 | 206.0 | 98.2 | 10 | 214.8 | 102.4 | 10 | 214.0 | 102.0 | 10 | 206.0 | 98.2 | 10 | 205.6 | 98.0 | 10
60 | 214.1 | 10 | 211.6 | 98.8 | 10 | 220.6 | 103.0 | 10 | 220.0 | 102.8 | 10 | 209.1 | 97.7 | 10 | 209.3 | 97.8 | 10
67 | 219.3 | 10 | 216.9 | 98.9 | 10 | 224.6 | 102.4 | 10 | 225.3 | 102.8 | 10 | 214.1 | 97.6 | 10 | 211.4 | 96.4 | 10
74 | 223.4 | 10 | 219.4 | 98.2 | 10 | 228.5 | 102.3 | 10 | 225.9 | 101.1 | 10 | 215.2 | 96.3 | 10 | 214.0 | 95.8 | 10
81 | 226.6 | 10 | 222.0 | 98.0 | 10 | 229.1 | 101.1 | 10 | 229.3 | 101.2 | 10 | 219.4 | 96.8 | 10 | 218.2 | 96.3 | 10
88 | 228.0 | 10 | 225.6 | 98.9 | 10 | 234.7 | 102.9 | 10 | 234.0 | 102.6 | 10 | 224.1 | 98.3 | 10 | 222.6 | 97.6 | 10
EOS | 227.7 | 10 | 225.5 | 99.0 | 10 | 234.9 | 103.2 | 10 | 235.1 | 103.2 | 10 | 224.6 | 98.6 | 10 | 223.7 | 98.2 | 10

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed in study.

Table 7 Summary of Clinical Observations for Male and Female Rats in the Three-month Inhalation Study of 2,3-Pentanedione

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male^a^
Abnormal Breathing | 0/10 | 0/10 | 0/10 | 0/10 | 2/10 SD 19 | 4/10 SD 40
Eye Abnormality | 0/10 | 0/10 | 0/10 | 0/10 | 4/10 SD 61 | 7/10 SD 61
Sneezing | 0/10 | 0/10 | 0/10 | 0/10 | 9/10 SD 26 | 10/10 SD 26
Female
Abnormal Breathing | 0/10 | 0/10 | 0/10 | 0/10 | 2/10 SD 67 | 3/10 SD 46
Eye Abnormality | 0/10 | 0/10 | 0/10 | 0/10 | 5/10 SD 60 | 9/10 SD 46
Sneezing | 0/10 | 0/10 | 0/10 | 0/10 | 7/10 SD 32 | 10/10 SD 25

No trend or pairwise statistical tests were performed on these data.

SD = study day.

^a^ Upper row displays cumulative number of animals with observation/total animals started on study. Lower row displays SD of observation onset.

Figure 3

Growth Curves for Male and Female Rats in the Three-month Inhalation Study of 2,3-Pentanedione

Growth curves are shown for (A) males and (B) females.

Absolute and relative lung weights and relative heart weight were significantly increased in the 100 ppm females compared to those of the control group (Table 8). Grossly, some male and female rats in the 50 and 100 ppm groups had unilateral or bilateral corneal opacities, and two female rats exposed to 100 ppm had one or more 1- to 3-mm pale lung foci (Appendix E).

Table 8 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Female Rats in the Three-month Inhalation Study of 2,3-Pentanedione^a,b^

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Terminal Body Wt. (g) | 227.7 ± 3.4 | 225.5 ± 6.1 | 234.9 ± 3.3 | 235.1 ± 4.5 | 224.6 ± 4.6 | 223.7 ± 4.1
Lung
Absolute (g) | 1.33 ± 0.04** | 1.37 ± 0.06 | 1.45 ± 0.06 | 1.39 ± 0.04 | 1.41 ± 0.06 | 1.65 ± 0.08**
Relative (mg/g)^c^ | 5.85 ± 0.14** | 6.09 ± 0.21 | 6.16 ± 0.26 | 5.93 ± 0.15 | 6.26 ± 0.22 | 7.39 ± 0.40**
Heart
Absolute (g) | 0.68 ± 0.01 | 0.71 ± 0.02 | 0.71 ± 0.01 | 0.71 ± 0.02 | 0.70 ± 0.02 | 0.72 ± 0.02
Relative (mg/g) | 2.97 ± 0.06* | 3.14 ± 0.05 | 3.00 ± 0.03 | 3.03 ± 0.07 | 3.12 ± 0.06 | 3.22 ± 0.05*

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

On day 23, white blood cell and monocyte counts were significantly increased in the 50 and 100 ppm female groups, and lymphocyte counts were significantly increased in groups of females exposed to ≥12.5 ppm; neutrophil counts were significantly increased in the 100 ppm group of both male and female rats (Table 9). At study termination, neutrophil counts were significantly increased in the 50 and 100 ppm male and female rats. Additionally, in females, the monocyte count was significantly increased in the 100 ppm group, whereas in males, the lymphocyte count was significantly decreased in the 100 ppm group. These changes were consistent with an exposure-related proinflammatory response. In addition, the decrease in lymphocyte count in male rats indicated a possible stress response to exposure (i.e., effects of a chronic increase in endogenous glucocorticoids).^91^ All other statistically significant hematology changes were mild, inconsistent, and/or considered due to biological variability and, thus, not considered related to 2,3-pentanedione exposure.

Table 9 Summary of Select Hematology Data for Male and Female Rats in the Three-month Inhalation Study of 2,3-Pentanedione^a,b^

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n | 10 | 10 | 10^c^ | 10 | 10^d^ | 10
Male (10^3^/µL)
White Blood Cells
Day 3 | 10.86 ± 0.77 | 10.38 ± 0.92 | 9.24 ± 0.60 | 10.07 ± 0.61 | 8.43 ± 0.32* | 9.40 ± 0.84
Day 23 | 10.00 ± 0.51 | 9.18 ± 0.65 | 8.90 ± 0.27 | 9.09 ± 0.39 | 9.76 ± 0.45 | 9.78 ± 0.94
Day 93 | 8.82 ± 0.69 | 8.50 ± 0.58 | 7.85 ± 0.56 | 7.66 ± 0.68 | 8.88 ± 0.83 | 7.36 ± 0.41
Lymphocytes
Day 3 | 9.30 ± 0.72 | 8.92 ± 0.85 | 7.85 ± 0.49 | 8.58 ± 0.61 | 7.39 ± 0.31 | 7.94 ± 0.80
Day 23 | 8.81 ± 0.49 | 8.00 ± 0.70 | 7.83 ± 0.26 | 7.88 ± 0.40 | 8.07 ± 0.31 | 7.29 ± 0.76
Day 93 | 7.31 ± 0.62** | 6.90 ± 0.54 | 6.50 ± 0.51 | 6.33 ± 0.61 | 6.61 ± 0.56 | 5.04 ± 0.28**
Monocytes
Day 3 | 0.33 ± 0.03 | 0.30 ± 0.03 | 0.34 ± 0.05 | 0.31 ± 0.03 | 0.25 ± 0.02 | 0.27 ± 0.03
Day 23 | 0.24 ± 0.01 | 0.19 ± 0.02 | 0.22 ± 0.01 | 0.22 ± 0.02 | 0.28 ± 0.03 | 0.28 ± 0.03
Day 93 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.13 ± 0.01 | 0.15 ± 0.02 | 0.21 ± 0.03 | 0.13 ± 0.01
Neutrophils
Day 3 | 1.11 ± 0.12 | 1.06 ± 0.10 | 0.95 ± 0.12 | 1.08 ± 0.15 | 0.71 ± 0.05* | 1.09 ± 0.12
Day 23 | 0.85 ± 0.06** | 0.90 ± 0.12 | 0.75 ± 0.09 | 0.89 ± 0.09 | 1.31 ± 0.17 | 2.06 ± 0.64**
Day 93 | 1.25 ± 0.07** | 1.31 ± 0.11 | 1.12 ± 0.06 | 1.09 ± 0.10 | 1.95 ± 0.28* | 2.08 ± 0.31*
Female (10^3^/µL)
White Blood Cells
Day 3 | 6.65 ± 0.17 | 6.91 ± 0.44 | 7.91 ± 0.31 | 6.88 ± 0.55 | 8.12 ± 0.68 | 7.03 ± 0.32
Day 23 | 5.69 ± 0.32** | 6.91 ± 0.59 | 7.30 ± 0.41 | 6.09 ± 0.24 | 8.59 ± 0.50** | 9.02 ± 0.64**
Day 93 | 6.14 ± 0.60 | 6.76 ± 0.63 | 7.26 ± 0.45 | 5.70 ± 0.37 | 6.74 ± 0.84 | 6.77 ± 0.49
Lymphocytes
Day 3 | 5.64 ± 0.19 | 5.99 ± 0.37 | 6.85 ± 0.25* | 5.90 ± 0.50 | 6.99 ± 0.64 | 6.11 ± 0.26
Day 23 | 4.74 ± 0.24** | 5.95 ± 0.54 | 6.53 ± 0.39** | 5.25 ± 0.24* | 6.97 ± 0.41** | 6.85 ± 0.51**
Day 93 | 4.94 ± 0.55* | 5.40 ± 0.57 | 5.83 ± 0.42 | 4.42 ± 0.34 | 4.67 ± 0.70 | 4.02 ± 0.31
Monocytes
Day 3 | 0.21 ± 0.02 | 0.19 ± 0.02 | 0.24 ± 0.03 | 0.21 ± 0.03 | 0.24 ± 0.03 | 0.20 ± 0.03
Day 23 | 0.14 ± 0.01** | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.15 ± 0.01 | 0.22 ± 0.03** | 0.25 ± 0.04**
Day 93 | 0.12 ± 0.01* | 0.13 ± 0.02 | 0.13 ± 0.01 | 0.10 ± 0.01 | 0.15 ± 0.02 | 0.20 ± 0.03*
Neutrophils
Day 3 | 0.68 ± 0.05 | 0.62 ± 0.06 | 0.70 ± 0.08 | 0.66 ± 0.08 | 0.74 ± 0.04 | 0.62 ± 0.07
Day 23 | 0.70 ± 0.07** | 0.67 ± 0.05 | 0.51 ± 0.03 | 0.63 ± 0.05 | 1.29 ± 0.34 | 1.79 ± 0.27*
Day 93 | 1.00 ± 0.08** | 1.12 ± 0.07 | 1.20 ± 0.05 | 1.09 ± 0.12 | 1.83 ± 0.21** | 2.42 ± 0.20**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ For the day 3 data, n = 9 for the male 12.5 ppm group.

^d^ For the day 23 data, n = 9 for the female 50 ppm group.

On day 3, triglyceride concentrations were significantly decreased in the 25 and 50 ppm female rats; these changes were most likely due to changes in feed consumption while acclimating to exposure (Appendix E). At study termination, globulin concentration was significantly increased, and albumin concentration was significantly decreased in the 100 ppm female rats in the absence of significant changes in total protein (Table 10). In addition, the A/G ratio was significantly decreased in male rats exposed to 50 and 100 ppm and in female rats exposed to 100 ppm. These changes are consistent with the exposure-related inflammation in the respiratory tract because globulin is a positive acute phase protein and albumin a negative acute phase protein. All other statistically significant changes were minimal, inconsistent, and/or not considered biologically relevant and, thus, not considered due to 2,3-pentanedione exposure.

Table 10 Summary of Select Clinical Chemistry Data for Male and Female Rats in the Three-month Inhalation Study of 2,3-Pentanedione^a,b^

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n | 10 | 10 | 10 | 10 | 10^c^ | 10
Male
Total Protein (g/dL)
Day 3 | 5.94 ± 0.09 | 5.83 ± 0.07 | 5.84 ± 0.04 | 5.70 ± 0.06 | 5.78 ± 0.07 | 5.83 ± 0.07
Day 23 | 6.39 ± 0.07 | 6.45 ± 0.06 | 6.33 ± 0.09 | 6.36 ± 0.05 | 6.38 ± 0.09 | 6.42 ± 0.08
Day 93 | 6.77 ± 0.07 | 7.05 ± 0.09 | 6.83 ± 0.09 | 6.96 ± 0.13 | 6.96 ± 0.10 | 6.84 ± 0.06
Albumin (g/dL)
Day 3 | 4.29 ± 0.05* | 4.23 ± 0.05 | 4.18 ± 0.04 | 4.15 ± 0.07 | 4.13 ± 0.05 | 4.19 ± 0.05
Day 23 | 4.37 ± 0.05 | 4.41 ± 0.05 | 4.28 ± 0.04 | 4.38 ± 0.04 | 4.27 ± 0.05 | 4.32 ± 0.05
Day 93 | 4.50 ± 0.04 | 4.57 ± 0.07 | 4.53 ± 0.06 | 4.55 ± 0.07 | 4.47 ± 0.06 | 4.40 ± 0.05
Globulin (g/dL)
Day 3 | 1.65 ± 0.07 | 1.60 ± 0.05 | 1.66 ± 0.05 | 1.55 ± 0.05 | 1.65 ± 0.03 | 1.64 ± 0.03
Day 23 | 2.02 ± 0.06 | 2.04 ± 0.05 | 2.05 ± 0.07 | 1.98 ± 0.06 | 2.11 ± 0.08 | 2.10 ± 0.06
Day 93 | 2.27 ± 0.07 | 2.48 ± 0.07 | 2.30 ± 0.04 | 2.41 ± 0.10 | 2.49 ± 0.08 | 2.44 ± 0.04
A/G Ratio
Day 3 | 2.63 ± 0.09 | 2.66 ± 0.08 | 2.55 ± 0.11 | 2.71 ± 0.12 | 2.51 ± 0.04 | 2.56 ± 0.04
Day 23 | 2.18 ± 0.06 | 2.17 ± 0.06 | 2.11 ± 0.07 | 2.23 ± 0.08 | 2.05 ± 0.08 | 2.07 ± 0.06
Day 93 | 2.00 ± 0.06** | 1.85 ± 0.06 | 1.97 ± 0.04 | 1.92 ± 0.09 | 1.81 ± 0.07* | 1.81 ± 0.04*
Female
Total Protein (g/dL)
Day 3 | 6.24 ± 0.11 | 6.16 ± 0.08 | 6.24 ± 0.12 | 6.07 ± 0.09 | 6.05 ± 0.07 | 6.08 ± 0.07
Day 23 | 6.68 ± 0.10 | 6.62 ± 0.11 | 6.68 ± 0.14 | 6.53 ± 0.06 | 6.66 ± 0.12 | 6.64 ± 0.13
Day 93 | 7.26 ± 0.14 | 7.29 ± 0.13 | 7.24 ± 0.10 | 7.41 ± 0.11 | 7.40 ± 0.08 | 7.24 ± 0.11
Albumin (g/dL)
Day 3 | 4.60 ± 0.06 | 4.57 ± 0.06 | 4.61 ± 0.07 | 4.50 ± 0.07 | 4.55 ± 0.05 | 4.53 ± 0.07
Day 23 | 4.78 ± 0.05 | 4.79 ± 0.07 | 4.82 ± 0.08 | 4.75 ± 0.06 | 4.77 ± 0.10 | 4.60 ± 0.10
Day 93 | 5.36 ± 0.09 | 5.40 ± 0.19 | 5.27 ± 0.06 | 5.51 ± 0.18 | 5.38 ± 0.08 | 5.03 ± 0.05*
Globulin (g/dL)
Day 3 | 1.64 ± 0.05 | 1.59 ± 0.04 | 1.63 ± 0.07 | 1.57 ± 0.05 | 1.50 ± 0.04 | 1.55 ± 0.03
Day 23 | 1.90 ± 0.05 | 1.83 ± 0.05 | 1.86 ± 0.06 | 1.78 ± 0.03 | 1.89 ± 0.06 | 2.04 ± 0.06
Day 93 | 1.90 ± 0.06** | 1.89 ± 0.10 | 1.97 ± 0.05 | 1.90 ± 0.09 | 2.02 ± 0.03 | 2.21 ± 0.09**
A/G Ratio
Day 3 | 2.82 ± 0.06 | 2.89 ± 0.06 | 2.87 ± 0.13 | 2.89 ± 0.09 | 3.05 ± 0.07 | 2.93 ± 0.07
Day 23 | 2.53 ± 0.05* | 2.63 ± 0.07 | 2.61 ± 0.06 | 2.68 ± 0.06 | 2.54 ± 0.09 | 2.27 ± 0.07
Day 93 | 2.84 ± 0.08** | 3.02 ± 0.38 | 2.69 ± 0.06 | 3.03 ± 0.32 | 2.67 ± 0.07 | 2.30 ± 0.08**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

A/G = albumin/globulin.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ For the day 23 data, n = 9 for the female 50 ppm group.

#### Histopathology

This section describes statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions in the respiratory tract (nose, larynx, trachea, lung) and the eyes of rats (Appendix E).

Nose: The exposure-related lesions observed in the nose were similar in males and females, and the incidences and average severities of these lesions tended to increase with increasing exposure concentration. The exposure-related lesions observed in both sexes were olfactory epithelial atrophy, olfactory epithelial degeneration, olfactory epithelial respiratory metaplasia, respiratory epithelial hyperplasia, respiratory epithelial squamous metaplasia, respiratory epithelial necrosis, respiratory epithelial regeneration, lymphoid hyperplasia (by positive trend only in females), suppurative inflammation, and turbinate atrophy (Table 11). Most of these lesions were seen in the 50 and/or 100 ppm groups, but a few were seen in groups exposed to lower concentrations. Significant increases in incidence were seen for these lesions in the 50 and/or 100 ppm groups compared to their respective control groups. In males, a significant increase in the incidence of respiratory epithelial hyperplasia was seen at exposure concentrations ≥25 ppm relative to control animals. Increased incidences of necrosis and regeneration of the respiratory epithelium, as well as turbinate atrophy, were seen in the 100 ppm male and female groups relative to control animals. In males, a significantly increased incidence of olfactory epithelial degeneration was seen in the 50 ppm group relative to the control group; the incidence in the 100 ppm group was lower than it was in the 50 ppm group and not statistically significant. This observation is presumably because the lesion progressed beyond degeneration in most of the animals in this group to necrosis, atrophy, or metaplasia—all of which are considered representative of a more severe manifestation of epithelial damage. Olfactory epithelial squamous metaplasia was seen in two males in the 100 ppm group, and respiratory epithelial ulceration was seen in one female exposed to 100 ppm. These increases did not reach statistical significance (except for the olfactory epithelial squamous metaplasia with a positive trend) but are considered related to exposure because they are consistent with the spectrum of 2,3-pentanedione-induced epithelial lesions observed in the nasal cavity.

Table 11 Incidences of Select Nonneoplastic Lesions of the Respiratory Tract in Male and Female Rats in the Three-month Inhalation Study of 2,3-Pentanedione

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n^a^ | 10 | 10 | 10 | 10 | 10 | 10
Male
Nose
Hyperplasia, lymphoid^b^ | 0** | 1 (1.0)^c^ | 1 (1.0) | 1 (1.0) | 7** (1.1) | 5* (1.6)
Inflammation, suppurative | 0** | 0 | 0 | 2 (1.0) | 10** (2.3) | 10** (3.0)
Olfactory epithelium, atrophy | 1** (1.0) | 1 (1.0) | 0 | 4 (1.0) | 10** (1.0) | 10** (1.0)
Olfactory epithelium, degeneration | 2* (1.0) | 0 | 0 | 2 (1.0) | 10** (1.4) | 3 (1.7)
Olfactory epithelium, metaplasia, respiratory | 2** (1.0) | 0 | 2 (1.0) | 1 (1.0) | 8* (1.0) | 10** (1.0)
Olfactory epithelium, metaplasia, squamous | 0** | 0 | 0 | 0 | 0 | 2 (1.0)
Respiratory epithelium, hyperplasia | 0** | 1 (1.0) | 2 (1.0) | 9** (1.0) | 10** (2.1) | 10** (2.9)
Respiratory epithelium, metaplasia, squamous | 0** | 0 | 1 (1.0) | 0 | 10** (1.1) | 10** (2.0)
Respiratory epithelium, necrosis | 0** | 0 | 0 | 0 | 2 (1.0) | 10** (2.1)
Respiratory epithelium, regeneration | 0** | 0 | 0 | 0 | 0 | 10** (1.5)
Turbinate, atrophy | 0** | 0 | 0 | 0 | 2 (1.5) | 10** (2.0)
Larynx
Inflammation, suppurative | 0 | 0 | 0 | 0 | 2 (1.0) | 0
Inflammation, chronic active | 1** (1.0) | 0 | 0 | 0 | 0 | 4 (1.0)
Respiratory epithelium, hyperplasia | 0** | 1 (1.0) | 0 | 1 (1.0) | 7** (1.0) | 3 (1.7)
Respiratory epithelium, metaplasia, squamous | 1** (1.0) | 1 (1.0) | 1 (1.0) | 5 (1.0) | 10** (1.7) | 10** (3.0)
Respiratory epithelium, necrosis | 0** | 0 | 0 | 0 | 0 | 2 (1.0)
Respiratory epithelium, regeneration | 0* | 0 | 0 | 0 | 1 (1.0) | 2 (1.0)
Respiratory epithelium, ulcer | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Squamous epithelium, hyperplasia | 0** | 0 | 0 | 0 | 0 | 7** (1.1)
Trachea
Inflammation, acute | 0** | 0 | 0 | 1 (1.0) | 0 | 3 (1.0)
Epithelium, hyperplasia | 0** | 0 | 0 | 0 | 0 | 8** (2.5)
Epithelium, metaplasia, squamous | 0** | 0 | 0 | 0 | 0 | 3 (1.7)
Epithelium, necrosis | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Epithelium, regeneration | 0** | 1 (1.0) | 1 (1.0) | 0 | 8** (1.4) | 10** (2.8)
Lung
Fibrosis, focal | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Inflammation, eosinophil | 3** (1.0) | 3 (1.0) | 1 (1.0) | 5 (1.0) | 3 (1.0) | 10** (2.0)
Alveolus, infiltration, cellular, polymorphonuclear | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Bronchiole, epithelium, hyperplasia | 0** | 0 | 0 | 0 | 3 (1.0) | 10** (2.2)
Bronchus, epithelium, hyperplasia | 0** | 0 | 0 | 0 | 0 | 5* (1.6)
Bronchus, epithelium, regeneration | 0** | 0 | 0 | 0 | 1 (1.0) | 9** (2.8)
Bronchus, epithelium, metaplasia, squamous | 0** | 0 | 0 | 0 | 0 | 3 (1.3)
Bronchus, epithelium, metaplasia, goblet cell | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Female
Nose
Hyperplasia, lymphoid | 0** | 0 | 0 | 1 (1.0) | 0 | 3 (1.0)
Inflammation, suppurative | 0** | 0 | 0 | 0 | 10** (1.9) | 10** (3.0)
Olfactory epithelium, atrophy | 1** (1.0) | 0 | 1 (1.0) | 1 (1.0) | 10** (1.0) | 9** (1.0)
Olfactory epithelium, degeneration | 0** | 1 (1.0) | 0 | 0 | 4* (1.3) | 5* (1.6)
Olfactory epithelium, metaplasia, respiratory | 0** | 0 | 1 (1.0) | 1 (1.0) | 8** (1.0) | 9** (1.2)
Respiratory epithelium, hyperplasia | 1** (1.0) | 0 | 0 | 3 (1.0) | 10** (2.0) | 10** (3.0)
Respiratory epithelium, metaplasia, squamous | 0** | 0 | 0 | 0 | 10** (1.1) | 10** (2.0)
Respiratory epithelium, necrosis | 0** | 0 | 0 | 0 | 1 (1.0) | 10** (2.1)
Respiratory epithelium, regeneration | 0** | 0 | 0 | 0 | 3 (1.0) | 10** (1.9)
Respiratory epithelium, ulcer | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Turbinate, atrophy | 0** | 0 | 0 | 0 | 2 (1.0) | 9** (2.0)
Larynx
Inflammation, chronic active | 0** | 0 | 1 (1.0) | 1 (1.0) | 0 | 5* (1.4)
Respiratory epithelium, hyperplasia | 0 | 0 | 0 | 0 | 2 (1.0) | 1 (1.0)
Respiratory epithelium, metaplasia, squamous | 0** | 0 | 0 | 4* (1.0) | 10** (1.5) | 10** (3.0)
Respiratory epithelium, necrosis | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Respiratory epithelium, regeneration | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Respiratory epithelium, ulcer | 0 | 0 | 0 | 1 (1.0) | 0 | 0
Squamous epithelium, hyperplasia | 0** | 0 | 0 | 0 | 0 | 9** (1.0)
Squamous epithelium, necrosis | 0** | 0 | 0 | 0 | 0 | 5* (1.2)
Squamous epithelium, ulcer | 0** | 0 | 0 | 0 | 0 | 4* (2.3)
Trachea^d^
Inflammation, acute | 0* | 0 | 0 | 0 | 0 | 2 (1.0)
Epithelium, hyperplasia | 0** | 0 | 0 | 1 (2.0) | 0 | 4* (3.0)
Epithelium, metaplasia, squamous | 0* | 0 | 0 | 0 | 0 | 2 (1.0)
Epithelium, necrosis | 0* | 0 | 0 | 0 | 0 | 2 (1.0)
Epithelium, regeneration | 0** | 3 (1.0) | 0 | 0 | 7** (1.6) | 10** (3.0)
Lung
Fibrosis, focal | 0** | 0 | 0 | 0 | 0 | 2 (1.0)
Inflammation, eosinophil | 4** (1.3) | 3 (1.0) | 4 (1.0) | 3 (1.0) | 5 (1.0) | 10** (1.7)
Alveolus, infiltration, cellular, polymorphonuclear | 0** | 0 | 0 | 0 | 0 | 2 (1.0)
Bronchiole, epithelium, hyperplasia | 0** | 0 | 0 | 0 | 0 | 7** (1.1)
Bronchus, epithelium, hyperplasia | 0** | 0 | 0 | 0 | 0 | 4* (1.5)
Bronchus, epithelium, regeneration | 0** | 0 | 0 | 0 | 0 | 8** (1.8)
Bronchus, epithelium, metaplasia, goblet cell | 0** | 0 | 0 | 0 | 0 | 3 (2.3)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Cochran-Armitage (trend) or Fisher’s exact (pairwise) test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

^d^ For the trachea data, n = 9 for the female 12.5 ppm group.

Olfactory epithelial atrophy consisted of thinning (attenuation) of the olfactory epithelium. Olfactory epithelium degeneration consisted of swollen and/or vacuolated olfactory epithelial cells (Figure 4A). The thickness of the epithelium was also decreased in some cases of degeneration. Respiratory metaplasia of the olfactory epithelium was characterized by replacement of the olfactory epithelium by ciliated, columnar epithelium resembling respiratory epithelium. Squamous metaplasia of the olfactory epithelium was characterized by replacement of the olfactory epithelium by squamous epithelium (Figure 4B). The metaplastic lesions were seen predominantly in the dorsal meatus of nasal sections II and III. These lesions are thought to be part of the same pathological process with degeneration of the olfactory epithelium leading to atrophy and further damage leading to respiratory and squamous metaplasia (respiratory and squamous epithelial types are thought to be more resistant to damage).

Figure 4

Representative Images of Atrophy, Squamous Metaplasia, and Suppurative Inflammation in the Nasal Cavity of Male Rats in the Three-month Inhalation Study of 2,3-Pentanedione (H&E)

(A) Atrophy of the olfactory epithelium (arrowhead) and olfactory nerves (arrow) at level I of the nasal cavity of a male rat exposed to 100 ppm 2,3-pentanedione (20×). (B) Squamous metaplasia of the epithelium at level I of the nasal cavity of a male rat exposed to 100 ppm 2,3-pentanedione (20×). (C) Suppurative inflammation at level II of the nasal cavity of a male rat exposed to 100 ppm 2,3-pentanedione. There are numerous degenerate neutrophils amid cellular debris and proteinaceous fluid on the right side of the photo (20×). H&E = hematoxylin and eosin stain.

Respiratory epithelial hyperplasia was characterized by increased numbers of cells in the respiratory epithelium. The cells were crowded along the basement membrane and were narrower and taller than typical respiratory epithelial cells. In some cases, the cells were more cuboidal and were piled up into three or more layers. The respiratory epithelium lining the nasal septum occasionally formed rugal folds. Squamous metaplasia of the respiratory epithelium consisted of replacement of the respiratory epithelium by the more resistant squamous epithelium. Necrosis of the respiratory epithelium was characterized by an attenuated or denuded epithelium often bordered by hypereosinophilic, shrunken cells with pyknotic nuclei and cellular debris. Ulceration is generally considered a sequel to necrosis and was diagnosed when there was complete, focal loss of the epithelium. Regeneration of the respiratory epithelium was diagnosed when the necrotic epithelium was replaced by flattened epithelium that extended from the adjacent nonnecrotic epithelium. While squamous metaplasia of the respiratory epithelium is thought to be a protective response of the respiratory epithelium (as are metaplastic lesions in the olfactory epithelium), regeneration and hyperplasia are thought to be reparative responses after necrosis of the epithelium.

Turbinate atrophy was characterized by blunted, shortened, and/or thinned turbinates with increased airway space between the tips of the turbinates. Turbinate atrophy was primarily evident in the maxilloturbinates of level I, less frequently in maxilloturbinates of level II, and rarely in the nasoturbinates of level II.

Suppurative inflammation (Figure 4C) was characterized by variable numbers of neutrophils in the nasal cavity lumen admixed with cellular debris and eosinophilic proteinaceous material, neutrophils in the nasal mucosa lamina propria, and neutrophils transmigrating the nasal epithelium, generally involving all levels of the nose.

Larynx: Most of the exposure-related lesions in the larynx were similar in male and female rats (but to a varying extent), and the incidences and average severities of these lesions either increased with increasing exposure concentration or were only seen in the highest exposure group (Table 11). The exposure-related lesions observed in both sexes were hyperplasia, squamous metaplasia, necrosis, ulceration, and regeneration of the respiratory epithelium; hyperplasia of the squamous epithelium; and chronic active inflammation. Two males in the 50 ppm group exhibited suppurative inflammation, and five and four females in the 100 ppm group had significantly increased incidences of necrosis and ulceration, respectively, of the squamous epithelium. Significant increases in the incidences of respiratory epithelial squamous metaplasia were seen in the 50 and 100 ppm groups of males and females compared to the control groups. In females, the incidence of this lesion was also significantly increased in the 25 ppm group relative to the control group. Hyperplasia of the squamous epithelium and of the respiratory epithelium was significantly increased in the 100 ppm groups of males and females and in the 50 ppm group of males, respectively, compared to the control groups. Chronic active inflammation of the larynx was significantly increased in 100 ppm group of females (and in males by positive trend only).

Chronic active inflammation of the larynx was characterized by an increased number of lymphocytes, macrophages, and neutrophils present in the laryngeal subepithelial tissue and occasionally extending into the mucosa and laryngeal lumen. Suppurative inflammation was characterized mainly by the presence of neutrophils in the lumen, many of which were degenerate, with fewer macrophages and lymphocytes. Some of the inflammatory cells were also present in the mucosa and submucosa. Regeneration of the respiratory epithelium consisted of flattened epithelial cells that stretched across the basement membrane and individualized epithelial cells with loss of cilia or an increase in thickness that did not exceed three cell layers. Hyperplasia of the respiratory and squamous epithelia were characterized by an increase in the thickness of the epithelium that was greater than three cell layers (Figure 5A). Respiratory epithelial squamous metaplasia was diagnosed when the normal ciliated columnar respiratory epithelium was replaced by stratified squamous epithelium, which was sometimes keratinized (Figure 5B). Necrosis of the respiratory or squamous epithelium was characterized by loss of the epithelial cell layer and replacement by necrotic cellular debris admixed with variable numbers of inflammatory cells and eosinophilic proteinaceous material or, rarely, individual cells with increased cytoplasmic eosinophilia and pyknotic nuclei. Ulceration of the respiratory and squamous epithelia was characterized by the absence of the epithelial cells, exposing the underlying connective tissue.

Figure 5

Representative Images of Hyperplasia and Squamous Metaplasia in the Larynx of Male Rats in the Three-month Inhalation Study of 2,3-Pentanedione (H&E)

(A) Hyperplasia and squamous metaplasia in the laryngeal pouch at level I of the larynx in a male rat exposed to 100 ppm 2,3-pentanedione. The squamous metaplasia is exemplified by the sheet-like cells in the center of the lesion (arrow), and the undulations and multiple layers of cells exemplify the hyperplasia (10×). (B) Squamous metaplasia of the epithelium on the lateral wall at level II of the larynx in a male rat exposed to 100 ppm 2,3-pentanedione. Note the keratinizing surface of the thickened epithelium (20×). H&E = hematoxylin and eosin stain.

Trachea: The exposure-related lesions in the trachea were consistent with the same general processes that were observed in the other respiratory tract organs. Lesion type, incidence, and significant increases in incidence were similar in males and females (Table 11). In both sexes, acute inflammation, epithelial squamous metaplasia, and epithelial hyperplasia were seen in the 100 ppm group, but only epithelial hyperplasia showed a significant increase in incidence over the respective control group by pairwise test. There were significant increases in the incidences of epithelial regeneration (Figure 6) in the male and female 50 and 100 ppm groups compared to the control groups. One male and two females in the 100 ppm groups were diagnosed with epithelial necrosis. Although not statistically significant (by pairwise test as there was a positive trend in females), the necrosis was considered related to exposure due to the presence of regeneration, a sequel to necrosis, in all animals in the 100 ppm groups. All of these lesions, except for acute inflammation, are similar to those described in the nose and larynx.

Figure 6

Representative Image of Regeneration in the Trachea of a Male Rat in the Three-month Inhalation Study of 2,3-Pentanedione (H&E)

Regeneration of the respiratory epithelium in the trachea of a male rat exposed to 100 ppm 2,3-pentanedione (10×). H&E = hematoxylin and eosin stain.

Lung: Most exposure-related lesions in the lungs were similar in males and females. In both sexes, there were significant increases in the incidences of eosinophilic inflammation, bronchial epithelial hyperplasia, bronchiolar epithelial hyperplasia, and bronchial epithelial regeneration in the 100 ppm groups compared to the control groups (Table 11). Other exposure-related lesions for which the incidences in exposed groups were not significantly different from control animals, or there was only a positive trend, included polymorphonuclear cell infiltration of the alveoli, goblet cell metaplasia of the bronchi, and focal fibrosis (with positive trends in females only) and squamous metaplasia of the bronchi (with a positive trend in males only). These lesions were considered exposure related because they are not typically seen in control animals; a few of them had slightly higher incidences in the females, and they are common responses to exposure.

Focal fibrosis consisted of small foci of fibrous connective tissue entrapping alveoli with low numbers of macrophages, with fewer eosinophils and lymphocytes and with occasional mast cells. The macrophages rarely contained golden-brown pigment, which was presumed to be hemosiderin.

Microscopically, eosinophilic inflammation was characterized mainly by eosinophils with fewer macrophages and occasional lymphocytes and neutrophils cuffing vessels and airways. The eosinophils were sometimes seen in the wall and epithelium of smaller airways and occasionally larger airways. Macrophages occasionally contained intracytoplasmic, golden-brown material (presumed to be hemosiderin).

In the bronchus, epithelial regeneration consisted of either flattening and elongation of the epithelium with loss of cilia or piling up of epithelium to three or more cell layers thick.

Epithelial hyperplasia in the bronchi was characterized by an increased thickness of the epithelium due to piling up of cells more than three layers thick (Figure 7A). Rarely, single cell necrosis was noted in these areas of high cell turnover. Squamous metaplasia in the bronchi consisted of replacement of the normal respiratory epithelium with flattened, squamous epithelium or with goblet cells, which had abundant, slightly basophilic, and vacuolated cytoplasm (Figure 7B).

Figure 7

Representative Images of Hyperplasia and Squamous Metaplasia in the Lung of Male Rats in the Three-month Inhalation Study of 2,3-Pentanedione (H&E)

(A) Hyperplasia (arrow) and squamous metaplasia (arrowheads) of the epithelium of a bronchus in the lung of a male rat exposed to 100 ppm 2,3-pentanedione (10×). (B) Squamous metaplasia of the epithelium of a bronchus in the lung of a male rat exposed to 100 ppm 2,3-pentanedione (20×). H&E = hematoxylin and eosin stain.

Eyes: There was acute inflammation in the eyes (cornea, ciliary body, anterior chamber, sclera, and/or iris), which was significantly increased in the cornea of males (positive trend only), in the cornea of females exposed to 50 and 100 ppm, and in the ciliary body of females exposed to 50 ppm (Table 12). Three male rats and two female rats had minimal inflammation of the conjunctiva (two males and one female in the 12.5 ppm group and one male and one female in the 50 ppm group). The inflammatory cells were predominantly neutrophils and were present within the cornea, ciliary body, anterior chamber, iris, and/or sclera. The overlying corneal epithelium was occasionally hyperplastic, vacuolated, ulcerated, and/or neovascularized (there was a positive trend for neovascularization and vacuolation in males).

Table 12 Incidences of Select Nonneoplastic Lesions of the Eye in Male and Female Rats in the Three-month Inhalation Study of 2,3-Pentanedione

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
Eye^a^ | 10 | 10 | 9 | 10 | 10 | 10
Anterior chamber, inflammation, acute^b^ | 0 | 0 | 0 | 0 | 2 (1.0)^c^ | 0
Ciliary body, inflammation, acute | 0 | 0 | 0 | 0 | 3 (1.3) | 0
Conjunctiva, inflammation, acute | 0 | 0 | 2 (1.0) | 0 | 1 (1.0) | 0
Cornea, inflammation, acute | 0** | 0 | 0 | 0 | 3 (1.0) | 3 (1.3)
Cornea, neovascularization | 0* | 0 | 0 | 0 | 0 | 2 (1.0)
Cornea, ulcer | 0 | 0 | 0 | 0 | 1 (2.0) | 0
Cornea, epithelium, hyperplasia | 0 | 0 | 0 | 0 | 0 | 1 (3.0)
Cornea, epithelium, vacuolation | 0* | 0 | 0 | 0 | 0 | 2 (2.5)
Iris, inflammation, acute | 0 | 0 | 0 | 0 | 2 (1.0) | 0
Female
Eye | 10 | 10 | 10 | 9 | 9 | 10
Anterior chamber, inflammation, acute | 0 | 0 | 0 | 0 | 3 (1.0) | 0
Ciliary body, inflammation, acute | 0** | 0 | 0 | 0 | 5* (1.2) | 2 (1.0)
Conjunctiva, inflammation, acute | 0 | 0 | 1 (1.0) | 0 | 1 (1.0) | 0
Cornea, inflammation, acute | 0** | 0 | 1 (1.0) | 0 | 5* (1.2) | 6** (1.3)
Cornea, ulcer | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Cornea, epithelium, hyperplasia | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Cornea, epithelium, vacuolation | 0 | 0 | 0 | 0 | 1 (2.0) | 0
Sclera, inflammation, acute | 0 | 0 | 0 | 0 | 2 (1.5) | 0

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Cochran-Armitage (trend) or Fisher’s exact (pairwise) test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Goblet cell metaplasia was noted in secondary bronchi, and occasionally there was accumulation of mucus within smaller, peripheral airways that was admixed with polymorphonuclear inflammatory cells and very rare sloughed epithelial cells.

Hyperplasia of the bronchiolar epithelium consisted of epithelial cells that were enlarged, piling up, crowding along the basement membrane, and often protruding into the airway lumen. Occasional cellular characteristics of slightly vacuolated cytoplasm, hyperchromatic nuclei, and reverse polarity (where the nucleus was closer to the lumen than the basement membrane) were present.

Polymorphonuclear cellular infiltration consisted of variable numbers of histiocytes infiltrating the alveoli.

### Three-month Study in Mice

All 3-month study mice survived to study termination. In the 100 ppm exposed mice, group mean body weight at day 8 was lower than the day 1 pre-exposure mean body weight and did not exceed the day 1 mean body weight until day 68 in males and day 40 in females (Table 13; Figure 8). Body weight gain and mean body weights were lower in males and females exposed to 50 or 100 ppm relative to controls (Figure 8). Terminal mean body weights were significantly decreased for male and female mice exposed to 50 and 100 ppm (Appendix E). Exposure-related clinical observations in the 50 and 100 ppm groups included abnormal breathing and sneezing in both sexes and eye abnormality in females (Table 14).

Table 13 Summary of Survival and Mean Body Weights of Male and Female Mice in the Three-month Inhalation Study of 2,3-Pentanedione

Study Day^a^ | 0 ppm | | 6.25 ppm | | | 12.5 ppm | | | 25 ppm | | | 50 ppm | | | 100 ppm
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 22.5 | 10 | 22.3 | 99.3 | 10 | 22.6 | 100.8 | 10 | 22.4 | 99.7 | 10 | 22.3 | 99.2 | 10 | 22.4 | 99.6 | 10
8 | 24.3 | 10 | 24.0 | 98.5 | 10 | 24.1 | 99.1 | 10 | 24.1 | 98.9 | 10 | 23.9 | 98.2 | 10 | 19.9 | 82.0 | 10
19 | 25.7 | 10 | 25.5 | 99.1 | 10 | 25.6 | 99.5 | 10 | 25.3 | 98.5 | 10 | 24.4 | 94.8 | 10 | 21.4 | 83.0 | 10
26 | 26.5 | 10 | 26.3 | 99.4 | 10 | 26.2 | 99.0 | 10 | 26.1 | 98.5 | 10 | 24.9 | 94.2 | 10 | 21.7 | 82.1 | 10
33 | 27.1 | 10 | 27.0 | 99.7 | 10 | 27.1 | 100.1 | 10 | 27.1 | 100.3 | 10 | 25.5 | 94.3 | 10 | 21.8 | 80.6 | 10
40 | 27.9 | 10 | 27.6 | 99.2 | 10 | 28.1 | 101.0 | 10 | 28.0 | 100.6 | 10 | 26.3 | 94.5 | 10 | 21.8 | 78.2 | 10
47 | 28.4 | 10 | 28.3 | 99.7 | 10 | 28.8 | 101.2 | 10 | 28.8 | 101.3 | 10 | 26.7 | 93.9 | 10 | 22.0 | 77.4 | 10
54 | 29.4 | 10 | 29.2 | 99.1 | 10 | 29.7 | 100.9 | 10 | 29.6 | 100.4 | 10 | 27.5 | 93.3 | 10 | 22.0 | 74.7 | 10
61 | 29.9 | 10 | 30.0 | 100.2 | 10 | 30.6 | 102.3 | 10 | 30.4 | 101.7 | 10 | 27.7 | 92.8 | 10 | 22.1 | 73.9 | 10
68 | 30.7 | 10 | 30.5 | 99.6 | 10 | 31.4 | 102.3 | 10 | 30.9 | 100.7 | 10 | 28.3 | 92.3 | 10 | 22.6 | 73.7 | 10
75 | 31.6 | 10 | 31.5 | 99.6 | 10 | 32.2 | 101.8 | 10 | 31.9 | 101.0 | 10 | 28.5 | 90.1 | 10 | 23.4 | 74.0 | 10
82 | 32.5 | 10 | 32.4 | 99.7 | 10 | 33.0 | 101.5 | 10 | 32.8 | 100.7 | 10 | 29.1 | 89.4 | 10 | 23.3 | 71.6 | 10
89 | 33.1 | 10 | 33.2 | 100.3 | 10 | 33.9 | 102.2 | 10 | 33.6 | 101.5 | 10 | 29.3 | 88.4 | 10 | 23.3 | 70.2 | 10
EOS | 33.7 | 10 | 33.9 | 100.7 | 10 | 34.4 | 102.1 | 10 | 34.1 | 101.2 | 10 | 29.6 | 87.8 | 10 | 23.3 | 69.2 | 10
Female
1 | 19.7 | 10 | 19.3 | 98.0 | 10 | 19.5 | 98.8 | 10 | 19.5 | 98.7 | 10 | 19.5 | 98.9 | 10 | 19.0 | 96.2 | 10
8 | 21.3 | 10 | 21.0 | 98.6 | 10 | 21.0 | 98.6 | 10 | 20.9 | 98.4 | 10 | 20.8 | 97.9 | 10 | 18.0 | 84.5 | 10
19 | 22.2 | 10 | 21.8 | 98.2 | 10 | 22.0 | 99.4 | 10 | 21.3 | 96.3 | 10 | 21.0 | 94.7 | 10 | 18.6 | 84.0 | 10
27 | 23.4 | 10 | 23.0 | 98.1 | 10 | 23.3 | 99.7 | 10 | 22.7 | 97.0 | 10 | 21.6 | 92.2 | 10 | 18.3 | 78.3 | 10
33 | 24.2 | 10 | 23.8 | 98.3 | 10 | 23.4 | 96.6 | 10 | 23.5 | 97.2 | 10 | 21.8 | 90.2 | 10 | 18.5 | 76.5 | 10
40 | 24.8 | 10 | 24.8 | 100.2 | 10 | 24.9 | 100.5 | 10 | 24.3 | 98.2 | 10 | 22.6 | 91.5 | 10 | 19.1 | 77.1 | 10
47 | 25.0 | 10 | 25.3 | 101.0 | 10 | 25.2 | 100.5 | 10 | 25.3 | 101.2 | 10 | 23.1 | 92.1 | 10 | 19.7 | 78.5 | 10
54 | 26.3 | 10 | 26.4 | 100.5 | 10 | 26.0 | 98.7 | 10 | 26.3 | 99.9 | 10 | 23.2 | 88.4 | 10 | 19.8 | 75.3 | 10
61 | 26.5 | 10 | 26.8 | 101.2 | 10 | 26.3 | 99.2 | 10 | 26.2 | 98.8 | 10 | 23.7 | 89.5 | 10 | 19.7 | 74.3 | 10
68 | 26.5 | 10 | 27.4 | 103.2 | 10 | 26.9 | 101.3 | 10 | 27.1 | 102.3 | 10 | 24.0 | 90.3 | 10 | 20.4 | 77.1 | 10
75 | 27.4 | 10 | 27.6 | 100.9 | 10 | 26.9 | 98.4 | 10 | 27.4 | 100.2 | 10 | 24.5 | 89.5 | 10 | 20.7 | 75.7 | 10
82 | 28.0 | 10 | 28.4 | 101.3 | 10 | 27.8 | 99.1 | 10 | 28.1 | 100.4 | 10 | 25.3 | 90.3 | 10 | 21.1 | 75.3 | 10
89 | 28.2 | 10 | 28.9 | 102.3 | 10 | 28.2 | 99.9 | 10 | 28.9 | 102.5 | 10 | 25.2 | 89.2 | 10 | 20.1 | 71.1 | 10
EOS | 29.1 | 10 | 29.7 | 102.2 | 10 | 28.9 | 99.5 | 10 | 29.4 | 101.1 | 10 | 25.1 | 86.2 | 10 | 20.3 | 69.7 | 10

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 8

Growth Curves for Male and Female Mice in the Three-month Inhalation Study of 2,3-Pentanedione

Growth curves are shown for (A) males and (B) females.

Table 14 Summary of Clinical Observations for Male and Female Mice in the Three-month Inhalation Study of 2,3-Pentanedione

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male^a^
Abnormal Breathing | 0/10 | 0/10 | 0/10 | 0/10 | 0/10 | 9/10 SD 33
Sneezing | 0/10 | 0/10 | 0/10 | 0/10 | 10/10 SD 26 | 10/10 SD 33
Female
Abnormal Breathing | 0/10 | 0/10 | 0/10 | 0/10 | 0/10 | 5/10 SD 33
Sneezing | 0/10 | 0/10 | 0/10 | 0/10 | 10/10 SD 27 | 10/10 SD 27
Eye Abnormality | 0/10 | 0/10 | 0/10 | 0/10 | 0/10 | 2/10 SD 68

No trend or pairwise statistical tests were performed on these data.

SD = study day.

^a^ Upper row displays cumulative number of animals with observation/total animals started on study. Lower row displays SD of observation onset.

There were significant increases in relative lung weights of males exposed to ≥50 ppm and females exposed to 100 ppm, whereas absolute lung weights were significantly decreased in females exposed to ≥50 ppm relative to control groups (Table 15). There were significant decreases in absolute heart, kidney, and liver weights of males and females and absolute spleen weights of females exposed to ≥50 ppm relative to control groups, as well as significant decreases in absolute spleen weights of males and relative spleen weights of females exposed to 100 ppm relative to control groups. There were significant increases in relative heart and spleen weights of males and relative kidney weights of females exposed to 100 ppm relative to control groups. Other statistically significant changes in absolute or relative organ weights were considered to be of uncertain biological significance and were likely due to decreased terminal body weights of groups exposed to ≥50 ppm. Grossly, two female mice exposed to 100 ppm had corneal lesions described as “pale” or “opaque” (Appendix E).

Table 15 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male and Female Mice in the Three-month Inhalation Study of 2,3-Pentanedione^a,b^

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Terminal Body Wt. (g) | 33.7 ± 0.4** | 33.9 ± 0.7 | 34.4 ± 0.5 | 34.1 ± 0.7 | 29.6 ± 0.4** | 23.3 ± 0.5**
Heart
Absolute (g) | 0.14 ± 0.00** | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.15 ± 0.00 | 0.13 ± 0.00** | 0.11 ± 0.00**
Relative (mg/g)^c^ | 4.22 ± 0.08** | 4.26 ± 0.08 | 4.17 ± 0.09 | 4.29 ± 0.08 | 4.23 ± 0.06 | 4.82 ± 0.12**
Right Kidney
Absolute (g) | 0.30 ± 0.01** | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.26 ± 0.01** | 0.22 ± 0.00**
Relative (mg/g) | 8.77 ± 0.23 | 8.67 ± 0.24 | 8.52 ± 0.18 | 8.61 ± 0.16 | 8.66 ± 0.12 | 9.24 ± 0.20
Liver
Absolute (g) | 1.44 ± 0.02** | 1.50 ± 0.04 | 1.42 ± 0.03 | 1.48 ± 0.05 | 1.24 ± 0.03** | 1.01 ± 0.03**
Relative (mg/g) | 42.70 ± 0.86 | 44.21 ± 0.99 | 41.46 ± 1.13 | 43.41 ± 1.05 | 42.04 ± 1.02 | 43.10 ± 0.85
Lung
Absolute (g) | 0.20 ± 0.00 | 0.21 ± 0.00 | 0.20 ± 0.00 | 0.20 ± 0.00 | 0.21 ± 0.00 | 0.20 ± 0.01
Relative (mg/g) | 6.04 ± 0.13** | 6.16 ± 0.16 | 5.94 ± 0.13 | 5.85 ± 0.14 | 6.99 ± 0.20** | 8.59 ± 0.18**
Spleen
Absolute (g) | 0.061 ± 0.002** | 0.062 ± 0.002 | 0.062 ± 0.001 | 0.060 ± 0.003 | 0.057 ± 0.002 | 0.049 ± 0.002**
Relative (mg/g) | 1.82 ± 0.07* | 1.84 ± 0.10 | 1.80 ± 0.03 | 1.76 ± 0.07 | 1.93 ± 0.05 | 2.11 ± 0.08*
Female
Terminal Body Wt. (g) | 29.1 ± 0.6** | 29.7 ± 0.7 | 28.9 ± 0.6 | 29.4 ± 0.7 | 25.1 ± 0.5** | 20.3 ± 0.5**
Heart
Absolute (g) | 0.13 ± 0.00** | 0.13 ± 0.00 | 0.13 ± 0.00 | 0.13 ± 0.00 | 0.12 ± 0.00** | 0.10 ± 0.00**
Relative (mg/g) | 4.52 ± 0.11 | 4.53 ± 0.13 | 4.51 ± 0.09 | 4.53 ± 0.11 | 4.59 ± 0.10 | 4.70 ± 0.09
Right Kidney
Absolute (g) | 0.20 ± 0.00** | 0.21 ± 0.01 | 0.20 ± 0.00 | 0.21 ± 0.00 | 0.18 ± 0.00** | 0.15 ± 0.01**
Relative (mg/g) | 6.95 ± 0.11** | 7.03 ± 0.14 | 6.93 ± 0.17 | 7.05 ± 0.15 | 7.19 ± 0.12 | 7.43 ± 0.10*
Liver
Absolute (g) | 1.36 ± 0.05 ** | 1.36 ± 0.03 | 1.29 ± 0.02 | 1.39 ± 0.08 | 1.08 ± 0.03** | 0.87 ± 0.03**
Relative (mg/g) | 46.66 ± 1.22** | 45.88 ± 0.73 | 44.71 ± 1.09 | 47.04 ± 2.41 | 43.02 ± 0.80 | 42.92 ± 0.84
Lung
Absolute (g) | 0.22 ± 0.01** | 0.21 ± 0.01 | 0.21 ± 0.00 | 0.21 ± 0.00 | 0.19 ± 0.00** | 0.19 ± 0.00**
Relative (mg/g) | 7.49 ± 0.26** | 7.12 ± 0.22 | 7.34 ± 0.11 | 7.27 ± 0.15 | 7.68 ± 0.25 | 9.28 ± 0.17**
Spleen
Absolute (g) | 0.096 ± 0.006** | 0.095 ± 0.003 | 0.088 ± 0.002 | 0.089 ± 0.003 | 0.074 ± 0.003** | 0.058 ± 0.002**
Relative (mg/g) | 3.30 ± 0.18** | 3.20 ± 0.11 | 3.05 ± 0.11 | 3.03 ± 0.09 | 2.96 ± 0.11 | 2.85 ± 0.08 **

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

There were no significant exposure-related changes in the hematology endpoints of mice exposed to 2,3-pentanedione (Appendix E).

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions in the respiratory tract (nose, larynx, trachea, lungs) and the eyes of mice (Appendix E).

Nose: The lesions in the nose were similar in males and females, and the incidences and average severities of these lesions tended to increase with increasing exposure concentration (Table 16). With the exception of respiratory epithelial squamous metaplasia and regeneration, which were observed in males and females in the 25 ppm groups, lesions were limited to animals exposed to ≥50 ppm 2,3-pentanedione. A complex array of lesions was observed that was similar to those in other organs of the respiratory tract. Lesions included inflammation, degenerative and regenerative lesions in the olfactory and/or respiratory epithelium, necrosis and perforation of the nasal septum, necrosis and atrophy of the nasal turbinates, and accumulation of hyaline droplets in the olfactory and respiratory epithelia. One or more of these lesions were present in most animals exposed to ≥50 ppm (Table 16).

Table 16 Incidences of Select Nonneoplastic Lesions of the Respiratory Tract in Male and Female Mice in the Three-month Inhalation Study of 2,3-Pentanedione

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | | 100 ppm
Male
Nose^a^ | 10 | 10 | 10 | 10 | 10 | | 10
Inflammation, suppurative^b^ | 0** | 0 | 0 | 0 | 10** (1.1)^c^ | | 10** (2.4)
Olfactory epithelium, accumulation, hyaline droplet | 0** | 0 | 0 | 0 | 1 (1.0) | | 6** (1.7)
Olfactory epithelium, atrophy | 0** | 0 | 0 | 0 | 10** (2.2) | | 10** (1.9)
Olfactory epithelium, metaplasia, respiratory | 0** | 0 | 0 | 0 | 10** (1.3) | | 9** (1.3)
Respiratory epithelium, accumulation, hyaline droplet | 0** | 0 | 0 | 0 | 4* (1.0) | | 7** (1.1)
Respiratory epithelium, hyperplasia | 0** | 0 | 0 | 0 | 3 (1.7) | | 4* (2.0)
Respiratory epithelium, metaplasia, squamous | 0** | 0 | 0 | 4* (1.0) | 8** (1.9) | | 9** (2.8)
Respiratory epithelium, necrosis | 0** | 0 | 0 | 0 | 1 (1.0) | | 4* (1.8)
Respiratory epithelium, regeneration | 0** | 0 | 0 | 6** (1.0) | 9** (1.4) | | 10** (2.2)
Septum, necrosis | 0** | 0 | 0 | 0 | 0 | | 7** (1.6)
Septum, perforation | 0** | 0 | 0 | 0 | 2 (3.0) | | 4* (2.8)
Turbinate, atrophy | 0** | 0 | 0 | 0 | 9** (1.3) | | 10** (1.8)
Turbinate, necrosis | 0** | 0 | 0 | 0 | 9** (1.4) | | 10** (2.3)
Larynx | 10 | 10 | 10 | 10 | 10 | | 10
Inflammation, acute | 0 | 0 | 1 (1.0) | 0 | 2 (1.5) | | 0
Inflammation, chronic active | 1** (1.0) | 0 | 0 | 1 (1.0) | 2 (1.0) | | 10** (1.4)
Respiratory epithelium, hyperplasia, atypical | 0 | 0 | 0 | 0 | 1 (3.0) | | 0
Respiratory epithelium, metaplasia, squamous, atypical | 0** | 0 | 0 | 0 | 8** (2.8) | | 10** (2.6)
Respiratory epithelium, metaplasia, squamous | 0 | 1 (1.0) | 0 | 2 (1.0) | 1 (3.0) | | 0
Respiratory epithelium, necrosis | 0** | 0 | 1 (1.0) | 0 | 0 | | 3 (1.0)
Respiratory epithelium, regeneration | 0 | 1 (2.0) | 2 (1.0) | 2 (1.5) | 9** (1.9) | | 0
Respiratory epithelium, ulcer | 0 | 0 | 1 (1.0) | 0 | 0 | | 0
Squamous epithelium, hyperplasia | 0 | 1 (1.0) | 1 (1.0) | 2 (1.0) | 0 | | 2 (1.0)
Squamous epithelium, hyperplasia, atypical | 0** | 0 | 0 | 0 | 9** (2.3) | | 8** (1.8)
Squamous epithelium, necrosis | 0* | 0 | 0 | 0 | 1 (1.0) | | 2 (1.0)
Squamous epithelium, regeneration | 0 | 0 | 0 | 3 (1.0) | 1 (3.0) | | 0
Squamous epithelium, ulcer | 0 | 0 | 1 (1.0) | 0 | 0 | | 2 (1.0)
Trachea | 10 | 10 | 9 | 10 | 10 | | 10
Inflammation, suppurative | 0** | 0 | 1 (2.0) | 0 | 0 | | 5* (1.6)
Inflammation, chronic active | 0** | 0 | 0 | 0 | 0 | | 5* (1.2)
Epithelium, hyperplasia, atypical | 0 | 0 | 0 | 0 | 1 (1.0) | | 1 (3.0)
Epithelium, metaplasia, squamous, atypical | 0** | 0 | 0 | 0 | 1 (2.0) | | 10** (3.3)
Epithelium, necrosis | 0 | 0 | 0 | 0 | 0 | | 1 (2.0)
Epithelium, regeneration | 0** | 0 | 0 | 0 | 8** (2.9) | | 0
Lung | 10 | 10 | 10 | 10 | 10 | | 10
Bronchiole, infiltration, cellular, polymorphonuclear | 0** | 0 | 0 | 0 | 0 | | 5* (1.0)
Bronchiole, epithelium, degeneration | 0** | 0 | 0 | 0 | 0 | | 4* (1.5)
Bronchiole, epithelium, hyperplasia | 0** | 0 | 0 | 0 | 1 (1.0) | | 4* (1.0)
Bronchus, infiltration, cellular, polymorphonuclear | 0** | 0 | 0 | 0 | 0 | | 9** (1.1)
Bronchus, inflammation, chronic | 0** | 0 | 0 | 1 (1.0) | 6** (1.2) | | 9** (1.2)
Bronchus, ulcer | 0 | 0 | 0 | 0 | 0 | | 1 (1.0)
Bronchus, epithelium, degeneration | 0** | 0 | 0 | 2 (1.0) | 9** (3.0) | | 8** (2.5)
Bronchus, epithelium, hyperplasia | 0 | 0 | 0 | 0 | 2 (2.5) | | 0
Bronchus, epithelium, hyperplasia, atypical | 0 | 0 | 0 | 0 | 7** (2.1) | | 0
Bronchus, epithelium, necrosis | 0** | 0 | 0 | 0 | 0 | | 3 (2.0)
Bronchus, epithelium, metaplasia, squamous, atypical | 0** | 0 | 0 | 0 | 0 | | 10** (2.6)
Bronchus, epithelium, regeneration | 0** | 1 (1.0) | 0 | 1 (1.0) | 8** (3.5) | | 7** (2.3)
Female
Nose | 10 | 10 | 10 | 10 | 10 | | 10
Inflammation, suppurative | 0** | 0 | 0 | 0 | 10** (1.8) | | 10** (2.5)
Olfactory epithelium, accumulation, hyaline droplet | 0** | 0 | 0 | 0 | 7** (1.1) | | 10** (1.5)
Olfactory epithelium, atrophy | 0** | 1 (1.0) | 0 | 0 | 10** (2.0) | | 9** (1.8)
Olfactory epithelium, metaplasia, respiratory | 0** | 0 | 0 | 0 | 7** (1.1) | | 8** (1.3)
Respiratory epithelium, accumulation, hyaline droplet | 1** (1.0) | 0 | 0 | 0 | 5 (1.0) | | 10** (1.5)
Respiratory epithelium, hyperplasia | 0** | 0 | 0 | 0 | 8** (1.8) | | 4* (1.8)
Respiratory epithelium, metaplasia, squamous | 0** | 0 | 0 | 8** (1.0) | 10** (2.0) | | 10** (2.1)
Respiratory epithelium, necrosis | 0* | 0 | 0 | 0 | 1 (1.0) | | 2 (1.0)
Respiratory epithelium, regeneration | 0** | 0 | 0 | 1 (1.0) | 5* (1.2) | | 9** (2.4)
Septum, necrosis | 0** | 0 | 0 | 0 | 0 | | 8** (2.1)
Septum, perforation | 0** | 0 | 0 | 0 | 1 (3.0) | | 3 (3.0)
Turbinate, atrophy | 0** | 0 | 0 | 0 | 10** (1.0) | | 10** (1.9)
Turbinate, necrosis | 0** | 0 | 0 | 0 | 9** (2.3) | | 10** (2.4)
Larynx | 10 | 10 | 10 | 10 | 10 | | 10
Inflammation, acute | 0 | 0 | 2 (1.5) | 0 | 0 | | 0
Inflammation, chronic active | 0** | 0 | 1 (1.0) | 1 (1.0) | 2 (1.0) | | 10** (1.6)
Lumen, inflammation, suppurative | 0 | 0 | 0 | 0 | 0 | | 1 (3.0)
Respiratory epithelium, hyperplasia | 0 | 1 (1.0) | 0 | 0 | 1 (4.0) | | 0
Respiratory epithelium, hyperplasia, atypical | 0 | 0 | 0 | 0 | 0 | | 1 (2.0)
Respiratory epithelium, metaplasia, squamous, atypical | 0** | 0 | 0 | 0 | 9** (2.2) | | 10** (3.0)
Respiratory epithelium, metaplasia, squamous | 0 | 1 (2.0) | 0 | 0 | 0 | | 0
Respiratory epithelium, necrosis | 0 | 0 | 2 (1.0) | 0 | 0 | | 2 (1.0)
Respiratory epithelium, regeneration | 0 | 0 | 0 | 1 (1.0) | 7** (2.0) | | 0
Respiratory epithelium, ulcer | 0 | 0 | 0 | 0 | 1 (1.0) | | 0
Squamous epithelium, hyperplasia | 0 | 0 | 0 | 4* (1.5) | 1 (1.0) | | 0
Squamous epithelium, hyperplasia, atypical | 0** | 0 | 0 | 0 | 9** (2.2) | | 10** (2.4)
Squamous epithelium, necrosis | 0** | 0 | 0 | 0 | 3 (1.0) | | 3 (1.0)
Squamous epithelium, regeneration | 0 | 0 | 2 (1.0) | 0 | 0 | | 0
Squamous epithelium, ulcer | 0 | 0 | 0 | 0 | 0 | | 1 (1.0)
Trachea | 10 | 10 | 10 | 10 | 10 | | 8
Inflammation, suppurative | 0** | 0 | 0 | 0 | 0 | | 5** (1.6)
Inflammation, chronic active | 0** | 0 | 0 | 0 | 0 | | 3 (2.0)
Epithelium, hyperplasia, atypical | 0** | 0 | 0 | 0 | 0 | | 3 (2.0)
Epithelium, metaplasia, squamous, atypical | 0** | 0 | 0 | 0 | 1 (1.0) | | 8** (3.1)
Epithelium, necrosis | 0 | 0 | 0 | 0 | 1 (1.0) | | 1 (1.0)
Epithelium, regeneration | 1 (1.0) | 0 | 0 | 0 | 10** (2.8) | | 0
Lung | 10 | 10 | 10 | 10 | 10 | | 10
Bronchiole, infiltration, cellular, polymorphonuclear | 0** | 0 | 0 | 0 | 0 | | 3 (1.0)
Bronchiole, epithelium, hyperplasia | 0 | 0 | 0 | 0 | 1 (1.0) | | 1 (1.0)
Bronchus, infiltration, cellular, polymorphonuclear | 0** | 0 | 0 | 0 | 0 | 9** (1.3)
Bronchus, inflammation, chronic | 0** | 0 | 0 | 0 | 4* (1.0) | 9** (1.6)
Bronchus, epithelium, degeneration | 0** | 0 | 0 | 0 | 9** (1.8) | 8** (2.8)
Bronchus, epithelium, hyperplasia | 0 | 0 | 0 | 0 | 1 (2.0) | 0
Bronchus, epithelium, hyperplasia, atypical | 0 | 0 | 0 | 0 | 1 (3.0) | 0
Bronchus, epithelium, metaplasia, squamous, atypical | 0** | 0 | 0 | 0 | 0 | 10** (2.1)
Bronchus, epithelium, necrosis | 0** | 0 | 0 | 0 | 0 | 2 (1.0)
Bronchus, epithelium, regeneration | 0** | 0 | 0 | 0 | 9** (2.4) | 9** (2.1)
Bronchus, epithelium, ulcer | 0** | 0 | 0 | 0 | 0 | 2 (1.0)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Cochran-Armitage (trend) or Fisher’s exact (pairwise) test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Suppurative inflammation was present in all levels of the nose and was characterized by the presence of variable numbers of neutrophils in the nasal mucosa and the lumen of the nasal cavity. In the lumen, the neutrophils were admixed with cellular debris and eosinophilic proteinaceous material. Rarely, foreign bodies, bone fragments, and bacterial cocci were also present. In the olfactory epithelium, there was significantly increased atrophy in all mice exposed to ≥50 ppm relative to control animals (except one female at 100 ppm). This change was most prominent in the dorsal meatus of levels II and III and was characterized by decreased thickness of the olfactory epithelium due to loss of epithelial cells. Respiratory metaplasia of the olfactory epithelium, defined as the replacement of the normal olfactory epithelium by ciliated, columnar epithelium (respiratory epithelium), was seen in all male and seven female mice exposed to 50 ppm and nine male and eight female mice exposed to 100 ppm 2,3-pentanedione. Hyaline droplet accumulation was also noted in the olfactory epithelium and was characterized by the presence of eosinophilic, globular material within the cytoplasm of affected epithelial cells.

The finding of respiratory epithelial regeneration described either flattening and elongation of epithelial cells with loss of cilia or enlarged cuboidal epithelial cells and karyomegaly piled up to three cell layers thick. Hyperplasia was characterized by epithelial cells that were taller than normal or were piling up more than three cell layers thick with resultant increased thickness of the epithelium. Necrosis of the respiratory epithelium consisted of loss of epithelium and replacement by cellular and karyorrhectic debris. This finding primarily affected the lateral aspects of the nasal cavity in levels I and II. Squamous metaplasia of the respiratory epithelium was characterized by replacement of the normal respiratory epithelium by squamous epithelium. Hyaline droplet accumulation in the respiratory epithelium was characterized by the presence of small, red, hyaline droplets within the cytoplasm of respiratory epithelial cells.

Septal necrosis was present in seven male and eight female mice from the 100 ppm groups. Septal perforation was present in two males and one female exposed to 50 ppm and in four males and three females exposed to 100 ppm 2,3-pentanedione. Septal necrosis was characterized by the absence of osteocytes from lacunae; absence of the osteoblast lining cell layer; and infrequent thickening of the affected bone, scalloping of the edge of the affected bone, and clusters of neutrophils in proximity to the affected bone. Septal perforation was seen in level I of the nose and was characterized by loss of the central portion of the septum. Turbinate necrosis and atrophy affected the maxillo- and nasoturbinates in levels I and II. Turbinate necrosis was characterized by loss of osteocytes from lacunae and the osteoblast layer and fragmentation of the affected bone with occasional extrusion of the necrotic bone into the nasal cavity lumen. Turbinate atrophy was characterized by shortened, blunted naso- and maxilloturbinates (Figure 9).

Figure 9

Representative Images of Turbinate Atrophy and Control Turbinate in the Nose of Male Mice in the Three-month Inhalation Study of 2,3-Pentanedione (H&E)

(A) Turbinate atrophy in the nose of a male mouse exposed to 100 ppm 2,3-pentanedione (compare to control in Panel B) (2×). (B) Turbinates in the nose of a male mouse exposed to 0 ppm 2,3-pentanedione (control mouse) (2×). H&E = hematoxylin and eosin stain.

Larynx: The lesions in the larynx were similar in male and female mice and included inflammation and epithelial necrosis, ulceration of the epithelium, regeneration and hyperplasia of the epithelium, atypical squamous metaplasia of the respiratory epithelium, and atypical hyperplasia of the squamous epithelium (Table 16). These lesions were seen at all levels of the larynx. They were most commonly seen in groups exposed to ≥50 ppm, in which the differences in incidence from the control group often reached statistical significance. A few of these lesions were seen at lower incidences in the groups exposed to lower concentrations (Table 16). In females, the incidence of squamous epithelial hyperplasia was significantly increased only in the 25 ppm group relative to control females. In general, these lesions were most common in the ventral and cranial portions of the larynx, and with increasing severity, the more caudal portions and lateral walls were increasingly affected.

Atypical hyperplasia of the squamous epithelium and atypical squamous metaplasia of the respiratory epithelium were observed in male and female mice exposed to ≥50 ppm 2,3-pentanedione. Squamous metaplasia of the respiratory epithelium is defined as replacement of the normally ciliated, columnar epithelium by squamous epithelium. These atypical metaplastic or hyperplastic lesions had histologic features that included cytomegaly, karyomegaly, hyperchromasia, multiple prominent nucleoli, and disorganized epithelial cell layers (Figure 10). Many of the mice with atypical hyperplasia or atypical squamous metaplasia of the larynx also had nonatypical squamous epithelial hyperplasia or squamous metaplasia in other portions of the larynx.

Figure 10

Representative Images of Atypical Squamous Metaplasia and Control Respiratory Epithelium in the Larynx of Male Mice in the Three-month Inhalation Study of 2,3-Pentanedione (H&E)

(A) Atypical squamous metaplasia of the respiratory epithelium in the larynx of a male mouse exposed to 100 ppm 2,3-pentanedione. The cells, particularly at the base of the epithelium, have enlarged nuclei (compare to control in Panel B) (20×). (B) Respiratory epithelium in the larynx of a male mouse exposed to 0 ppm 2,3-pentanedione (control mouse) (20×). H&E = hematoxylin and eosin stain.

Chronic active inflammation was the most commonly observed type of inflammation in the larynx and consisted of a mixed population of macrophages, lymphocytes, and neutrophils in the subepithelial tissue. Occasional neutrophils were seen within the submucosal glands. Acute inflammation was composed of neutrophils in the laryngeal lamina propria. Suppurative inflammation, present at all laryngeal levels in one 100 ppm female mouse, consisted of intraluminal neutrophils that entrapped layers of sloughed keratin. Regeneration, hyperplasia, and squamous metaplasia of the respiratory epithelium in the larynx were similar to the changes in the nose. Infrequently, individual necrotic cells were noted in the respiratory epithelium in these areas of high cell turnover. Regeneration of the respiratory epithelium was characterized by cuboidal, hyperchromatic epithelial cells up to three cell layers thick. Hyperplasia of the squamous epithelium consisted of an increased thickness and piling up of the squamous epithelium overlying the arytenoid cartilage of level I with occasional keratinization. Necrosis of the respiratory or squamous epithelium was characterized by nuclear pyknosis and hypereosinophilic cytoplasm with varying degrees of cell sloughing and loss, hemorrhage, and neutrophilic inflammation. Respiratory or squamous epithelial ulceration was characterized by loss of the epithelial cells with exposure of the subepithelial tissue; this change was generally noted overlying the distal tips of the arytenoid cartilage.

Trachea: As with the other organs of the upper respiratory tract, lesions in the trachea included inflammation and degenerative and regenerative lesions in the epithelium. These lesions were seen in the 50 and 100 ppm groups and were similar in males and females (Table 16). Similar to the larynx, there was evidence of atypia in the regenerating epithelial cells. In both sexes, atypical squamous metaplasia and regeneration of the epithelium were significantly increased in the 100 ppm and 50 ppm groups, respectively.

Microscopically, chronic active inflammation consisted of a mixed population of inflammatory cells in the tracheal submucosa, similar to that in the larynx. Suppurative inflammation was characterized by the presence of neutrophil aggregates in the tracheal lumen admixed with sloughed epithelial cells. Atypical epithelial hyperplasia was seen in three female mice exposed to 100 ppm and in two male mice (one exposed to 50 ppm and the other exposed to 100 ppm) and was characterized by an increase in epithelial cell layers to more than three. Atypical squamous metaplasia consisted of replacement of the respiratory epithelium with stratified squamous, occasionally keratinized epithelium. Atypical epithelial hyperplastic and squamous metaplastic changes were characterized by nuclear atypia, karyomegaly, cytomegaly, prominent and often multiple nucleoli, and general disorganization of the epithelial cell layers. Epithelial necrosis was seen infrequently but was considered the result of exposure to 2,3-pentanedione. It was characterized by individual, or rafts of epithelial cells detached from the basement membrane and sloughed into the tracheal lumen; these epithelial cells sometimes exhibited hypereosinophilic cytoplasm and shrunken, pyknotic nuclei. Epithelial regeneration was seen only in the 50 ppm groups of mice and was characterized either by elongation and flattening of epithelial cells in areas of necrosis or by increased thickness of the epithelium up to three cell layers thick.

Lung: The lesions in the lungs were limited to the airways and were similar to what was seen in the other organs of the respiratory tract: inflammation, hyperplasia/squamous metaplasia, degeneration/necrosis, and regeneration of the airway epithelium. As with the other organs, the majority of the lesions were similar in male and female mice and were most commonly seen at [underlined: >]50 ppm. Bronchial inflammation and bronchial epithelial degeneration and regeneration were seen in a few males in the 25 ppm group (Table 16).

The airway epithelium exhibited multiple changes. Chronic bronchial inflammation was observed in males and females in the 50 and 100 ppm groups of mice and in one male in the 25 ppm group. Chronic inflammation was characterized by increased numbers and aggregates of lymphocytes and plasma cells in the bronchial adventitia. Increased numbers of polymorphonuclear cells were also seen in the bronchi and bronchioles of some males and females in the 100 ppm groups. Atypical squamous metaplasia of the bronchial epithelium, characterized by replacement of the respiratory bronchial epithelium by squamous epithelium, was seen in males and females exposed to 100 ppm 2,3-pentanedione. Atypical bronchial epithelial hyperplasia, seen as an increase in the number of epithelial cell layers with atypical cellular features, was present in seven males and one female in the 50 ppm group. The atypical features of both these lesions were the same as those seen in the trachea and larynx. Bronchial and bronchiolar epithelial cell degeneration was characterized by enlarged cells with colorless cytoplasm that occasionally projected into the airway lumen (ballooning degeneration). Bronchial epithelial degeneration was significantly increased in the 50 and 100 ppm groups in both sexes of mice. Bronchiolar epithelial degeneration was significantly increased in the 100 ppm group in males but was not observed in female mice. Epithelial regeneration was seen only in the bronchi in both sexes in the 50 and 100 ppm groups. In the males, one animal each from the 6.25 and 25 ppm groups was also diagnosed with regeneration. It was characterized both by enlarged cells that occasionally lacked cilia with enlarged nuclei forming a single layer of cells and by increased numbers of epithelial cells piling up and extending into the airway lumen. Bronchial epithelial hyperplasia (Figure 11), seen in two males and one female in the 50 ppm groups, and bronchiolar epithelial hyperplasia, seen in one male and one female in the 50 ppm groups and in four males and one female in the 100 ppm groups, were characterized by the increased thickness of the epithelium due to the presence of more than three layers of epithelial cells. There also were scattered necrotic epithelial cells in these areas of high cell turnover in the bronchi. Ulceration of the epithelium in the bronchus was present, as well, and was characterized by the absence of the epithelium, exposing the underlying tissue, and by infiltration by low numbers of neutrophils on the surface.

Figure 11

Representative Image of Hyperplasia in the Lung of a Male Mouse in the Three-month Inhalation Study of 2,3-Pentanedione (H&E)

Hyperplasia of the respiratory epithelium in the bronchus of the lung from a male mouse exposed to 50 ppm 2,3-pentanedione. (20×).

Eyes: There was mineralization in the cornea in six female mice exposed to 100 ppm 2,3-pentanedione (Table 17). Three of these six animals also had hyperplasia of the corneal epithelium, two had acute corneal inflammation, and two had corneal epithelial ulceration. In the 50 ppm females, three animals had minimal focal cellular alteration of the cornea. Only the increase in corneal mineralization incidence was statistically significant (with a positive trend for the other lesions except the focal cellular alteration). In male mice exposed to 100 ppm, one animal was diagnosed with corneal epithelial hyperplasia, and one had acute corneal inflammation. In the 25 ppm group, one male had acute scleral inflammation.

Table 17 Incidences of Select Nonneoplastic Lesions of the Eyes in Male and Female Mice in the Three-month Inhalation Study of 2,3-Pentanedione

| 0 ppm | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n^a^ | 10 | 10 | 10 | 10 | 10 | 10
Male
Eye
Cornea, inflammation, acute^b^ | 0 | 0 | 0 | 0 | 0 | 1 (1.0)^c^
Cornea, epithelium, hyperplasia | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Sclera, inflammation, acute | 0 | 0 | 0 | 1 (1.0) | 0 | 0
Female
Eye
Cornea, inflammation, acute | 0** | 0 | 0 | 0 | 0 | 2 (1.5)
Cornea, mineralization | 0** | 0 | 0 | 0 | 0 | 6** (2.3)
Cornea, ulcer | 0** | 0 | 0 | 0 | 0 | 2 (1.5)
Cornea, epithelium, cellular alteration, focal | 0 | 0 | 0 | 0 | 3 (1.0) | 0
Cornea, epithelium, hyperplasia | 0** | 0 | 0 | 0 | 0 | 3 (1.0)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Cochran-Armitage (trend) or Fisher’s exact (pairwise) test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Microscopically, corneal hyperplasia consisted of multiple layers of epithelial cells with resultant increased corneal thickness. Corneal ulceration was characterized by loss of the corneal epithelium. Deposition of basophilic granular material, interpreted as mineralization, was observed in the corneal stroma beneath areas of corneal hyperplasia or ulceration. Acute inflammation consisted of varying numbers of neutrophils within the corneal stroma or at the base of the ciliary body. Cellular alteration was characterized by disorganized, slightly atypical, and slightly enlarged corneal epithelial cells that generally were associated with slight thinning of the corneal epithelium.

## Genetic Toxicology

Data from all NTP genetic toxicity tests with acetoin and 2,3-pentanedione are available in the NTP Chemical Effects in Biological Systems database: https://doi.org/10.22427/NTP-DATA-TOX-98.^90^

Acetoin (tested up to 10,000 μg/plate) was not mutagenic when tested in Salmonella typhimurium strains TA97, TA98, TA100, or TA1535, in the presence or absence of 10% or 30% induced rat or hamster liver S9 (Table D-1). Both acetoin (up to 800 ppm) and 2,3-pentanedione (up to 100 ppm) were evaluated for induction of micronucleated erythrocytes following 3 months of exposure via inhalation in male and female Wistar Han [Crl:WI(Han)] rats (Table D-2, Table D-3) and B6C3F1/N mice (Table D-4, Table D-5). Results of the micronucleus tests were negative in both rats and mice for both chemicals, and no alterations in the percentage of immature erythrocytes (% PCE) were observed in mice exposed to either acetoin or 2,3-pentanedione. In the acetoin study, a small but significant exposure concentration-related increase in % PCE was observed in male, but not female, rats, suggesting a mild perturbation in erythropoiesis in male rats. In the study with 2,3-pentanedione, small increases in micronucleated normochromatic erythrocytes (NCEs) were observed at the highest concentration tested (100 ppm) in male and female rats. These increases were not considered indicative of a biological response as they were in the NCE population—which is not the appropriate cell population to evaluate for frequency of micronuclei in rats due to the efficient removal by the spleen of damaged erythrocytes soon after they enter the blood stream—and because the values were well within the laboratory historical control ranges. A small exposure concentration-related increase in % PCE was observed in female rats exposed to 2,3-pentanedione.