# Materials and Methods

## Procurement and Characterization of Acetoin and 2,3-Pentanedione

Acetoin was obtained from Sigma-Aldrich, Inc. (Milwaukee, WI) in one lot (09118JH). 2,3-Pentanedione also was obtained from Sigma-Aldrich, Inc. (Milwaukee, WI) in one lot (MKBB7504). Identity and purity analyses were conducted by the analytical chemistry and animal study laboratories at Battelle Toxicology Northwest (Richland, WA) (Appendix A). Reports on analyses performed in support of the acetoin and 2,3-pentanedione studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot 09118JH, a solid white powder, was identified as acetoin by Chemir Analytical Services (Maryland Heights, MO) using Fourier transform infrared (IR) and ^1^H nuclear magnetic resonance (NMR) spectroscopies. Lot MKBB7504, a clear yellow liquid, was identified as 2,3-pentanedione by the study laboratory using IR and by Chemir Analytical Services using ^1^H NMR. Lot 09118JH was consistent with comparison spectra of IR and NMR from commercially procured reference standards. All spectra for both lot 09118JH and lot MKBB7504 matched the anticipated structures of the test articles (Appendix A). Elemental analysis was performed by Galbraith Laboratories, Inc. (Knoxville, TN) to aid in identification. The elemental compositions matched acetoin and 2,3-pentanedione.

Acetoin was received as a solid dimer and was thermally cracked to form the liquid monomer used as the exposure material. The purity of lot 09118JH in the solid and liquid form was determined by the study laboratory using gas chromatography (GC) with flame ionization detection (FID), and impurities were identified using GC with mass spectrometry (MS) detection (Table A-1). The purity of the solid dimer was determined to be 99.4%, and the purity of the liquid monomer was determined to be 99.2%. Three reportable impurities with peak areas ≥0.1% of the total integrated peak area were detected in the solid form, and two of the three reportable impurities were detected in the liquid form of acetoin. Karl Fischer titration, performed by Chemir Analytical Services, indicated <0.1% water in the solid test article. The overall purity of lot 09118JH was determined to be >99%.

The purity of lot MKBB7504 of 2,3-pentanedione was determined by the study laboratory using GC/FID (Table A-1). GC/FID determined a purity of 98.2% and detected four reportable impurities with peak areas ≥0.1%. Karl Fischer titration, performed by Chemir Analytical Services, yielded a water content of 0.75%. The overall purity of lot MKBB7504 was determined to be >98%.

To ensure stability, bulk acetoin was stored in sealed white plastic buckets at 5°C, and bulk 2,3-pentanedione was stored in sealed metal pails at 5°C. Periodic analyses of the bulk chemicals were performed by the study laboratory using GC/FID, and no degradation of either bulk chemical was detected.

## Vapor Generation and Exposure System

A diagram of the vapor generation and delivery system used in the studies is shown in Figure A-5. The test chemical, cracked acetoin or 2,3-pentanedione, was pumped from a 4-liter glass reservoir into a heated glass vaporizer column filled with glass beads and wrapped with heat tape. For the acetoin studies, formation of solid dimer was prevented by maintaining the generator reservoir at approximately 90°F and by daily rinsing of the liquid pump with water from an additional reservoir. For all studies, a waste collection flask was connected to the bottom of the column to collect residual chemical not completely vaporized.

Preheated nitrogen entered the vaporizer column from below, vaporized the test chemical, and carried the vapor from the generator cabinet to the distribution manifold through a heated chemical transport line. The nitrogen-chemical mixture was diluted with heated air before entering the distribution manifold. Concentration in the manifold was determined by the chemical pump rate, nitrogen flow rate, and dilution airflow rate. Pressure in the distribution manifold was kept fixed to ensure constant flow rates through the manifold and into all exposure chambers as the flow of vapor to each chamber was adjusted.

Individual heated Teflon^®^ delivery lines carried the diluted acetoin or 2,3-pentanedione vapor from the distribution manifold to three-way exposure valves at the chamber inlets. The chamber exposure valves diverted vapor delivery to the chamber exhaust until the generation system stabilized and exposure could proceed. The flow rate to each chamber was controlled by a metering valve at the distribution manifold. To initiate exposure, the chamber exposure valves were rotated to allow the acetoin or 2,3-pentanedione vapor to flow to each exposure chamber inlet duct, where it was diluted with conditioned air to achieve the desired exposure concentration. Conditioned air was a temperature-controlled and filtered mix of air derived from each exposure chamber’s wet and dry air duct supplies.

The study laboratory designed the inhalation exposure chamber (built by Lab Products, Inc., Seaford, DE) so that uniform vapor concentrations could be maintained throughout the chamber with catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small particle detector (Model 3022A) was used with and without animals in the exposure chambers to ensure that acetoin or 2,3-pentanedione vapors, and not aerosols, were produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## Vapor Concentration Monitoring

Exposure chamber and room concentrations of acetoin and 2,3-pentanedione were monitored using online GC/FID (Table A-1). Approximately every 20 minutes during each 6-hour exposure period, samples were drawn through stainless steel (acetoin) or Teflon (2,3-pentanedione) tubing connected to each exposure chamber’s sampling line using a 16-port Hastelloy^®^-C stream-select valve that directs a continuous stream of sampled atmosphere to a 6-port Hastelloy-C gas-sampling valve with a 1-mL Silicosteel^®^ sample loop. Both valves and the sampling loop were mounted in a dedicated valve oven. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and GC allowed for digital measurement of sample flow. Summaries of the chamber vapor concentrations are given in Table A-2 through Table A-4. The mean relative errors were within the acceptance criteria of 10% for all exposure groups for all studies.

## Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with (all studies) and without (3-month studies) animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9 minutes. A T_90_ value of 12 minutes was selected for both chemicals for all studies.

The persistence of the test chemical in the chambers was determined with (all studies) and without (3-month studies) animals present in the chambers. The time for the chamber concentration to decay to <1% of the target concentration after vapor generation was terminated (T_1_) was measured in the 800 ppm chambers for acetoin and in the 100 ppm chambers for 2,3-pentanedione. In the 2-week acetoin studies, T_1_ was approximately 47 minutes with animals present. In the 3-month acetoin studies, T_1_ was approximately 22 minutes without animals present; when animals were present, the chamber concentration did not drop below 1% of the target concentration until after the chamber doors were opened to perform animal care activities (up to 134 minutes after shutdown). In the 3-month 2,3-pentanedione studies, T_1_ was approximately 23 minutes without animals present and approximately 32 minutes with animals present. The presence of animals had a moderate effect on the decay of chamber concentration.

The uniformity of acetoin or 2,3-pentanedione vapor concentration was evaluated with (all studies) and without (3-month studies) animals present in the chambers. Concentrations were measured at 12 chamber positions, one in front and one in back, for each of the six possible animal cage positions per chamber, except for during the 3-month 2,3-pentanedione studies wherein concentrations were measured only at the regular monitoring port and from chamber positions where animals were present. Chamber concentration uniformity was maintained throughout the studies.

To measure stability and purity of the test chemicals in the generation and delivery system, samples of the test atmosphere from the distribution lines and low- and high-exposure concentration chambers for each species were collected during the first and last hours of generation with (all studies) and without (3-month studies) animals present in the chambers. The atmosphere samples were collected with sorbent gas-sampling tubes containing silica gel followed by a tube containing activated coconut charcoal. Grab samples were collected from the bulk chemical and generator reservoir for all studies of both test articles. To measure stability of the test chemicals in the exposure system, concentrations in all exposure chambers were monitored using online GC during 3 days of test generation prior to the 3-month studies.

Acetoin and 2,3-pentanedione were stable under the generation and exposure conditions used during the studies. During the 2-week and 3-month studies of acetoin, the impurities 2,3-butanedione, acetic acid, 3-methyl-2,4-pentanedione, and isomers of di-2-butan-3-one ether were detected in the atmosphere and generator reservoir samples. During the 3-month studies of 2,3-pentanedione, the impurities 2,3-butanedione, 3,4-hexanedione, acetaldehyde, paraldehyde, acetic acid, and five unknown peaks were detected in the atmosphere and generator reservoir samples.

## Animal Source

Male and female Wistar Han [Crl:WI(Han)] rats were obtained from Charles River Laboratories, Inc. (Raleigh, NC). Male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained by Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (Richland, WA) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Exposure Concentration Selection Rationale

The exposure concentrations used for 2,3-pentanedione matched those used for 2,3-butanedione (diacetyl), which is structurally similar (also a vicinal diketone), in the NTP 3-month inhalation toxicity study in rats and mice.^15^ The highest exposure concentration for 2,3-pentanedione (100 ppm) was also previously used for 3-month inhalation toxicity testing of 2,3-butanedione in C57BL/6 mice.^11^ When the 3-month toxicity study of 2,3-pentanedione was initiated, it was expected that the potencies of 2,3-butanedione and 2,3-pentanedione would be similar due to their structural similarity (and, therefore, the exposure concentrations could be matched), which has since been shown to be true on the basis of comparative 2-week studies.^13^ Acetoin is a less reactive hydroxyl-ketone compared to the diketones 2,3-butanedione and 2,3-pentanedione and is thought to be of relatively lower toxicological potency^34^; thus, higher exposure concentrations were selected.

## Two-week Studies

Rats and mice were approximately 4 weeks old on receipt. Animals were quarantined for 13 (rats) or 12 (mice) days and were approximately 6 weeks old (rats and mice) on the first day of the studies. Rats and mice were randomly assigned to one of six exposure groups before the start of the study. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Cedar Knolls, NJ).

Before the studies began, five male and five female rats and mice were randomly selected for necropsy, parasite evaluation, and selected histopathology for evidence of disease. At study termination, sera collected from five male rats and mice, and five female rats and mice were analyzed according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Groups of five male and five female rats and mice were exposed to acetoin vapors at concentrations of 0 (air), 6.25, 25, 100, 400, or 800 ppm for 6 hours plus T_90_ per day, 5 days per week, for 2 weeks plus 2 (rats) or 3 (mice) additional exposure days for a total of 12 (rats) or 13 (mice) exposures over a period of 16 (rats) or 17 (mice) days.

Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Rats and mice were observed twice daily for signs of mortality or moribundity. Clinical observations were made twice daily. Body weights were recorded before exposure on day 1, on days 6 and 13, and at study termination. Details of the study design and animal maintenance are summarized in Table 2. Information on feed composition and contaminants is provided in Appendix B.

Table 2 Experimental Design and Materials and Methods in the Two-week Inhalation Studies of Acetoin and Three-month Inhalation Studies of Acetoin and 2,3-Pentanedione

Two-week Studies | Three-month Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Same as 2-week studies
Strain and Species
Wistar Han [Crl:WI(Han)] rats | Same as 2-week studies
B6C3F1/N mice
Animal Source
Rats: Charles River Laboratories, Inc. (Raleigh, NC) | Same as 2-week studies
Mice: Taconic Biosciences, Inc. (Germantown, NY)
Time Held before Studies
Rats: 13 days | Rats (acetoin): 13 (males) or 14 (females) days Rats (2,3-pentanedione): 12 (males) or 13 (females) days
Mice: 12 days | Mice (acetoin): 12 days Mice (2,3-pentanedione): 13 days
Average Age When Studies Began
Rats: 6 weeks | Rats: 6 weeks
Mice: 6 weeks | Mice: 5–6 weeks
Date of First Exposure
October 27, 2008 | Rats (acetoin): June 29 (males) or 30 (females), 2009 Rats (2,3-pentanedione): September 13 (males) or 14 (females), 2010
| Mice (acetoin): June 29, 2009 Mice (2,3-pentanedione): September 13, 2010
Duration of Exposure
Rats: 6 hours plus T_90_ (12 minutes)/day, 5 days/week, for 2 weeks plus 2 additional exposure days for a total of 12 exposures over a period of 16 days | 6 hours plus T_90_ (12 minutes)/day, 5 days/week, for 3 months
Mice: 6 hours plus T_90_ (12 minutes)/day, 5 days/week, for 2 weeks plus 3 additional exposure days for a total of 13 exposures over a period of 17 days
Date of Last Exposure
Rats: November 11, 2008 | Rats (acetoin): September 28 (males) or 29 (females), 2009 Rats (2,3-pentanedione): December 13 (males) or 14 (females), 2010
Mice: November 12, 2008 | Mice (acetoin): September 30 (males) or October 1 (females), 2009 Mice (2,3-pentanedione): December 15 (males) or 16 (females), 2010
Necropsy Dates
Rats: November 12, 2008 | Rats (acetoin): September 29 (males) or 30 (females), 2009 Rats (2,3-pentanedione): December 14 (males) or 15 (females), 2010
Mice: November 13, 2008 | Mice (acetoin): October 1 (males) or 2 (females), 2009 Mice (2,3-pentanedione): December 16 (males) or 17 (females), 2010
Average Age at Necropsy
8 weeks | 19–20 weeks
Size of Study Groups
5 males and 5 females | 3-month study: 10 males and 10 females
| Clinical pathology (rats only): 10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies
Animals per Cage
1 | Same as 2-week studies
Method of Animal Identification
Tail tattoo | Same as 2-week studies
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, except during exposure, changed weekly | Same as 2-week studies
Water
Tap water (City of Richland, WA, municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as 2-week studies
Cages
Rats: R-24 stainless steel wire-bottom (Lab Products, Inc., Seaford, DE), changed weekly | Rats: Same as 2-week studies
Mice: M-40 stainless steel wire-bottom cage units (Lab Products, Inc.), changed weekly | Mice: Same as 2-week studies
Rack Filters/Excreta Liner
Single HEPA (Environmental Filter, Santa Rosa, CA); charcoal (RSE, Inc., New Baltimore, MI); Purafil (Environmental Systems, Lynnwood, WA). Excreta pans and the cage board lining the pans (Techboard Ultra, Shepherd Specialty Papers, Watertown, TN) were changed daily. | Same as 2-week studies
Chambers
Stainless steel with excreta pan suspended below each cage unit, changed weekly | Same as 2-week studies
Chamber Environment
Temperature: 75°F ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour | Same as 2-week studies
Exposure Concentrations
0, 6.25, 25, 100, 400, or 800 ppm by whole-body inhalation | Acetoin: 0, 50, 100, 200, 400, or 800 ppm by whole-body inhalation
| 2,3-Pentanedione: 0, 6.25, 12.5, 25, 50, or 100 ppm by whole-body inhalation
Type and Frequency of Observation
Observed twice daily; animals were weighed before exposure on day 1; animals were weighed, and clinical observations were recorded on days 6 and 13 and at study termination. | Observed twice daily; animals were weighed before exposure on day 1; animals were weighed, and clinical observations were recorded on day 8, weekly thereafter, and at study termination.
Method of Euthanasia
Carbon dioxide | Same as 2-week studies
Necropsy
Complete necropsies were performed on all animals. Organs weighed at study termination were heart, right kidney, liver, lung, right testis, and thymus. | Complete necropsies were performed on all animals. Organs weighed at study termination were heart, right kidney, liver, lung, spleen, right testis, and thymus.
Clinical Pathology
None | Acetoin: Blood was collected from the retroorbital plexus of clinical pathology rats on days 4 and 23, from 3-month core study rats at study termination, and from the supraorbital sinus of all mice at study termination for clinical chemistry (rats only) and hematology. 2,3-Pentanedione: Blood was collected from the retroorbital plexus of clinical pathology rats on days 3 and 23, from 3-month core study rats at study termination, and from the supraorbital sinus of all mice at study termination for clinical chemistry (rats only) and hematology.
| Hematology: hematocrit; hemoglobin; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and white blood cell count and differentials.
| Clinical chemistry (rats only): urea nitrogen, creatinine, glucose, total protein, albumin, globulin, A/G ratio, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, cholesterol, triglyceride, and bile salt/acids.
Histopathology
Histopathology was performed on 0, 6.25, 25, 100, 400, and 800 ppm rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined to the no-effect level: larynx, lung, lymph nodes (mediastinal and tracheobronchial), nasal cavity, and trachea. | Acetoin: Complete histopathology was performed on 0 and 800 ppm 3-month study rats and mice. 2,3-Pentanedione: Complete histopathology was performed on 0 and 100 ppm 3-month study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicles, thymus, thyroid gland, trachea, urinary bladder, and uterus.

A/G = albumin/globulin.

Complete necropsies were performed on all animals. Organ weights were determined for the heart, right kidney, liver, lung, right testis, and thymus from all animals. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, which were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides, which were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with hematoxylin and eosin (H&E). Lung, nasal cavity, trachea, larynx, mediastinal and tracheobronchial lymph nodes, and organs/tissues showing gross evidence of exposure-related lesions were examined microscopically to a no-effect level. Table 2 lists the tissues and organs examined.

## Three-month Studies

Rats and mice were 3 to 4 weeks old on receipt. Animals in the acetoin study were quarantined for 13 (male rats), 14 (female rats), or 12 (male and female mice) days. Animals in the 2,3-pentanedione study were quarantined for 12 (male rats) or 13 (female rats; male and female mice) days. Rats were approximately 6 weeks old, and mice were approximately 5 to 6 weeks old on the first day of the studies. Rats and mice were randomly assigned to one of six exposure groups before the start of the study. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Cedar Knolls, NJ).

Before the studies began, five male and five female rats and mice were randomly selected for necropsy, parasite evaluation, and selected histopathology for evidence of disease. Serologic analyses and parasite evaluations were performed on five male rats and mice and five female rats and mice 3 weeks after arrival and at study termination (only sera were analyzed at the end of the acetoin study). Health monitoring was performed using the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Groups of 10 male and 10 female rats and mice in the 3-month study group and 10 male and 10 female rats in the clinical pathology group were exposed to acetoin vapors at concentrations of 0 (air), 50, 100, 200, 400, or 800 ppm for 6 hours plus T_90_ per day, 5 days per week, for approximately 13 to 14 weeks. Groups of 10 male and 10 female rats and mice in the 3-month study group and 10 male and 10 female rats in the clinical pathology group were exposed to 2,3-pentanedione vapors at concentrations of 0 (air), 6.25, 12.5, 25, 50, or 100 ppm for 6 hours plus T_90_ per day, 5 days per week, for approximately 13 to 14 weeks.

Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Rats and mice were observed twice daily for signs of mortality or moribundity. Clinical observations were recorded on day 8, weekly thereafter, and at study termination. Body weights were recorded before exposure on day 1, on day 8, weekly thereafter, and at study termination. Details of the study design and animal maintenance are summarized in Table 2. Information on feed composition and contaminants is provided in Appendix B.

Animals were anesthetized with carbon dioxide, and blood was collected for hematology (rats and mice) and clinical chemistry (rats). For the acetoin studies, blood was collected from the retroorbital plexus of clinical pathology rats on days 4 and 23 and from 3-month rats at study termination for hematology and clinical chemistry analyses; blood was collected from the supraorbital sinus of all 3-month mice at study termination for hematology. For the 2,3-pentanedione studies, blood was collected from the retroorbital plexus of clinical pathology rats on days 3 and 23 and from 3-month rats at study termination for hematology and clinical chemistry analyses; blood was collected from the supraorbital sinus of all mice at study termination for hematology. Blood was collected in tubes containing a potassium ethylenediaminetetraacetic acid (K^+^-EDTA) anticoagulant for hematology (rats and mice) or into serum separator tubes for clinical chemistry (rats only). The following hematology parameters were measured using the ADVIA 120 analyzer (Siemens Medical Solutions Diagnostics, Tarrytown, NY): erythrocyte, platelet, and reticulocyte counts; hematocrit; hemoglobin concentration; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and white blood cell count and differential. Manual hematocrit values were determined using a microcentrifuge (Heraeus haemofuge, Heraeus Holding GmbH, Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Co., Needham Heights, MA). Blood smears were stained with Romanowsky-type aqueous stain in a Wescor 7120 aerospray slide stainer (Wescor, Inc., Logan, UT), and the cell morphology and number of nucleated red blood cells were assessed. Blood samples for clinical chemistry were allowed to clot and centrifuged, and the serum was harvested. Clinical chemistry parameters were determined using a Cobas c311 analyzer (Roche Diagnostics Corp., Indianapolis, IN). Clinical chemistry parameters measured are listed in Table 2.

Complete necropsies were performed on all animals. Organ weights were determined for the heart, right kidney, liver, lung, spleen, right testis, and thymus from all animals. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, which were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides, which were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with H&E. Complete histopathological examinations were performed on all 0 and 800 ppm 3-month rats and mice in the acetoin studies and in all 0 and 100 ppm 3-month rats and mice in the 2,3-pentanedione studies. Table 2 lists the tissues and organs examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the Division of Translational Toxicology (DTT) pathology peer-review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, DTT pathologist, QA pathologist(s), and PWG coordinator. Details of these review procedures have been described, in part, by Maronpot^67^ and Boorman.^68^

## Statistical Methods

Statistical methods were chosen based on distributional assumptions. Unless specifically mentioned, all endpoints were tested for a trend across exposure groups, followed by pairwise tests for each exposed group against the control group. Significance of all trend and pairwise tests is determined by a p value of ≤0.05 and is reported at both 0.05 and 0.01 levels.

### Calculation and Analysis of Nonneoplastic Lesion Incidences

The incidences of nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomical site and the numbers of animals with that site examined microscopically. Fisher’s exact test,^69^ a procedure that uses the overall proportion of affected animals, was used to determine statistical significance between exposed and vehicle control animals, and the Cochran-Armitage trend test was used to test for significant trends.^70^

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^71^ and Williams.^72,73^ Hematology and clinical chemistry data, which typically have skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^74^ (as modified by Williams^75^) and Dunn.^76^ The Jonckheere test^77^ was used to assess the significance of the exposure concentration-related trends and to determine whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test). Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey^78^ were examined by DTT personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

The 2-week and 3-month studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^79^ In addition, the 2-week and 3-month study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by DTT staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Report.

## Genetic Toxicology

The genetic toxicity of acetoin and 2,3-pentanedione was assessed by testing whether each chemical induces mutations in various strains of Salmonella typhimurium or increases the frequency of micronucleated erythrocytes in rat and mouse peripheral blood. The protocol for these studies, their analyses, and the results are given in Appendix D.

The genetic toxicity studies have evolved from an earlier effort to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals that is based on numerous considerations, including the relationship between the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were developed originally to clarify proposed mechanisms of chemical-induced DNA damage, given the relationship between electrophilicity and mutagenicity,^80^ and the somatic mutation theory of cancer.^81,82^ Not all cancers, however, arise through genotoxic mechanisms.

### Bacterial Mutagenicity (Acetoin)

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^83^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^84,85^ Additionally, no battery of tests that included the Salmonella test improved predictivity over the Salmonella test alone. Other tests, however, can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

### Peripheral Blood Micronucleus Test (Acetoin and 2,3-Pentanedione)

Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^86,87^ Acute in vivo bone marrow chromosome aberration and micronucleus tests appear to be less predictive of carcinogenicity than the Salmonella test.^87,88^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^89^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, determination of in vivo genetic effects is important to overall understanding of risks associated with exposure to a particular chemical.