# Introduction

Table 1 Acetoin and 2,3-Pentanedione

Chemical Name | Chemical Formula | CASRN | Molecular Weight (g/mol) | Structure
Acetoin | C_4_H_8_O_2_ | 513-86-0 | 88.11
2,3-Pentanedione | C_5_H_8_O_2_ | 600-14-6 | 100.12

Images generated with ChemSpider.^20^

Synonyms: 3-hydroxy-2-butanone, butan-2-ol-3-one, acetylmethylcarbinol (acetoin), acetyl propionyl (2,3-pentanedione).

## Chemical and Physical Properties

3-Hydroxy-2-butanone (acetoin) and 2,3-pentanedione (acetyl propionyl)—referred to as acetoin and 2,3-pentanedione, respectively, throughout this report—are both volatile, water-soluble ketones used as flavoring agents.^21^ Acetoin is a yellow liquid monomer or solid crystal dimer with a pleasant butter aroma and a “sweet, buttery, creamy, sour, fatty, vanilla” organoleptic profile.^22,23^ 2,3-Pentanedione is a clear yellow liquid with a “creamy, penetrating, cheese, oily, sweet, buttery,” almond-like organoleptic profile.^22,24^ 2,3-Pentanedione, a five-carbon diketone, is more water-soluble and volatile than acetoin, a four-carbon hydroxyl-keto compound.

## Production, Use, and Human Exposure

Acetoin occurs widely in nature and is produced by microorganisms, plants, and animals. Naturally occurring acetoin contributes to the flavors of butter, honey, cocoa, fruits, vegetables, and flours.^21,25,26^ Almost all alcoholic beverages contain acetoin that results from yeast or bacterial fermentation.^27^ Acetoin is also an abundant volatile compound in fresh human sweat (9.5%).^28^

Chemical synthesis of acetoin can be performed by three main methods: partial reduction of 2,3-butanedione (diacetyl) with zinc and acid, halogenation of 2-butanone and hydrolysis to acetoin, and condensation of acetaldehyde with catalysis by triazolium ylide or thiazolium ylide.^21,25^ Annual production levels of acetoin in the United States increased from 116,000 pounds in 1995 to 216,000 pounds in 2015.^29^

2,3-Pentanedione is produced naturally as a fermentation product in foods and beverages, such as beer, wine, and yogurt.^30^ Chemical synthesis of 2,3-pentanedione is mainly via oxidation of methyl propyl ketone when in the presence of hydroxylamine hydrochloride and catalyzed by sodium nitrite and diluted hydrochloric acid; it can also be synthesized by condensation of acetol with hexanal catalyzed by acid.^31,32^ The annual production of 2,3-pentanedione in the United States increased from 2,600 pounds in 1995 to 87,500 pounds in 2015.^29^

Acetoin and 2,3-pentanedione are used primarily as ingredients in synthetic flavoring formulations used as food additives.^15^ Acetoin is also used as a fragrance carrier in the preparation of perfumes and essences. 2,3-Pentanedione is a common constituent of synthetic flavorings and is used as a 2,3-butanedione substitute in some flavor manufacturing and food production operations, including artificial butter flavorings (ABF).^33,34^ Another use of 2,3-pentanedione is as a raw material in the preparation of alkyl-substituted pyrazines.^22^

Human exposure to acetoin and 2,3-pentanedione occurs primarily by ingestion and inhalation of vapors, but dermal absorption is another potential route of exposure. Ingestion of low amounts of these flavorings typically present in foods and beverages has not been reported to cause adverse health effects.^34^ Nonoccupational inhalation exposure to acetoin or 2,3-pentanedione can occur through exposure to fragrance vapors, use of e-cigarettes, and flavored tobacco in hookah water pipes.^35,36^ Cigarette smoke also has been reported to contain 2,3-pentanedione and 2,3-butanedione,^37,38^ and therefore can contribute to nonoccupational inhalation exposure. Occupational inhalation exposure to vapors can occur in workers involved in the production of microwave popcorn, coffee, baked goods, and other industries in which flavorings containing acetoin or 2,3-pentanedione, such as ABF, are heated.^34^ Exposure levels for the related compound, 2,3-butanedione, were reported to be 57.2 ppm in the mixing room of a microwave popcorn production plant where some workers developed obliterative bronchiolitis (OB),^39^ and the peak level of 2,3-butanedione measured in the headspace of mixing vats containing ABF was reported to be as high as 1,230 ppm.^1^ Exposure levels for 2,3-pentanedione have been reported in food production facilities (range: 15.14–172.07 ppb),^16^ in buttermilk flavoring for bakeries (up to 91 ppb),^33^ and in coffee production including roasting, grinding, and flavoring (up to 3.82 ppm).^40-42^ Duling et al.^41^ reported the peak 15-minute exposure to 2,3-butanedione and 2,3-pentanedione in a coffee flavoring room to be 14.3 and 13.8 ppm, respectively.^41^

## Regulatory Status

Currently there are no Occupational Safety and Health Administration (OSHA) occupational exposure limits (OELs) for acetoin or 2,3-pentanedione vapors. Acetoin is regulated by the U.S. Food and Drug Administration (FDA) as a synthetic flavoring substance or adjuvant for human consumption^43^ and for animal drugs, feeds, and related products.^43,44^ The addition of acetoin as a synthetic flavoring to human food in the United States is generally recognized as safe (GRAS), as defined by the FDA (21 CFR 182.60).^43^ 2,3-Pentanedione is also GRAS and approved by FDA for use in flavoring.^45^ The National Institute for Occupational Safety and Health (NIOSH) recommends that inhalation exposure to 2,3-pentanedione be kept below a time-weighted average concentration of 9.3 ppb (recommended exposure limits [RELs]) during a 40-hour work week.^34^ NIOSH also recommends short-term exposure limits (STELs) of 31 ppb 2,3-pentanedione during a 15-minute period.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Acetoin fed to dogs was reported to be partially excreted in the urine,^46^ along with a metabolite, butane-2,3-diol.^47^ Additional reports have described the metabolism of acetoin by liver preparations in vitro and in laboratory animals fed acetoin. Doisy and Westerfeld^48^ and Lipmann^49^ reported an increase of acetylation of sulfanilamide upon feeding acetoin to rabbits or incubating it with liver homogenates. Gabriel et al.^50^ demonstrated that cell-free extracts from mammalian liver could reduce acetoin to butane-2,3-diol. In subsequent studies, it was reported that ^14^C-labeled acetoin was oxidized to carbon dioxide in Sprague Dawley rats and in rat liver preparations and that oxidation probably proceeded through the formation of acetate from acetoin prior to oxidation.^51^ More recent studies on the metabolism of acetoin have not been identified. The literature contains no studies on the absorption, distribution, metabolism, and excretion (ADME) of inhaled 2,3-pentanedione in laboratory animals.

### Humans

The literature contains no studies on the ADME of inhaled acetoin or 2,3-pentanedione vapors in humans. 2,3-Pentanedione and other α-dicarbonyls are metabolized by dicarbonyl/L-xylulose reductase (DCXR) in cell-free liver and kidney preparations.^52,53^ DCXR and its counterparts are enzymes found in the lung, kidney, liver, and epididymis of various species.^53^ Zaccone et al.^54^ demonstrated the ability of intact primary human tracheobronchial epithelial cells in vitro to metabolize 2,3-pentanedione to 2-hydroxy-3-pentanone after exposure to 2,3-pentanedione vapors.

## Toxicity

### Experimental Animals

The literature contains no studies on the toxicity of inhaled acetoin vapors in laboratory animals. The effects of acetoin administered in dosed drinking water were evaluated in male and female CFE rats.^55^ Rats received drinking water containing 0 (control), 750, 3,000, or 12,000 ppm acetoin for 13 weeks. Exposure to 750 or 3,000 ppm had no adverse effects on body weight gain, hematological findings, serum chemistry, renal cell excretion, urinary concentration tests, organ weights, or histopathology. Exposure to 12,000 ppm acetoin resulted in a reduced rate of body weight gain, which was associated with a reduction in feed and water consumption. Relative liver weight was increased at 12,000 ppm, and animals exhibited slight anemia. The no-adverse-effect level was 3,000 ppm in drinking water, equivalent to an intake of approximately 330 mg acetoin/kg body weight/day or almost 700 times the calculated maximum daily intake in humans.^55^

Inhalation (whole-body) exposure of male Sprague Dawley [Hla^®^(SD)CVF^®^] rats or male and female Wistar Han rats to 2,3-pentanedione vapors caused significant respiratory tract toxicity, similar to that caused by 2,3-butanedione, including obliterative bronchiolitis (OB)-like airway fibrosis.^13,17-19^ Morgan et al.^13^ compared the toxicity of 2,3-pentanedione in the respiratory tract with that of 2,3-butanedione and 2,3-hexanedione in a 2-week inhalation study in rats. Male Wistar Han rats were evaluated the day after 2 weeks of whole-body exposure (6 hours/day, 5 days/week [plus 2 days], for 12 exposures total) to 0, 100, 150, or 200 ppm 2,3-butanedione, 2,3-pentanedione, or 2,3-hexanedione (postexposure groups) or 2 weeks later (recovery groups). Bronchial fibrosis was observed in all 200 ppm 2,3-butanedione and 2,3-pentanedione rats and in most 150 ppm 2,3-butanedione and all 2,3-pentanedione rats in the postexposure groups. For the recovery groups, bronchial fibrosis was observed in all surviving rats exposed to 200 ppm 2,3-butanedione or 2,3-pentanedione, some rats exposed to 150 ppm 2,3-butanedione, and most rats exposed to 150 ppm 2,3-pentanedione. Patchy interstitial fibrosis in the lungs of recovery group animals exposed to 150 or 200 ppm 2,3-pentanedione or 2,3-butanedione correlated with deficits in pulmonary function. Chemical reactivity of the α-diketones with an arginine substrate decreased with increasing chain length (2,3-butanedione ≥ 2,3-pentanedione > 2,3-hexanedione). Morgan et al.^13^ concluded that 2,3-butanedione and 2,3-pentanedione vapors were of similar reactivity and potency in causing bronchial fibrosis in rats.

Increased airway reactivity to methacholine with bronchial constriction was shown in rats exposed to 2,3-pentanedione, and increased hypersensitivity (measured by increased lymphocyte proliferation in draining lymph nodes) was observed in a murine model of dermal sensitization to diacetyl alternatives, including 2,3-pentanedione.^56^

### Humans

The literature contains no studies on the toxicity of acetoin and is limited for 2,3-pentanedione in humans. Acetoin has been detected in many of the workplaces where OB occurred in workers who make or use 2,3-butanedione.^3,5^ 2,3-Pentanedione has been used as a primary substitute for 2,3-butanedione in some workplace settings^34,56,57^; therefore, there is potential for occupational exposure to 2,3-pentanedione vapors.^42,58^

Abnormal (decreased) lung function (suggestive of undiagnosed or subclinical OB), increased dyspnea, and asthma-like and other respiratory symptoms have been reported in workers exposed to components of flavorings, including ABF (e.g., 2,3-pentanedione).^56,57,59^

Eye irritation was frequently reported in NIOSH medical surveys at microwave popcorn and flavoring manufacturing plants.^34^

## Reproductive and Developmental Toxicity

The literature contains no studies on the reproductive and developmental toxicity of acetoin or 2,3-pentanedione.

## Carcinogenicity

The literature contains no studies on the carcinogenicity of acetoin or 2,3-pentanedione. Chronic inhalation exposure to the related α-diketone, 2,3-butanedione, resulted in a low incidence of rare nasal cavity tumors (squamous cell carcinomas) in male and female Wistar Han [Crl:WI(Han)] rats; a low incidence of adenocarcinoma of the nose was also observed in female B6C3F1/N mice exposed to 2,3-butanedione.^15^

## Genetic Toxicity

Published reports on the genetic toxicity of acetoin or 2,3-pentanedione are limited. Negative results were observed when these chemicals were tested in bacterial mutagenicity assays. Acetoin (identified by the authors as butan-2-ol-3-one), tested at several concentrations ranging from 5 nmol to 0.5 mmol per plate, was not mutagenic in Salmonella typhimurium strains TA98, TA100, and TA102 in the absence or presence of rat metabolic liver enzymes (S9 mix).^60^ The literature contains no additional peer-reviewed publications on acetoin genotoxicity. A book chapter authored by Garst et al.,^61^ however, reported bacterial mutation test results for a series of structurally related α-hydroxy ketones, which included acetoin, identified by the authors as acetylmethylcarbinol; although no data were shown, acetoin was listed as nonmutagenic in TA100 in the absence or presence of S9 mix.

2,3-Pentanedione, tested at several concentrations ranging from 9 nmol to 0.9 mmol per plate, was not mutagenic in S. typhimurium strains TA98, TA100, or TA102 in the absence or presence of S9 mix.^60^ In addition, no mutagenicity was observed with 2,3-pentanedione tested at a single concentration of 3 µmol per plate in strains TA98, TA100, TA1535, or TA1537, with or without S9 mix.^62^ A recent study using in silico QSAR (quantitative structure-activity relationship) modeling, bacterial mutagenicity testing, and in vitro micronucleus tests with human TK6 cells to characterize the toxicity potential for a group of data-poor chemicals confirmed the absence of mutagenicity for 2,3-pentanedione in S. typhimurium strains.^63^ In the in vitro micronucleus test in TK6 cells, the authors called the responses observed with 2,3-pentanedione inconclusive, with and without S9, because the dose range tested was suboptimal (too high without S9 and too low with S9).^63^

A structurally related α-diketone, 2,3-butanedione, was shown to be mutagenic in S. typhimurium base-substitution strains TA100, TA102, and TA104, with and without rat liver S9 activation^60,64,65^; no mutagenicity was shown in the frameshift strain TA98, with or without S9.^60,64^ 2,3-Butanedione was also tested in two independent bacterial gene mutation assays as part of an NTP study.^15^ In the first set of assays, conducted with and without hamster and rat liver S9, 2,3-butanedione was mutagenic in S. typhimurium strain TA97 with and without hamster and rat S9, equivocal in strain TA100 with hamster and rat S9, and negative in strains TA98, TA100, and TA1535. In the second set of assays, 2,3-butanedione, tested with and without rat liver S9, was mutagenic in strain TA97 without S9 and in Escherichia coli strain WP2 uvrA (pKM101) with and without S9; equivocal results were obtained in strain TA97 with S9 and in strain TA100 with and without S9, while no mutagenicity was observed in strain TA98. Results of a bone marrow micronucleus test conducted in male B6C3F1/N mice following intraperitoneal injection of 2,3-butanedione were negative. Results of a peripheral blood micronucleus test conducted in male and female Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice following 3 months of inhalation exposure were also negative.^15^

## Study Rationale

The inhalation toxicities of acetoin and 2,3-pentanedione were investigated due to extensive occupational and nonoccupational exposures to the vapors of these chemicals and because both are structurally similar to 2,3-butanedione, a known profibrotic respiratory tract toxicant. To date, the inhalation toxicity of 2,3-pentanedione has only been reported for 2-week and shorter whole-body exposure studies in rats with a main focus on adverse respiratory tract effects. The primary objective of the NTP study reported herein was to evaluate the 3-month inhalation toxicity of 2,3-pentanedione vapors within the respiratory tract, the eyes, and other target organs in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice, including airway/lung lesion formation following 3 months of whole-body exposure and potential mechanism(s) of chemical-induced pathogenesis within the airways/lung. The inhalation toxicity of acetoin, which like 2,3-butanedione was originally found to be a major volatile component of ABF,^9^ has not been investigated. Therefore, this NTP study also evaluated the 2-week and 3-month inhalation toxicity of acetoin in Wistar Han rats and B6C3F1/N mice. Additional toxicological data for 2,3-pentanedione and acetoin are needed by regulatory agencies to help inform inhalation exposure limits to mitigate occupational exposure risks.

NTP subchronic and chronic inhalation studies typically and historically have used whole-body exposure instead of nose-only exposure. Whole-body exposure has been shown to be less stressful than nose-only exposure (due to animal immobilization and increased heating within the nose-only exposure tubes), especially for repeated exposures, whereas nose-only exposure is more amenable to acute exposures.^18,66^ Whole-body exposure is also a more occupationally relevant exposure route to a volatile chemical for which, in addition to inhalation, there is potential for dermal and ocular exposure (which would be similar to exposed workers without proper PPE). Furthermore, initial testing of ABF (including the related compound 2,3-butanedione) reported in NTP studies^15^ and others (e.g., Hubbs et al. 2002^9^) used whole-body exposure. As part of NTP’s evaluation of ABF, 2,3-butanedione was also tested in 3-month and 2-year inhalation toxicity studies using whole-body exposure; therefore, the exposure method and route for the 2,3-pentanedione 3-month study were matched to that of 2,3-butanedione for comparative purposes. It is also known from several 2-week studies that whole-body exposure of rats to 2,3-pentanedione vapors consistently induces obliterative bronchiolitis (OB)-like fibrotic airway lesions in the lung, which reflect those observed occupationally in workers,^39^ suggesting that 2,3-pentanedione permeates into the distal airways of the lung with whole-body exposure.