# Appendix E Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-98.

## E.1 Two-week Acetoin Study – Rats

### E.1.1 Data Tables

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

### E.1.2 Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

## E.2 Two-week Acetoin Study – Mice

### E.2.1 Data Tables

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

### E.2.2 Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Male Individual Animal Body Weight Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

## E.3 Three-month Acetoin Study – Rats

### E.3.1 Data Tables

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

### E.3.2 Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

Individual Animal Clinical Chemistry Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## E.4 Three-month Acetoin Study – Mice

### E.4.1 Data Tables

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA43 – Hematology Summary

### E.4.2 Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## E.5 Three-month 2,3-Pentanedione Study – Rats

### E.5.1 Data Tables

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

### E.5.2 Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Female Individual Clinical Observations

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

Male Individual Clinical Observations

Individual Animal Clinical Chemistry Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## E.6 Three-month 2,3-Pentanedione Study – Mice

### E.6.1 Data Tables

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA43 – Hematology Summary

### E.6.2 Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Female Individual Clinical Observations

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

Male Individual Clinical Observations

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## E.7 Genetic Toxicology

### E.7.1 Acetoin Micronucleus Study in Wistar Han Rats

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.7.2 Acetoin Micronucleus Study in B6C3F1 Mice

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.7.3 Acetoin Salmonella/E.coli Mutagenicity Test or Ames Test

G06 – Ames Summary Data

### E.7.4 2,3-Pentanedione Micronucleus Study in Wistar Han Rats

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.7.5 2,3-Pentanedione Micronucleus Study in B6C3F1 Mice

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data