# Appendix D Genetic Toxicology

## D.1 Evaluation Protocol

The National Toxicology Program (NTP) considers biological as well as statistical factors to determine an overall assay result. For an individual assay, the statistical procedures for data analysis are described in the following protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. In such cases, all the data are critically evaluated with attention given to possible protocol variations in determining the weight of evidence for an overall conclusion of chemical activity in an assay. For in vitro assays conducted with and without exogenous metabolic activation, results obtained in the absence of activation are analyzed separately from results obtained in the presence of activation. The summary table in the abstract of this toxicity report presents the Division of Translational Toxicology’s scientific judgment regarding the overall evidence for activity of the chemical in an assay.

## D.2 Bacterial Mutagenicity

### D.2.1 Bacterial Mutagenicity Test Protocol

Testing procedures were modified from those originally reported by Zeiger et al.^85^ Coded samples of acetoin (lot 02209CS) were incubated with the Salmonella typhimurium (TA97, TA98, TA100, TA1535) tester strains, either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat liver and male Syrian hamster liver), for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted after incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of acetoin. The highest concentration tested was 10,000 µg/plate.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. No minimum percentage or fold-increase is required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### D.2.2 Results

Acetoin (tested up to 10,000 μg/plate) was not mutagenic when tested in S. typhimurium strains TA97, TA98, TA100, and TA1535 in the presence or absence of 10% or 30% induced rat or hamster liver S9 (Table D-1).

Table D-1 Mutagenicity of Acetoin in Bacterial Tester Strains^a^

Strain | Dose (ppm) | Without S9 | Without S9 | With 10% Rat S9 | With 30% Rat S9 | With 10% Hamster S9 | With 30% Hamster S9
TA97
| 0 | 127 ± 4.4 | 118 ± 5.2 | 164 ± 3.5 | 216 ± 11.0 | 145 ± 11.2 | 152 ± 10.9
| 100 | 129 ± 10.6 | 104 ± 4.8 | 167 ± 5.2 | 197 ± 12.7 | 135 ± 8.2 | 178 ± 3.5
| 333 | 145 ± 5.7 | 117 ± 3.8 | 160 ± 13.9 | 222 ± 12.8 | 136 ± 4.6 | 173 ± 0.9
| 1,000 | 136 ± 1.9 | 104 ± 4.0 | 159 ± 14.2 | 210 ± 9.2 | 160 ± 10.1 | 175 ± 7.6
| 3,333 | 143 ± 2.5 | 126 ± 7.5 | 162 ± 12.0 | 222 ± 9.8 | 126 ± 7.0 | 180 ± 13.7
| 10,000 | 129 ± 5.9 | 122 ± 2.3 | 167 ± 1.7 | 216 ± 10.1 | 162 ± 4.5 | 158 ± 7.7
Trial Summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive Control^b^ | | 306 ± 36.4 | 242 ± 15.9 | 1,432 ± 27.6 | 524 ± 25.1 | 551 ± 7.8 | 808 ± 10.2
TA98
| 0 | 13 ± 1.5 | 17 ± 3.2 | 20 ± 4.5 | 17 ± 2.3 | 19 ± 2.2 | 20 ± 3.0
| 100 | 11 ± 0.3 | 16 ± 2.7 | 30 ± 1.8 | 18 ± 1.5 | 28 ± 3.8 | 15 ± 2.6
| 333 | 11 ± 2.7 | 14 ± 1.0 | 20 ± 1.2 | 18 ± 2.8 | 20 ± 0.9 | 20 ± 0.9
| 1,000 | 10 ± 1.2 | 12 ± 1.0 | 19 ± 2.0 | 16 ± 4.2 | 19 ± 3.8 | 18 ± 0.9
| 3,333 | 9 ± 3.2 | 11 ± 1.5 | 17 ± 2.3 | 14 ± 1.9 | 20 ± 3.1 | 19 ± 2.3
| 10,000 | 9 ± 1.2 | 17 ± 2.7 | 23 ± 3.4 | 17 ± 1.2 | 22 ± 1.8 | 18 ± 1.5
Trial Summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive Control | | 80 ± 9.6 | 74 ± 5.5 | 227 ± 37.9 | 124 ± 5.2 | 527 ± 20.9 | 151 ± 6.8
TA100
| 0 | 184 ± 8.8 | 156 ± 2.5 | 183 ± 14.0 | 191 ± 15.0 | 161 ± 5.6 | 137 ± 10.9
| 100 | 187 ± 13.0 | 159 ± 10.7 | 171 ± 4.4 | 196 ± 25.6 | 160 ± 6.9 | 143 ± 1.9
| 333 | 165 ± 9.5 | 155 ± 13.7 | 182 ± 15.2 | 193 ± 11.3 | 158 ± 14.4 | 139 ± 6.0
| 1,000 | 165 ± 7.2 | 151 ± 6.3 | 198 ± 1.5 | 211 ± 12.7 | 165 ± 13.5 | 127 ± 8.4
| 3,333 | 189 ± 9.5 | 147 ± 7.7 | 178 ± 1.2 | 215 ± 15.5 | 171 ± 5.8 | 151 ± 6.0
| 10,000 | 168 ± 5.8 | 153 ± 1.7 | 165 ± 10.5 | 228 ± 17.3 | 192 ± 12.1 | 138 ± 9.2
Trial Summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive Control | | 398 ± 45.0 | 343 ± 10.7 | 469 ± 6.8 | 704 ± 58.2 | 520 ± 40.1 | 806 ± 20.5
TA1535
| 0 | 10 ± 1.2 | 10 ± 1.9 | 13 ± 1.2 | 10 ± 1.2 | 17 ± 3.2 | 9 ± 2.7
| 100 | 7 ± 1.9 | 9 ± 1.2 | 13 ± 3.1 | 8 ± 2.1 | 14 ± 2.0 | 12 ± 0.9
| 333 | 7 ± 1.7 | 8 ± 0.3 | 10 ± 1.5 | 10 ± 1.7 | 9 ± 1.2 | 6 ± 0.0
| 1,000 | 9 ± 1.3 | 9 ± 1.5 | 10 ± 1.7 | 10 ± 0.0 | 9 ± 2.4 | 8 ± 2.5
| 3,333 | 9 ± 1.2 | 9 ± 2.3 | 11 ± 4.5 | 11 ± 3.0 | 12 ± 0.3 | 9 ± 1.5
| 10,000 | 5 ± 1.2 | 10 ± 0.6 | 15 ± 0.7 | 12 ± 0.9 | 15 ± 1.5 | 11 ± 3.4
Trial Summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive Control | | 233 ± 5.2 | 219 ± 13.3 | 202 ± 5.5 | 205 ± 4.4 | 45 ± 4.5 | 78 ± 4.8

^a^ Studies performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate served as the solvent control.

^b^ The positive controls in the absence of metabolic activation were 9-aminiacridine (TA97), 4-nitro-o-phenylenediamine (TA98), and sodium azide (TA100, TA1535). The positive control for metabolic activation with all strains was 2-aminoanthracene.

## D.3 Micronucleus Assay

### D.3.1 Peripheral Blood Micronucleus Test Protocol

At termination of the 3-month inhalation toxicity studies of acetoin and 2,3-pentanedione, blood samples were collected from male and female Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice, placed in ethylenediaminetetraacetic acid (EDTA)-coated tubes, and shipped overnight to the testing laboratory. Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY), according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature reticulocytes (i.e., reticulocytes or polychromatic erythrocytes [PCEs]) and mature erythrocytes (i.e., normochromatic erythrocytes [NCEs]) using a flow cytometer^92^; both the mature and immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte subpopulation (CD71+ cells) can be targeted using this technique, rat blood samples can be analyzed for damage that occurred in the bone marrow within the past 24–48 hours, before the rat spleen appreciably alters the percentage of PCEs in circulation.^93^ In mice, both the mature and immature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice after 4 weeks of continuous exposure. Approximately 20,000 PCEs and 1 × 10^6^ NCEs were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from chemical exposure.

Prior experience with the large number of cells scored using flow cytometric scoring techniques^94^ suggests it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. The Levene test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with exposure concentration, and the Williams test is used to test for pairwise differences between each exposed group and the control group. In the case of unequal variances, the Jonckheere test is used to test for linear trend, and the Dunn test is used for pairwise comparisons of each exposed group with the control group. To correct for multiple pairwise comparisons, the p value for each comparison with the control group is multiplied by the number of comparisons made. If this product is >1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the control group are considered statistically significant at p ≤ 0.025.

In the micronucleus test, it is preferable to base a positive result on the presence of both a positive trend as well as at least one significantly elevated exposed group compared with the corresponding control group. In addition, historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. The presence of either a positive trend or a single significant exposed group generally results in an equivocal call. The absence of both a trend and any significant differences between exposed groups and the control group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

### D.3.2 Results

Both acetoin (up to 800 ppm) and 2,3-pentanedione (up to 100 ppm) were evaluated for induction of micronucleated erythrocytes following 3 months of exposure via inhalation in male and female Wistar Han rats (Table D-2, Table D-3) and B6C3F1/N mice (Table D-4, Table D-5). Results of the micronucleus tests were negative in both rats and mice for both chemicals, and no alterations in % PCE were observed in mice exposed to either acetoin or 2,3-pentanedione. In the acetoin study, a small but significant exposure concentration-related increase in % PCE was observed in male, but not female, rats, suggesting a mild perturbation in erythropoiesis in male rats. In the study with 2,3-pentanedione, small increases in micronucleated NCEs were observed at the highest concentration tested (100 ppm) in male and female rats. These increases were not considered indicative of a biological response as they were in the NCE population—which is not the appropriate cell population to evaluate for frequency of micronuclei in rats due to the efficient removal by the spleen of damaged erythrocytes soon after they enter the blood stream—and because the values were well within the laboratory historical control ranges. A small exposure concentration-related increase in % PCE was observed in female rats exposed to 2,3-pentanedione.

Table D-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Rats in the Three-month Inhalation Study of Acetoin^a^

| Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (ppm)
0 | 5 | 0.960 ± 0.147 | | 0.042 ± 0.007 | | 0.648 ± 0.064
50 | 5 | 0.580 ± 0.044 | 0.8081 | 0.042 ± 0.009 | 0.4823 | 0.717 ± 0.067 | 0.4083
100 | 5 | 0.770 ± 0.125 | 0.8799 | 0.052 ± 0.007 | 0.4692 | 0.831 ± 0.068 | 0.0563
200 | 5 | 0.920 ± 0.138 | 0.8332 | 0.045 ± 0.013 | 0.4998 | 0.871 ± 0.034 | 0.0209
400 | 5 | 0.750 ± 0.174 | 0.8481 | 0.040 ± 0.014 | 0.5179 | 0.877 ± 0.074 | 0.0201
800 | 5 | 0.980 ± 0.221 | 0.6072 | 0.050 ± 0.006 | 0.3649 | 1.014 ± 0.099 | 0.0016
Trend^d^ | | p = 0.1866 | | p = 0.3409 | | p = 0.0016
Female
Exposure Concentration (ppm)
0 | 5 | 0.810 ± 0.168 | | 0.073 ± 0.034 | | 1.053 ± 0.182
50 | 5 | 0.790 ± 0.111 | 0.5632 | 0.036 ± 0.007 | 1.0000 | 1.101 ± 0.138 | 1.0000
100 | 5 | 0.860 ± 0.109 | 0.6483 | 0.079 ± 0.014 | 0.3520 | 1.150 ± 0.147 | 1.0000
200 | 5 | 0.784 ± 0.143 | 0.6821 | 0.041 ± 0.010 | 1.0000 | 0.797 ± 0.060 | 0.5300
400 | 5 | 0.680 ± 0.096 | 0.7014 | 0.038 ± 0.007 | 1.0000 | 1.068 ± 0.023 | 1.0000
800 | 5 | 0.760 ± 0.157 | 0.7149 | 0.046 ± 0.008 | 1.0000 | 1.045 ± 0.086 | 1.0000
Trend | | p = 0.7122 | | p = 0.5505 | | p = 0.9278

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

Table D-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Rats in the Three-month Inhalation Study of 2,3-Pentanedione^a^

| Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (ppm)
0 | 5 | 1.337 ± 0.140 | | 0.102 ± 0.015 | | 0.764 ± 0.043
6.25 | 5 | 0.920 ± 0.117 | 0.9299 | 0.087 ± 0.014 | 0.7629 | 0.883 ± 0.042 | 0.4678
12.5 | 5 | 1.290 ± 0.040 | 0.9666 | 0.096 ± 0.014 | 0.8421 | 0.860 ± 0.071 | 0.5614
25.0 | 5 | 0.840 ± 0.117 | 0.9769 | 0.061 ± 0.008 | 0.8706 | 0.798 ± 0.047 | 0.6005
50.0 | 5 | 1.060 ± 0.117 | 0.9808 | 0.085 ± 0.016 | 0.8829 | 0.845 ± 0.098 | 0.6182
100.0 | 5 | 1.060 ± 0.144 | 0.9836 | 0.145 ± 0.022 | 0.0385 | 0.961 ± 0.133 | 0.1836
Trend^d^ | | p = 0.7620 | | p = 0.0114 | | p = 0.2653
Female
Exposure Concentration (ppm)
0 | 5 | 0.749 ± 0.167 | | 0.040 ± 0.012 | | 0.925 ± 0.078
6.25 | 5 | 0.960 ± 0.143 | 0.3763 | 0.058 ± 0.013 | 0.4978 | 0.851 ± 0.053 | 1.0000
12.5 | 5 | 0.840 ± 0.033 | 0.4456 | 0.046 ± 0.013 | 0.5792 | 0.958 ± 0.201 | 1.0000
25.0 | 5 | 0.730 ± 0.089 | 0.4754 | 0.027 ± 0.006 | 0.6123 | 0.952 ± 0.050 | 1.0000
50.0 | 5 | 0.660 ± 0.066 | 0.4929 | 0.031 ± 0.006 | 0.6322 | 1.207 ± 0.131 | 0.8062
100.0 | 5 | 0.800 ± 0.087 | 0.4954 | 0.080 ± 0.016 | 0.0155 | 1.366 ± 0.117 | 0.1703
Trend | | p = 0.7173 | | p = 0.0357 | | p = 0.0044

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

Table D-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Mice in the Three-month Inhalation Study of Acetoin^a^

| Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (ppm)
0 | 5 | 2.390 ± 0.212 | | 1.511 ± 0.018 | | 1.359 ± 0.051
50 | 5 | 2.380 ± 0.159 | 0.5939 | 1.435 ± 0.024 | 0.9217 | 1.443 ± 0.038 | 0.7267
100 | 5 | 2.420 ± 0.164 | 0.6801 | 1.436 ± 0.043 | 0.9619 | 1.394 ± 0.034 | 0.8502
200 | 5 | 2.380 ± 0.072 | 0.7145 | 1.459 ± 0.030 | 0.9735 | 1.429 ± 0.094 | 0.8921
400 | 5 | 2.120 ± 0.152 | 0.7333 | 1.434 ± 0.022 | 0.9776 | 1.381 ± 0.065 | 0.9120
800 | 5 | 2.570 ± 0.142 | 0.2868 | 1.481 ± 0.016 | 0.9053 | 1.304 ± 0.054 | 0.6758
Trend^d^ | | p = 0.2949 | | p = 0.4292 | | p = 0.1579
Female
Exposure Concentration (ppm)
0 | 5 | 1.790 ± 0.233 | | 1.044 ± 0.030 | | 1.246 ± 0.123
50 | 5 | 1.970 ± 0.160 | 0.3328 | 1.069 ± 0.028 | 1.0000 | 1.072 ± 0.226 | 1.0000
100 | 5 | 1.830 ± 0.117 | 0.3962 | 0.984 ± 0.026 | 1.0000 | 1.599 ± 0.204 | 0.6199
200 | 5 | 2.060 ± 0.185 | 0.2340 | 1.022 ± 0.013 | 1.0000 | 1.452 ± 0.039 | 0.6631
400 | 5 | 1.990 ± 0.230 | 0.2403 | 1.048 ± 0.030 | 1.0000 | 1.305 ± 0.071 | 0.6837
800 | 5 | 2.020 ± 0.097 | 0.2457 | 1.057 ± 0.055 | 1.0000 | 1.427 ± 0.203 | 0.6956
Trend | | p = 0.2092 | | p = 0.5790 | | p = 0.4946

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

Table D-5 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Mice in the Three-month Inhalation Study of 2,3-Pentanedione^a^

| Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (ppm)
0 | 5 | 2.180 ± 0.046 | | 1.416 ± 0.030 | | 1.363 ± 0.057
6.25 | 5 | 2.600 ± 0.130 | 0.0379 | 1.457 ± 0.026 | 0.5393 | 1.555 ± 0.032 | 0.1182
12.5 | 5 | 2.750 ± 0.164 | 0.0457 | 1.455 ± 0.027 | 0.6220 | 1.540 ± 0.035 | 0.2410
25.0 | 5 | 2.650 ± 0.127 | 0.0479 | 1.382 ± 0.044 | 0.6572 | 1.495 ± 0.035 | 0.9191
50.0 | 5 | 2.310 ± 0.166 | 0.0477 | 1.416 ± 0.039 | 0.6765 | 1.372 ± 0.065 | 1.0000
100.0 | 5 | 2.460 ± 0.180 | 0.0488 | 1.344 ± 0.027 | 0.6895 | 1.636 ± 0.195 | 0.2213
Trend^d^ | | p = 0.6263 | | p = 0.9876 | | p = 0.6767
Female
Exposure Concentration (ppm)
0 | 5 | 2.100 ± 0.376 | | 1.055 ± 0.009 | | 1.545 ± 0.142
6.25 | 5 | 2.000 ± 0.092 | 0.7300 | 1.005 ± 0.016 | 0.9148 | 1.681 ± 0.086 | 0.8417
12.5 | 5 | 1.780 ± 0.086 | 0.8133 | 0.967 ± 0.026 | 0.9580 | 1.634 ± 0.142 | 0.9446
25.0 | 5 | 1.930 ± 0.291 | 0.8441 | 1.074 ± 0.043 | 0.9695 | 1.440 ± 0.149 | 0.9712
50.0 | 5 | 1.880 ± 0.174 | 0.8577 | 1.057 ± 0.017 | 0.9746 | 1.670 ± 0.097 | 0.7210
100.0 | 5 | 1.760 ± 0.110 | 0.8687 | 0.875 ± 0.023 | 0.9784 | 1.940 ± 0.403 | 0.3353
Trend | | p = 0.8296 | | p = 0.9987 | | p = 0.2414

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025)