# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected from each sentinel animal and allowed to clot, and the serum was separated. All samples were processed appropriately with serology testing performed in-house (acetoin) or by IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, (both chemicals) for determination of the presence of pathogens. Evaluation for endoparasites was performed in-house by the testing laboratory.

The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed (Table C-1, Table C-2, Table C-3, Table C-4).

## C.2 Results

Rats: All test results were negative for acetoin and 2,3-pentanedione.

Mice: All test results were negative for acetoin and 2,3-pentanedione.

Table C-1 Methods and Results for Sentinel Animal Testing in Male and Female Rats in the Two-week and Three-month Studies of Acetoin

Collection Time Points | Two-week Study | Three-month Study
Collection Time Points | Study Termination | Three Weeks | Study Termination
Number Examined (Males/Females) | 5/5 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | NT | − | −
Mycoplasma pulmonis | NT | − | −
Parvo NS-1 | NT | − | −
Pneumonia virus of mice (PVM) | NT | − | −
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | NT | − | −
Rat minute virus (RMV) | NT | − | −
Rat parvo virus (RPV) | NT | − | −
Rat theilovirus (RTV) | NT | − | −
Sendai | NT | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | NT | − | −
Toolan’s H-1 | NT | − | −
In-house Evaluation
Mycoplasma pulmonis | − | NT | NT
Pneumonia virus of mice (PVM) | − | NT | NT
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | − | NT | NT
Rat parvo virus (RPV) | − | NT | NT
Sendai | − | NT | NT
Endoparasite evaluation (evaluation of perianal surface for Syphacia sp.) | − | − | −

NT = not tested; − = negative.

Table C-2 Methods and Results for Sentinel Animal Testing in Male and Female Mice in the Two-week and Three-month Studies of Acetoin

Collection Time Points | Two-week Study | Three-month Study
Collection Time Points | Study Termination | Three Weeks | Study Termination
Number Examined (Males/Females) | 5/5 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus | NT | − | −
Epizootic diarrhea of infant mice (EDIM) | NT | − | −
Lymphocytic choriomeningitis virus (LCMV) | NT | − | −
Mycoplasma pulmonis | NT | − | −
Mouse hepatitis virus (MHV) | NT | − | −
Mouse norovirus (MNV) | NT | − | −
Parvo NS-1 | NT | − | −
Mouse parvovirus (MPV) | NT | − | −
Minute virus of mice (MVM) | NT | − | −
Pneumonia virus of mice (PVM) | NT | − | −
Reovirus (REO3) | NT | − | −
Sendai | NT | − | −
Theiler’s murine encephalomyelitis virus (TMEV) GDVII | NT | − | −
In-house Evaluation
Mycoplasma pulmonis | − | NT | NT
Mouse hepatitis virus (MHV) | − | NT | NT
Mouse parvovirus (MPV) | − | NT | NT
Pneumonia virus of mice (PVM) | − | NT | NT
Sendai | − | NT | NT
Theiler’s murine encephalomyelitis virus (TMEV) GDVII | − | NT | NT
Endoparasite evaluation (evaluation of perianal surface for Syphacia sp.) | − | − | −

NT = not tested; − = negative.

Table C-3 Methods and Results for Sentinel Animal Testing in Male and Female Rats in the Three-month Study of 2,3-Pentanedione

Collection Time Points | Three Weeks | Study Termination
Number Examined (Males/Females) | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | – | –
Mycoplasma pulmonis | – | –
Pneumonia virus of mice (PVM) | – | –
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | – | –
Rat minute virus (RMV) | – | –
Rat parvo virus (RPV) | – | –
Rat theilovirus (RTV) | – | –
Sendai | – | –
Toolan’s H-1 | – | –
In-house Evaluation
Endoparasite evaluation (evaluation of perianal surface for Syphacia sp.) | – | –

– = negative.

Table C-4 Methods and Results for Sentinel Animal Testing in Male and Female Mice in the Three-month Study of 2,3-Pentanedione

Collection Time Points | Three Weeks | Study Termination
Number Examined (Males/Females) | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus | – | –
Epizootic diarrhea of infant mice (EDIM) | – | –
Lymphocytic choriomeningitis virus (LCMV) | – | –
Mycoplasma pulmonis | – | –
Mouse hepatitis virus (MHV) | – | –
Mouse norovirus (MNV) | – | –
Mouse parvovirus (MPV) | – | –
Minute virus of mice (MVM) | – | –
Pneumonia virus of mice (PVM) | – | –
Reovirus (REO3) | – | –
Sendai | – | –
Theiler’s murine encephalomyelitis virus (TMEV) GDVII | – | –
In-house Evaluation
Endoparasite evaluation (evaluation of perianal surface for Syphacia sp.) | – | –

– = negative.