# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table B-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 4.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
α-Pantothenic Acid | 10 mg | α-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | α-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration in the Two-week and Three-month Studies of Acetoin

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.73 ± 0.498 | 14.1–15.7 | 8
Crude Fat (% by Weight) | 8.2 ± 0.251 | 7.7–8.5 | 8
Crude Fiber (% by Weight) | 9.01 ± 0.995 | 7.1–10.6 | 8
Ash (% by Weight) | 5.189 ± 0.158 | 4.99–5.43 | 8
Amino Acids (% of Total Diet)
Arginine | 0.806 ± 0.074 | 0.67–0.97 | 30
Cystine | 0.220 ± 0.021 | 0.15–0.25 | 30
Glycine | 0.702 ± 0.037 | 0.62–0.8 | 30
Histidine | 0.341 ± 0.069 | 0.27–0.68 | 30
Isoleucine | 0.548 ± 0.039 | 0.43–0.66 | 30
Leucine | 1.096 ± 0.062 | 0.96–1.24 | 30
Lysine | 0.070 ± 0.103 | 0.31–0.86 | 30
Methionine | 0.409 ± 0.041 | 0.26–0.49 | 30
Phenylalanine | 0.623 ± 0.046 | 0.471–0.72 | 30
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 30
Tryptophan | 0.156 ± 0.026 | 0.11–0.2 | 30
Tyrosine | 0.423 ± 0.065 | 0.28–0.54 | 30
Valine | 0.666 ± 0.039 | 0.55–0.73 | 30
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.939 ± 0.233 | 3.49–4.55 | 30
Linolenic | 0.306 ± 0.030 | 0.21–0.368 | 30
Vitamins
Vitamin A (IU/kg) | 3,700 ± 80.96 | 2,780–4,780 | 8
α-Tocopherol (ppm) | 2,376 ± 12,602 | 13.6–69,100 | 30
Thiamine (ppm)^a^ | 7.6 ± 1.80 | 5.3–11.0 | 8
Riboflavin (ppm) | 8.17 ± 2.792 | 4.2–17.5 | 30
Niacin (ppm) | 79.19 ± 8.497 | 66.4–98.2 | 30
Pantothenic Acid (ppm) | 26.33 ± 10.87 | 17.4–81.0 | 30
Pyridoxine (ppm)^a^ | 9.719 ± 2.018 | 6.44–14.3 | 30
Folic Acid (ppm) | 1.60 ± 0.440 | 1.15–3.27 | 30
Biotin (ppm) | 0.330 ± 0.097 | 0.2–0.704 | 30
B_12_ (ppb) | 50.06 ± 34.34 | 18.3–174.0 | 30
Choline (as chloride) (ppm) | 2,572 ± 634 | 1,160–3,790 | 30
Minerals
Calcium (%) | 0.904 ± 0.032 | 0.857–0.96 | 8
Phosphorus (%) | 0.548 ± 0.026 | 0.504–0.588 | 8
Potassium (%) | 0.668 ± 0.287 | 0.626–0.733 | 30
Chloride (%) | 0.391 ± 0.044 | 0.3–0.517 | 30
Sodium (%) | 0.194 ± 0.027 | 0.153–0.283 | 30
Magnesium (%) | 0.217 ± 0.053 | 0.185–0.49 | 30
Iron (ppm) | 190.43 ± 36.11 | 135–311 | 30
Manganese (ppm) | 50.02 ± 9.27 | 21.0–73.1 | 30
Zinc (ppm) | 56.81 ± 25.25 | 42.5–184 | 30
Copper (ppm) | 7.61 ± 2.46 | 3.21–16.3 | 30
Iodine (ppm) | 0.514 ± 0.217 | 0–0.972 | 30
Chromium (ppm) | 1.119 ± 1.157 | 0.33–3.97 | 30
Cobalt (ppm) | 0.219 ± 0.150 | 0.086–0.864 | 30

^a^ As hydrochloride.

Table B-4 Nutrient Composition of NTP-2000 Rat and Mouse Ration in the Three-month Studies of 2,3-Pentanedione

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.7 ± 0.383 | 14.2–15.0 | 4
Crude Fat (% by Weight) | 8.45 ± 0.173 | 8.3–8.7 | 4
Crude Fiber (% by Weight) | 9.13 ± 0.606 | 8.57–9.96 | 4
Ash (% by Weight) | 5.168 ± 0.118 | 5.0–5.26 | 4
Amino Acids (% of Total Diet)
Arginine | 0.806 ± 0.074 | 0.67–0.97 | 30
Cystine | 0.220 ± 0.021 | 0.15–0.25 | 30
Glycine | 0.702 ± 0.037 | 0.62–0.8 | 30
Histidine | 0.341 ± 0.069 | 0.27–0.68 | 30
Isoleucine | 0.548 ± 0.039 | 0.43–0.66 | 30
Leucine | 1.096 ± 0.062 | 0.96–1.24 | 30
Lysine | 0.070 ± 0.103 | 0.31–0.86 | 30
Methionine | 0.409 ± 0.041 | 0.26–0.49 | 30
Phenylalanine | 0.623 ± 0.046 | 0.471–0.72 | 30
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 30
Tryptophan | 0.156 ± 0.026 | 0.11–0.2 | 30
Tyrosine | 0.423 ± 0.065 | 0.28–0.54 | 30
Valine | 0.666 ± 0.039 | 0.55–0.73 | 30
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.939 ± 0.233 | 3.49–4.55 | 30
Linolenic | 0.306 ± 0.030 | 0.21–0.368 | 30
Vitamins
Vitamin A (IU/kg) | 3,800 ± 56.20 | 3,350–4,620 | 4
α-Tocopherol (ppm) | 2,376 ± 12,602 | 13.6–69,100 | 30
Thiamine (ppm)^a^ | 7.65 ± 0.802 | 6.7–8.6 | 4
Riboflavin (ppm) | 8.17 ± 2.792 | 4.2–17.5 | 30
Niacin (ppm) | 79.19 ± 8.497 | 66.4–98.2 | 30
Pantothenic Acid (ppm) | 26.33 ± 10.87 | 17.4–81.0 | 30
Pyridoxine (ppm)^a^ | 9.719 ± 2.018 | 6.44–14.3 | 30
Folic Acid (ppm) | 1.56 ± 0.440 | 1.15–3.27 | 30
Biotin (ppm) | 0.330 ± 0.097 | 0.2–0.704 | 30
B_12_ (ppb) | 50.06 ± 34.34 | 18.3–174.0 | 30
Choline (as Chloride) (ppm) | 2,572 ± 634 | 1,160–3,790 | 30
Minerals
Calcium (%) | 0.940 ± 0.063 | 0.856–0.994 | 4
Phosphorus (%) | 0.587 ± 0.042 | 0.531–0.63 | 4
Potassium (%) | 0.668 ± 0.287 | 0.626–0.733 | 30
Chloride (%) | 0.391 ± 0.044 | 0.3–0.517 | 30
Sodium (%) | 0.194 ± 0.027 | 0.153–0.283 | 30
Magnesium (%) | 0.217 ± 0.053 | 0.185–0.49 | 30
Iron (ppm) | 190.43 ± 36.11 | 135–311 | 30
Manganese (ppm) | 50.02 ± 9.27 | 21.0–73.1 | 30
Zinc (ppm) | 56.81 ± 25.25 | 42.5–184 | 30
Copper (ppm) | 7.61 ± 2.46 | 3.21–16.3 | 30
Iodine (ppm) | 0.514 ± 0.217 | 0–0.972 | 30
Chromium (ppm) | 1.119 ± 1.157 | 0.33–3.97 | 30
Cobalt (ppm) | 0.219 ± 0.150 | 0.086–0.864 | 30

^a^ As hydrochloride.

Table B-5 Contaminant Levels in NTP-2000 Rat and Mouse Ration in the Two-week and Three-month Studies of Acetoin

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.262 ± 0.037 | 0.183–0.307 | 8
Cadmium (ppm) | 0.066 ± 0.012 | 0.056–0.0957 | 8
Lead (ppm) | 0.190 ± 0.282 | 0.0789–0.887 | 8
Mercury (ppm) | 0.017 ± 0.003 | 0.012–0.021 | 8
Selenium (ppm) | 0.211 ± 0.039 | 0.165–0.272 | 8
Aflatoxins (ppb)^a^ | <5.0 | – | 8
Nitrate Nitrogen (ppm)^b^ | 22.68 ± 9.82 | 10.0–35.9 | 8
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 8
BHA (ppm)^a,c^ | <1.0 | – | 8
BHT (ppm)^a,c^ | <1.0 | – | 8
Aerobic Plate Count (CFU/g) | <10 | – | 8
Coliform (MPN/g) | <3 | – | 8
Escherichia coli (MPN/g) | <10 | – | 8
Salmonella (MPN/g) | Negative | – | 8
Total Nitrosamines (ppb)^d^ | 10.58 ± 4.97 | 2.0–16.2 | 8
N-Nitrosodimethylamine (ppb)^d^ | 4.75 ± 3.785 | 1.0–11.1 | 8
N-Nitrosopyrrolidine (ppb)^d^ | 6.96 ± 3.137 | 1.0–11.0 | 8
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 8
β-BHC^a^ | <0.02 | – | 8
γ-BHC^a^ | <0.01 | – | 8
δ-BHC^a^ | <0.01 | – | 8
Heptachlor^a^ | <0.01 | – | 8
Aldrin^a^ | <0.01 | – | 8
Heptachlor Epoxide^a^ | <0.01 | – | 8
DDE^a^ | <0.01 | – | 8
DDD^a^ | <0.01 | – | 8
DDT^a^ | <0.01 | – | 8
HCB^a^ | <0.01 | – | 8
Mirex^a^ | <0.01 | – | 8
Methoxychlor^a^ | <0.05 | – | 8
Dieldrin^a^ | <0.01 | – | 8
Endrin^a^ | <0.01 | – | 8
Telodrin^a^ | <0.01 | – | 8
Chlordane^a^ | <0.05 | – | 8
Toxaphene^a^ | <0.01 | – | 8
Estimated PCBs^a^ | <0.20 | – | 8
Ronnel^a^ | <0.01 | – | 8
Ethion^a^ | <0.02 | – | 8
Trithion^a^ | <0.05 | – | 8
Diazinon^a^ | <0.10 | – | 8
Methyl Chlorpyrifos | 0.133 ± 0.102 | 0.02–0.3 | 8
Methyl Parathion^a^ | <0.02 | – | 8
Ethyl Parathion^a^ | <0.02 | – | 8
Malathion | 0.073 ± 0.078 | 0.02–0.234 | 8
Endosulfan I^a^ | <0.01 | – | 8
Endosulfan II^a^ | <0.01 | – | 8
Endosulfane Sulfate^a^ | <0.03 | – | 8

All samples were irradiated. BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

Table B-6 Contaminant Levels in NTP-2000 Rat and Mouse Ration in the Three-month Studies of 2,3-Pentanedione

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.267 ± 0.048 | 0.222–0.313 | 4
Cadmium (ppm) | 0.051 ± 0.002 | 0.222–0.313 | 4
Lead (ppm) | 0.090 ± 0.008 | 0.079–0.098 | 4
Mercury (ppm) | 0.018 ± 0.004 | 0.012–0.022 | 4
Selenium (ppm) | 0.182 ± 0.017 | 0.166–0.202 | 4
Aflatoxins (ppb)^a^ | <5.0 | – | 4
Nitrate Nitrogen (ppm)^b^ | 10.38 ± 0.75 | 10.0–11.5 | 4
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 4
BHA (ppm)^a,c^ | <1.0 | – | 4
BHT (ppm)^c^ | 1.51 ± 1.02 | 1.0–3.04 | 4
Aerobic Plate Count (CFU/g) | 12.5 ± 5.0 | 10.0–20.0 | 4
Coliform (MPN/g) | <3 | – | 4
Escherichia coli (MPN/g) | <10 | – | 4
Salmonella (MPN/g) | Negative | – | 4
Total Nitrosamines (ppb)^d^ | 7.12 ± 2.71 | 3.68–9.7 | 4
N-Nitrosodimethylamine (ppb)^d^ | 2.01 ± 1.93 | 1.0–4.9 | 4
N-Nitrosopyrrolidine (ppb)^d^ | 5.12 ± 2.61 | 2.66–8.7 | 4
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 4
β-BHC^a^ | <0.02 | – | 4
γ-BHC^a^ | <0.01 | – | 4
δ-BHC^a^ | <0.01 | – | 4
Heptachlor^a^ | <0.01 | – | 4
Aldrin^a^ | <0.01 | – | 4
Heptachlor Epoxide^a^ | <0.01 | – | 4
DDE^a^ | <0.01 | – | 4
DDD^a^ | <0.01 | – | 4
DDT^a^ | <0.01 | – | 4
HCB^a^ | <0.01 | – | 4
Mirex^a^ | <0.01 | – | 4
Methoxychlor^a^ | <0.05 | – | 4
Dieldrin^a^ | <0.01 | – | 4
Endrin^a^ | <0.01 | – | 4
Telodrin^a^ | <0.01 | – | 4
Chlordane^a^ | <0.05 | – | 4
Toxaphene^a^ | <0.01 | – | 4
Estimated PCBs^a^ | <0.20 | – | 4
Ronnel^a^ | <0.01 | – | 4
Ethion^a^ | <0.02 | – | 4
Trithion^a^ | <0.05 | – | 4
Diazinon^a^ | <0.10 | – | 4
Methyl Chlorpyrifos | 0.044 ± 0.020 | 0.02–0.63 | 4
Methyl Parathion^a^ | <0.02 | – | 4
Ethyl Parathion^a^ | <0.02 | – | 4
Malathion | 0.112 ± 0.065 | 0.067–0.207 | 4
Endosulfan I^a^ | <0.01 | – | 4
Endosulfan II^a^ | <0.01 | – | 4
Endosulfane Sulfate^a^ | <0.03 | – | 4

All samples were irradiated. BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.