# Appendix A Chemical Characterization and Generation of Chamber Concentrations

## A.1 Procurement and Characterization

Acetoin was obtained from Sigma-Aldrich, Inc. (Milwaukee, WI) in one lot (09118JH) and was used in the 2-week and 3-month inhalation studies of acetoin. 2,3-Pentanedione, obtained from Sigma-Aldrich, Inc. (Milwaukee, WI) in one lot (MKBB7504), was used in the 3-month inhalation studies of 2,3-pentanedione. Identity and purity analyses of the two test chemicals were conducted by the analytical chemistry and animal study laboratories at Battelle Toxicology Northwest (Richland, WA). Reports on analyses performed in support of the acetoin and 2,3-pentanedione studies are on file at the National Institute of Environmental Health Sciences.

### A.1.1 Acetoin

Lot 09118JH, a solid white powder, was identified as acetoin by Chemir Analytical Services (Maryland Heights, MO) using Fourier transform infrared (IR) and ^1^H nuclear magnetic resonance (NMR) spectroscopies (Figure A-1, Figure A-2). All spectra were consistent with the reference spectra from a commercially procured standard (Sigma-Aldrich, Inc.; lot 01296MH) and matched the anticipated dimer structure of acetoin. Elemental analysis was performed by Galbraith Laboratories, Inc. (Knoxville, TN) to aid in identification. The relative amount of carbon (54.33%) and hydrogen (9.09%) were within 1% of the theoretical values (54.53% and 9.15%, respectively). Additionally, sulfur was detected (0.09%) and was within 1% of the theoretical value (0.00%).

Acetoin was received as a solid dimer and was thermally cracked to form the liquid monomer used as the exposure material. Monomer test materials were stored heated (approximately 90°F) to prevent reformation of solid dimer. Expiration dates of 14 days (2-week studies) or 26 days (3-month studies) after cracking were assigned to batches of prepared liquid monomer. The purity of lot 09118JH in the solid and liquid form was determined by the study laboratory using gas chromatography (GC) with flame ionization detection (FID), and impurities were identified using GC with mass spectrometry (MS) detection. The moisture content of the solid dimer was determined by Chemir Analytical Services using Karl Fischer titration.

For lot 09118JH, the purity of the solid dimer was determined to be 99.4% ± 0.2(sd)%, and the purity of the liquid monomer was determined to be 99.2% ± 0.2% using GC/FID (Table A-1, System A). Three reportable impurities with peak areas ≥0.1% of the total integrated peak area were detected in the solid form, and two of the three impurities were detected in the liquid form of acetoin. Using GC/MS, the impurities were identified as 2,3-butanedione (approximately 0.1%), acetic acid (approximately 0.1%, solid only), and di-2-butan-3-one ether (0.3% to 0.4%) (Table A-1, System B). Karl Fischer titration indicated <0.1% water in the solid test article. The overall purity of lot 09118JH was determined to be >99%.

To ensure stability, bulk acetoin was stored in sealed white plastic buckets at 5°C. Reanalyses of the bulk chemical were performed by the study laboratory prior to the 2-week studies; no degradation was detected by GC/FID (Table A-1, System A). Prior to the 3-month studies, the solid dimer appeared moist compared to its appearance prior to the 2-week studies; the chemical was dried with nitrogen before cracking and reanalyzing. Reanalyses of the bulk chemical were performed by the study laboratory prior to and after the 3-month studies; no degradation was detected by GC/FID (Table A-1, System A).

### A.1.2 2,3-Pentanedione

Lot MKBB7504, a clear yellow liquid, was identified as 2,3-pentanedione by the study laboratory using IR spectroscopy and by Chemir Analytical Services using ^1^H NMR spectroscopy (Figure A-3, Figure A-4). All spectra were consistent with the anticipated structure of 2,3-pentanedione. Elemental analysis was performed by Galbraith Laboratories, Inc. (Knoxville, TN) to aid in identification. The relative amount of carbon (58.00%) and hydrogen (7.95%) were within 2% of the theoretical values (59.98% and 8.05%, respectively).

The purity of lot MKBB7504 was determined by the study laboratory using GC/FID. The moisture content was determined by Chemir Analytical Services using Karl Fischer titration.

For lot MKBB7504, the purity was determined to be 98.20% ± 0.02% using GC/FID (Table A-1, System C). Four reportable impurities with areas ≥0.1% were detected. Two of these were identified as 2,3-butanedione (0.2%) and 3,4-hexanedione (0.3%); no match was found for the other two impurities present at 0.1% and 0.7%. There was some indication that the impurity present at 0.7% might have been the enol form of 2,3-pentanedione. Karl Fischer titration yielded a water content of 0.75%. The overall purity of lot MKBB7504 was determined to be >98%.

To ensure stability, bulk 2,3-pentanedione was stored in sealed metal pails at 5°C. Reanalyses of the bulk chemical were performed by the study laboratory prior to and after the 3-month studies; no degradation was detected by GC/FID (Table A-1, System C).

## A.2 Vapor Generation and Exposure System

A diagram of the vapor generation and delivery system used in the studies is shown in Figure A-5. The test chemical, cracked acetoin or 2,3-pentanedione, was pumped from a 4-liter glass reservoir into a heated glass vaporizer column (approximately 250°F for acetoin, approximately 120°F for 2,3-pentanedione) filled with glass beads and wrapped with heat tape. For the acetoin studies, formation of solid dimer was prevented by maintaining the generator reservoir at approximately 90°F and by daily rinsing of the liquid pump with water from an additional reservoir. For all studies, a waste collection flask was connected to the bottom of the vaporizer column to collect residual chemical not completely vaporized in the column.

Preheated nitrogen (approximately 255°F for acetoin, approximately 130°F for 2,3-pentanedione) entered the vaporizer column from below, vaporized the test chemical, and carried the vapor from the generator cabinet to the distribution manifold through a heated chemical transport line (approximately 110°F for acetoin, approximately 120°F for 2,3-pentanedione). The nitrogen-chemical mixture was diluted with heated air (approximately 110°F for acetoin, approximately 120°F for 2,3-pentanedione) before entering the distribution manifold. Concentration in the manifold was determined by the chemical pump rate, nitrogen flow rate, and dilution airflow rate. Pressure in the distribution manifold was kept fixed to ensure constant flow rates through the manifold and into all exposure chambers as the flow of vapor to each chamber was adjusted.

Individual heated Teflon delivery lines carried the diluted acetoin or 2,3-pentanedione vapor from the distribution manifold to three-way exposure valves at the chamber inlets. The chamber exposure valves diverted vapor delivery to the exposure chamber exhaust until the generation system stabilized and exposure could proceed. The flow rate to each chamber was controlled by a metering valve at the distribution manifold. To initiate exposure, the chamber exposure valves were rotated to allow the acetoin or 2,3-pentanedione vapor to flow to each exposure chamber inlet duct, where it was diluted with conditioned air to achieve the desired exposure concentration. Conditioned air was a temperature-controlled and filtered mix of air derived from each exposure chamber’s wet and dry air duct supplies. The temperature was adjusted by passage over a temperature-controlled radiator after sequential treatment with Purafil, charcoal, and HEPA (high efficiency particulate air) filters. Target dew point temperatures of the wet and dry ducts were 60°F and 40°F, respectively. Air for the ducts was obtained from the building air supply and was either passed over chillers to lower the dew point (dry duct) or injected with steam to raise it (wet duct).

The study laboratory designed the inhalation exposure chamber (built by Lab Products, Inc., Seaford, DE) so that uniform vapor concentrations could be maintained throughout the chamber with catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small particle detector (Model 3022A; TSI, Inc., St. Paul, MN) was used with and without animals in the exposure chambers to ensure that acetoin or 2,3-pentanedione vapors, and not aerosols, were produced. Particle counts <200 particles/cm^3^ are typical of an exposure atmosphere when no generation is occurring. Particle counts above this level, especially if the counts increase with exposure concentration and are above the level during the off-exposure period, suggest a contribution to the aerosol concentration from the generation system. No particle counts above the minimum resolvable level were detected.

## A.3 Vapor Concentration Monitoring

Exposure chamber and room concentrations of acetoin and 2,3-pentanedione were monitored using online GC/FID for the 2-week acetoin studies, the 3-month acetoin studies, and the 3-month 2,3-pentanedione studies (Table A-1, System D, E, and F, respectively). Approximately every 20 minutes during each 6-hour exposure period, samples were drawn through stainless steel (acetoin) or Teflon (2,3-pentanedione) tubing connected to each exposure chamber’s sampling line using a 16-port Hastelloy-C stream-select valve that directs a continuous stream of sampled atmosphere to a 6-port Hastelloy-C gas-sampling valve with a 1-mL Silicosteel sample loop. Both valves and the sampling loop were mounted in a dedicated valve oven (approximately 150°C for acetoin, approximately 175°C for 2,3-pentanedione). A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and GC allowed for digital measurement of sample flow.

The online GCs were checked throughout each exposure day for instrument drift against online standard vapors of acetoin or 2,3-pentanedione supplied by a permeation tube standard generator (KIN-TEK Models 491 or C0395, KIN-TEK Analytical, Inc., La Marque, TX). The online GCs were calibrated as required to meet acceptance criteria. Calibration was performed by correlating the peak area at the time of sampling with grab sample concentration data collected with silica gel sorbent gas-sampling tubes [ORBO™–53 (acetoin) or ORBO™–52 (2,3-pentanedione), Supelco, Inc., Bellefonte, PA]. The known volumes of chamber atmospheres were sampled from each chamber at a constant flow rate ensured by a calibrated critical orifice. Adsorbed test chemicals were extracted with acetone:water:methanol (95:4:1) (acetoin) or acetone (2,3-pentanedione) and analyzed using off-line GC/FID for acetoin (Table A-1, System G) or 2,3-pentanedione (Table A-1, System H); 2-methyl-1-propanol was used as an internal standard (ISTD) in both extraction vehicles. The off-line GCs were calibrated with gravimetrically prepared standard solutions of acetoin or 2,3-pentanedione containing the ISTD in the appropriate extraction vehicle.

Summaries of the chamber vapor concentrations are given in Table A-2 through Table A-4. The mean relative errors (RE) were within the acceptance criteria of 10% for all exposure groups for all studies. For the 2-week acetoin studies, the mean exposure concentrations were within 3% of the respective target concentrations, and the number of acceptable samples ranged from 94% to 100% (Table A-2). For the 3-month acetoin studies, the mean exposure concentrations were within 1% of the respective target concentrations, and the number of acceptable samples ranged from 96% to 100% (Table A-3). For the 3-month 2,3-pentanedione studies, the mean exposure concentrations were within 1% of the respective target concentrations, and the number of acceptable samples ranged from 99% to 100% (Table A-4).

## A.4 Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with (all studies) and without (3-month studies) animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9 minutes. For rats and mice in the 2-week acetoin studies with animals present, T_90_ values ranged from 13 to 19 minutes; T_10_ values ranged from 10 to 11 minutes. For rats and mice in the 3-month acetoin studies, T_90_ values ranged from 8 to 10 minutes without animals present and from 9 to 11 minutes with animals; T_10_ values ranged from 8 to 11 minutes without animals present and from 11 to 14 minutes with animals. For rats and mice in the 3-month 2,3-pentanedione studies, T_90_ values ranged from 9 to 10 minutes without animals present and from 9 to 12 minutes with animals; T_10_ values ranged from 9 to 10 minutes without animals present and from 11 to 12 minutes with animals. A T_90_ value of 12 minutes was selected for both chemicals for all studies.

The persistence of acetoin in the rat and mouse chambers after vapor delivery ended was determined by monitoring the concentration in the 800 ppm chambers in the 2-week and 3-month studies with (all studies) and without (3-month studies) animals present in the chambers. In the 2-week studies, the time for the chamber concentration to decay to <1% of the target concentration after vapor generation was terminated (T_1_) was approximately 47 minutes with animals present. In the 3-month studies, T_1_ was approximately 22 minutes without animals present; when animals were present, the chamber concentration did not drop to below 1% of the target concentration until after the chamber doors were opened to perform animal care activities (up to 134 minutes after shutdown).

The persistence of 2,3-pentanedione in the rat and mouse chambers after vapor delivery ended was determined by monitoring the concentration in the 100 ppm chambers in the 3-month studies, with and without animals present. In the 3-month studies, the concentration decreased to 1% of the target concentration within approximately 23 minutes without animals present and within approximately 32 minutes with animals present.

The uniformity of acetoin or 2,3-pentanedione vapor concentration without animals present in the chambers was evaluated before the 3-month studies began. In addition, concentration uniformity with animals present in the chambers was measured once during the 2-week and 3-month studies. The vapor concentration was measured using an online GC with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line for the 2-week acetoin studies, 3-month acetoin studies, and 3-month 2,3-pentanedione studies (Table A-1, System D, E, and F, respectively). For all acetoin studies, and prior to the 3-month 2,3-pentanedione studies, concentrations were measured at 12 chamber positions, one in front and one in back for each of the six possible animal cage positions per chamber. During the 3-month 2,3-pentanedione studies, concentrations were measured only at the regular monitoring port and from chamber positions where animals were present. Chamber concentration uniformity was maintained throughout the studies; uniformity measurements were all within the acceptable criterion of <5% of the relative standard deviation (RSD).

To measure stability and purity of the test chemicals in the generation and delivery system, samples of the test atmosphere from the distribution lines and low- and high-exposure concentration chambers for each species were collected during the first and last hours of generation prior to the 3-month studies without animals present and during the 2-week and 3-month studies with animals present. The atmosphere samples were collected with sorbent gas-sampling tubes containing silica gel (ORBO™–53, Supelco, Inc., Bellefonte, PA) followed by a tube containing activated coconut charcoal (ORBO™–32, Supelco, Inc., Bellefonte, PA). Grab samples were collected from the bulk chemical and generator reservoir for all studies of both test articles. Acetoin and 2,3-pentanedione were stable under the generation and exposure conditions used during the studies. No evidence of degradation of acetoin or 2,3-pentanedione was noted in any part of the exposure system in any of the samples collected prior to or during the 2-week and 3-month studies. Stability in the generator reservoir was determined to be up to 15 days for acetoin (after cracking) and up to 21 days for 2,3-pentanedione.

For acetoin, the test chemical was extracted from the sorbent tubes with acetone:water:methanol (95:4:1) and analyzed using GC/FID (Table A-1, System I). To assess whether impurities or degradation products co-eluted with acetoin or the solvent mixture, a second GC/FID analysis was performed using System I with a less polar column (DB-5, 30 m × 0.53 mm internal diameter, 1.5 µm film, J&W Scientific, Folsom, CA) than the polar DB WAXetr column to provide alternate separation characteristics. The additional purity analyses of the bulk chemical and the test article in the generator reservoir were conducted by GC/FID (Table A-1, System K). During the 2-week and 3-month studies of acetoin, the impurities 2,3-butanedione, acetic acid, 3-methyl-2,4-pentanedione, and isomers of di-2-butan-3-one ether were detected in the atmosphere and generator reservoir samples with areas generally >0.1% and <1% of the total peak area. No additional impurities were detected with analyses using the less polar column.

For 2,3-pentanedione, the test chemical was extracted from the sorbent tubes with acetone and analyzed using GC/FID (Table A-1, System J). Duplicate samples were collected and extracted with dimethylformamide to assess for impurities or degradation products that co-elute with acetone. The additional purity analyses of the bulk chemical and the test article in the generator reservoir were conducted by GC/FID (Table A-1, System H). During the 3-month studies of 2,3-pentanedione, the impurities 2,3-butanedione, 3,4-hexanedione, acetaldehyde, paraldehyde, acetic acid, and five unknowns were detected in the atmosphere and generator reservoir samples with areas generally >0.1% and <1% of the total peak area, except for one unknown peak with an area of approximately 2.2% to 3.5%.

To measure stability of the test chemicals in the exposure system, concentrations in all exposure chambers were monitored during 3 days of test generation prior to the 3-month studies of acetoin and 2,3-pentanedione using online GC/FID (Table A-1, System E and F, respectively). The mean concentrations for all chambers for all studies met the acceptance criteria of being within ±10% of the target concentration with an RSD of ≤10%. For acetoin, the mean exposure concentrations were within 2% of the target concentrations with an RSD ranging from 3% to 5%. For 2,3-pentanedione, the mean exposure concentrations were within 2% of the target concentrations with an RSD ranging from 2% to 4%.

Table A-1 Gas Chromatography Systems Used in the Two-week and Three-month Inhalation Studies of Acetoin and 2,3-Pentanedione

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization (250°C) | Restek Stabilwax^®^-DA (30 m × 0.25 mm ID, 0.25 µm film thickness) | Helium at 1.5 mL/minute | 40°C for 3 minutes, then increasing 6°C/minute to 240°C, then held for 5 minutes at 240°C
System B
Mass spectrometry with electron impact ionization (selective ion monitoring) | Restek Stabilwax^®^-DA, (30 m × 0.25 mm ID, 0.50 µm film thickness) | Helium at 1.5 mL/minute | 40°C for 3 minutes, then 6°C/minute to 240°C, held for 5 minutes
System C
Flame ionization (250°C) | Restek Rtx^®^-Wax, (30 m × 0.25 mm ID, 0.50 µm film thickness) | Helium at 1.0 mL/minute | 40°C for 2 minutes, then 6°C/minute to 230°C, held for 10 minutes
System D
Flame ionization^a^ | J&W DB-5, (15 m × 0.53 mm ID, 1.5 µm film thickness) | Nitrogen at 25 mL/minute | Isothermal at 45°C
System E
Flame ionization (250°C) | J&W DB-WAXetr, (15 m × 0.53 mm ID, 1.0 µm film thickness) | Nitrogen at 25 mL/minute | Isothermal at 80°C
System F
Flame ionization (250°C) | Restek Stabilwax^®^, (15 m × 0.53 mm ID, 2.0 µm film thickness) | Nitrogen at 25 mL/minute | Isothermal at 70°C or lowered to 35°C for better separation
System G
Flame ionization (250°C) | J&W DB-WAXetr, (30 m × 0.53 mm ID, 1.5 µm film thickness) | Helium at 7 mL/minute | 45°C for 1 minute, then 6°C/minute to 120°C, then 15°C/minute to 180°C, held for 2 minutes
System H
Flame ionization (250°C) | Restek Rtx^®^-Wax, (30 m × 0.25 mm ID, 0.25 µm film thickness) | Helium at 1.5 mL/minute | 40°C for 2 minutes, then 5°C/minute to 65°C, then 20°C/minute to 180°C, held for 2 minutes
System I
Flame ionization (250°C) | J&W DB-WAXetr, (30 m × 0.53 mm ID, 1.5 µm film thickness) | Helium at 7 mL/minute | 40°C for 4 (2-week studies) or 2 (3-month studies) minutes, then 6°C/minute to 235°C, held for 5 minutes
System J
Flame ionization (250°C) | Restek Rtx^®^-Wax, (30 m × 0.25 mm ID, 0.25 µm film thickness) | Helium at 1.5 mL/minute | 40°C for 3 minutes, then 4°C/minute to 65°C, then 6°C/minute to 230°C, held for 5 minutes
System K
Flame ionization (250°C) | Restek Stabilwax^®^-DA, (30 m × 0.25 mm ID, 0.25 µm film thickness) | Helium at 1.0 mL/minute | 45°C for 1 minute, then 6°C/minute to 120°C, then 15°C/minute to 180°C

ID = internal diameter.

^a^ Temperature for this system was not recorded.

Table A-2 Summary of Chamber Concentrations in the Two-week Inhalation Studies of Acetoin

Exposure Date | Target Concentration (ppm) | Total Number of Readings | Determined Concentration (ppm)^a^ | Difference from Target (%) | Acceptable Samples (%)^b^
Rat Chambers
October 27, 2008–November 11, 2008 | 0 (Room) | 247 | ND | NA | 99
October 27, 2008–November 11, 2008 | 0 | 246 | ND | NA | 100
| 6.25 | 229 | 6.23 ± 0.5 | −0.3 | 97
| 25 | 235 | 24.4 ± 1.4 | −2.4 | 94
| 100 | 226 | 100 ± 3.9 | 0 | 98
| 400 | 249 | 397 ± 21 | −0.8 | 96
| 800 | 234 | 796 ± 40 | −0.5 | 97
Mouse Chambers
October 27, 2008–November 12, 2008 | 0 (Room) | 267 | ND | NA | 99
October 27, 2008–November 12, 2008 | 0 | 266 | ND | NA | 100
| 6.25 | 247 | 6.23 ± 0.5 | −0.3 | 97
| 25 | 253 | 24.4 ± 1.3 | −2.4 | 94
| 100 | 244 | 100 ± 3.9 | 0 | 98
| 400 | 267 | 397 ± 21 | −0.8 | 95
| 800 | 252 | 795 ± 40 | −0.6 | 97

ND = not detectable; NA = not applicable.

^a^ Data shown as mean of readings ± standard deviation.

^b^ Acceptable range: target concentration ± 10%, except for room and 0 ppm chamber: <limit of detection (~0.3 ppm).

Table A-3 Summary of Chamber Concentrations in the Three-month Inhalation Studies of Acetoin

Exposure Date | Target Concentration (ppm) | Total Number of Readings | Determined Concentration (ppm)^a^ | Difference from Target (%) | Acceptable Samples (%)^b^
Rat Chambers
June 29, 2009–September 28, 2009 (Males) June 30, 2009–September 29, 2009 (Females) | 0 (Room) | 1,252 | ND | NA | 100
June 29, 2009–September 28, 2009 (Males) June 30, 2009–September 29, 2009 (Females) | 0 (Acclimation) | 18 | ND | NA | 100
June 29, 2009–September 28, 2009 (Males) June 30, 2009–September 29, 2009 (Females) | 0 | 1,236 | ND | NA | 100
June 29, 2009–September 28, 2009 (Males) June 30, 2009–September 29, 2009 (Females) | 50 | 1,261 | 49.6 ± 2.0 | −0.8 | 97
June 29, 2009–September 28, 2009 (Males) June 30, 2009–September 29, 2009 (Females) | 100 | 1,268 | 99.0 ± 4.7 | −1.0 | 96
June 29, 2009–September 28, 2009 (Males) June 30, 2009–September 29, 2009 (Females) | 200 | 1,287 | 197.9 ± 9.3 | −1.1 | 98
June 29, 2009–September 28, 2009 (Males) June 30, 2009–September 29, 2009 (Females) | 400 | 1,301 | 397.3 ± 19.6 | −0.7 | 97
June 29, 2009–September 28, 2009 (Males) June 30, 2009–September 29, 2009 (Females) | 800 | 1,283 | 794.2 ± 29.0 | −0.7 | 98
Mouse Chambers
June 29, 2009–September 30, 2009 (Males) June 29, 2009–October 1, 2009 (Females) | 0 (Room) | 1,291 | ND | NA | 100
June 29, 2009–September 30, 2009 (Males) June 29, 2009–October 1, 2009 (Females) | 0 | 1,274 | ND | NA | 100
June 29, 2009–September 30, 2009 (Males) June 29, 2009–October 1, 2009 (Females) | 50 | 1,299 | 49.6 ± 2.0 | −0.8 | 97
June 29, 2009–September 30, 2009 (Males) June 29, 2009–October 1, 2009 (Females) | 100 | 1,306 | 99.0 ± 4.6 | −1.0 | 96
June 29, 2009–September 30, 2009 (Males) June 29, 2009–October 1, 2009 (Females) | 200 | 1,325 | 198.0 ± 9.2 | −1.0 | 98
June 29, 2009–September 30, 2009 (Males) June 29, 2009–October 1, 2009 (Females) | 400 | 1,339 | 397.5 ± 19.4 | −0.6 | 97
June 29, 2009–September 30, 2009 (Males) June 29, 2009–October 1, 2009 (Females) | 800 | 1,321 | 795.0 ± 29.0 | −0.6 | 98

ND = not detectable; NA = not applicable.

^a^ Data shown as mean of readings ± standard deviation.

^b^ Acceptable range: target concentration ± 10%, except for room, acclimation, and 0 ppm chamber: <limit of detection (~0.2 ppm).

Table A-4 Summary of Chamber Concentrations in the Three-month Inhalation Studies of 2,3-Pentanedione

Exposure Date | Target Concentration (ppm) | Total Number of Readings | Determined Concentration (ppm)^a^ | Difference from Target (%) | Acceptable Samples (%)^b^
Rat Chambers
September 13, 2010–December 13, 2010 (Males) September 14, 2010–December 14, 2010 (Females) | 0 (Room) | 1,290 | ND | NA | 100
September 13, 2010–December 13, 2010 (Males) September 14, 2010–December 14, 2010 (Females) | 0 (Acclimation) | 18 | ND | NA | 100
September 13, 2010–December 13, 2010 (Males) September 14, 2010–December 14, 2010 (Females) | 0 | 1,280 | ND | NA | 100
September 13, 2010–December 13, 2010 (Males) September 14, 2010–December 14, 2010 (Females) | 6.25 | 1,254 | 6.28 ± 0.13 | 0.5 | >99^c^
September 13, 2010–December 13, 2010 (Males) September 14, 2010–December 14, 2010 (Females) | 12.5 | 1,263 | 12.5 ± 0.2 | 0.0 | 100
September 13, 2010–December 13, 2010 (Males) September 14, 2010–December 14, 2010 (Females) | 25 | 1,285 | 25.1 ± 0.5 | 0.4 | 100
September 13, 2010–December 13, 2010 (Males) September 14, 2010–December 14, 2010 (Females) | 50 | 1,303 | 50.1 ± 1.0 | 0.2 | >99^c^
September 13, 2010–December 13, 2010 (Males) September 14, 2010–December 14, 2010 (Females) | 100 | 1,306 | 100.8 ± 2.0 | 0.8 | >99^c^
Mouse Chambers
September 13, 2010–December 15, 2010 (Males) September 13, 2010–December 16, 2010 (Females) | 0 (Room) | 1,330 | ND | NA | 100
September 13, 2010–December 15, 2010 (Males) September 13, 2010–December 16, 2010 (Females) | 0 | 1,320 | ND | NA | 100
September 13, 2010–December 15, 2010 (Males) September 13, 2010–December 16, 2010 (Females) | 6.25 | 1,292 | 6.28 ± 0.13 | 0.5 | >99^c^
September 13, 2010–December 15, 2010 (Males) September 13, 2010–December 16, 2010 (Females) | 12.5 | 1,301 | 12.5 ± 0.2 | 0.0 | 100
September 13, 2010–December 15, 2010 (Males) September 13, 2010–December 16, 2010 (Females) | 25 | 1,323 | 25.1 ± 0.5 | 0.4 | 100
September 13, 2010–December 15, 2010 (Males) September 13, 2010–December 16, 2010 (Females) | 50 | 1,341 | 50.1 ± 1.1 | 0.2 | >99^c^
September 13, 2010–December 15, 2010 (Males) September 13, 2010–December 16, 2010 (Females) | 100 | 1,344 | 100.8 ± 2.0 | 0.8 | >99^c^

ND = not detectable; NA = not applicable.

^a^ Data shown as mean of readings ± standard deviation.

^b^ Acceptable range: target concentration ± 10%, except for room, acclimation, and 0 ppm chamber: <limit of detection (~0.2 ppm).

^c^ >99.5% but <100%.

Figure A-1

Infrared Absorption Spectrum of Acetoin

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of Acetoin

Figure A-3

Infrared Absorption Spectrum of 2,3-Pentanedione

Figure A-4

^1^H Nuclear Magnetic Resonance Spectrum of 2,3-Pentanedione

Figure A-5

Schematic of the Vapor Generation and Delivery System in the Inhalation Studies of Acetoin and 2,3-Pentanedione

The water reservoir used to rinse the liquid pump and prevent the formation of solid dimer acetoin was not used in the generation system for 2,3-pentanedione.