# Overview

The U.S. Environmental Protection Agency nominated the per/polyfluorinated alkyl substances (PFAS) class to the National Toxicology Program (NTP) for a variety of toxicity assessments. A major component of this nomination was a class toxicity evaluation of PFAS through in vitro and in vivo studies. The studies presented in this Toxicity Study Report are part of the in vivo class evaluation, which evaluated a suite of seven PFAS chemicals consisting of three sulfonates and four carboxylates of varying chain lengths (see list below). Measurement of plasma and liver levels of each chemical was conducted to allow for the correlation of toxicities to internal exposure parameters. An agonist of peroxisome proliferator-activated receptor alpha (PPARα), Wyeth-14,643, was included for qualitative comparisons to the PFAS tested because several PFAS are known to activate the PPARα pathway, and inclusion of a positive control would allow for the identification of non-PPARα-mediated toxicities. These studies are divided into two reports: those focused on the carboxylate subclass are presented in this report and those focused on the sulfonate subclass are presented in NTP Toxicity Study Report 96.

Other PFAS studies that were conducted with this nomination included an assessment of the contribution of perinatal exposure to perfluorooctanoic acid (PFOA) chronic toxicity and carcinogenicity in rats; an evaluation of the toxicokinetics of seven PFAS chemicals after a single dose in rats; and in vitro class evaluations of potential neurotoxicity, mitochondrial toxicity, and immunotoxicity with a follow-up in vivo immune toxicity study on perfluorodecanoic acid. As the PFAS class continues to expand with new uses and replacements, NTP continues to assess the potential toxicity of these chemicals through a variety of methods, including in silico, in vitro, and in vivo studies.

Perfluoroalkyl Substances Studied in Toxicity Reports 96 and 97

Chemical | CAS No. | Abbreviation | Toxicity Study Report
Perfluorobutane Sulfonic Acid | 375-73-5 | PFBS | 96
Perfluorohexane Sulfonate Potassium Salt | 3871-99-6 | PFHSK | 96
Perfluorooctane Sulfonic Acid | 1763-23-1 | PFOS | 96
Perfluorohexanoic Acid | 307-24-4 | PFHxA | 97
Perfluorooctanoic Acid | 335-67-1 | PFOA | 97
Perfluorononanoic Acid | 375-95-1 | PFNA | 97
Perfluorodecanoic Acid | 335-76-2 | PFDA | 97
Wyeth-14,643 | 50892-23-4 | WY | 96/97

Due to the comparative nature of the studies and concerns of variable kinetics across the class, NTP conducted toxicokinetic studies in the Sprague Dawley rat to understand the relationship of external dose to internal dose. A maximum tolerated daily dose was identified and four lower doses were selected on the basis of the resulting data and supporting kinetic and toxicity information from the literature. PFAS that displayed rapid elimination due to chain length or sex differences were administered at higher doses compared to PFAS with longer half-lives. Doses were administered twice daily for PFHxA and PFBS. The following table lists doses in mg/kg/day and µmol/kg/day for comparison for the chemicals discussed in both Toxicity Study Reports.

Doses Administered to Sprague Dawley Rats in the Gavage Studies of Perfluoroalkyl Substances and Wyeth-14,643

PFAS | Sex | Dose (mg/kg/day) | Micromolar Dose (µmol/kg/day)
PFBS | M/F | 0, 62.6, 125, 250, 500, 1,000* | 0, 208.6, 416.5, 833.1, 1,666, 3,332*
PFHxSK | M | 0, 0.625, 1.25, 2.5, 5, 10 | 0, 1.4, 2.9, 5.7, 11.4, 22.8
PFHxSK | F | 0, 3.12, 6.25, 12.5, 25, 50 | 0, 7.1, 14.3, 28.5, 57.1, 114.1
PFOS | M/F | 0, 0.312, 0.625, 1.25, 2.5, 5 | 0, 0.6, 1.2, 2.5, 5.0, 10.0
PFHxA | M/F | 0, 62.6, 125, 250, 500, 1,000* | 0, 199.3, 398.0, 796.0, 1,592, 3,184*
PFOA | M | 0, 0.625, 1.25, 2.5, 5, 10 | 0, 1.5, 3.0, 6.0, 12.1, 24.2
PFOA | F | 0, 6.25, 12.5, 25, 50, 100 | 0, 15.1, 30.2, 60.4, 120.8, 241.5
PFNA | M | 0, 0.625, 1.25, 2.5, 5, 10 | 0, 1.3, 2.7, 5.4, 10.8, 21.5
PFNA | F | 0, 1.56, 3.12, 6.25, 12.5, 25 | 0, 3.4, 6.7, 13.5, 26.9, 53.9
PFDA | M/F | 0, 0.156, 0.312, 0.625, 1.25, 2.5 | 0, 0.3, 0.6, 1.2, 2.4, 4.9
WY | M/F | 0, 6.25, 12.5, 25 | 0, 19.3, 38.6, 77.2

PFBS = perfluorobutane sulfonic acid; PFHxSK = perfluorohexane sulfonate potassium salt; PFOS = perfluorooctane sulfonic acid; PFHxA = perfluorohexanoic acid; PFOA = perfluorooctanoic acid; PFNA = perfluorononanoic acid; PFDA = perfluorodecanoic acid; WY = Wyeth-14,643.

* These are the total doses per day; one-half the dose was administered twice daily.