# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-97

Report Series: NTP Toxicity Report Series

Report Series Number: 97

Official citation: National Toxicology Program (NTP). 2022. NTP technical report on the toxicity studies of perfluoroalkyl carboxylates (perfluorohexanoic acid, perfluorooctanoic acid, perfluorononanoic acid, and perfluorodecanoic acid) administered by gavage to Sprague Dawley (Hsd:Sprague Dawley SD) rats (revised). Research Triangle Park, NC: National Toxicology Program. Toxicity Report 97.