# Revision Notice

Errors were identified in the NTP Technical Report on the Toxicity Studies of Perfluoroalkyl Carboxylates (Perfluorohexanoic Acid, Perfluorooctanoic Acid, Perfluorononanoic Acid, and Perfluorodecanoic Acid) Administered by Gavage to Sprague Dawley (Hsd:Sprague Dawley SD) rats (Toxicity Report 97). Revisions were made throughout the report, and these corrections are described in detail in Appendix F. [June 30, 2022]