# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.L. Dzierlenga, Ph.D., Study Scientist
  C.R. Blystone, Ph.D., Study Scientist
  R.A. Herbert, D.V.M., Ph.D., Study Pathologist
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  M.J. DeVito, Ph.D.
  J.M. Fostel, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  B.S. McIntyre, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  S.A. Masten, Ph.D.
  G.K. Roberts, Ph.D.
  V.G. Robinson, M.A.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.K. Vallant, B.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  K.S. Janardhan, M.V.Sc., Ph.D., Study Pathologist
- RTI International, Research Triangle Park, North Carolina, USA
  Provided sperm parameters and vaginal cytology analyses
  C.J. Price, Ph.D., Principal Investigator
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  B.R. Sparrow, Ph.D., Principal Investigator
  M.A. Buccellato, D.V.M., Ph.D.
  D.K. Gerken, D.V.M., Ph.D.
  T.A. Peace, D.V.M.
  A. Zmarowski, Ph.D.
- Battelle Chemistry Technical Center, Columbus, Ohio, USA
  Provided prestart and biological sample chemistry analyses
  T.A. Cristy, B.A.
  S.W. Graves, B.S.
- Pathology Associates, A Division of Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group (July 18 and July 20, 2017)
  S.A. Bouknight, D.V.M., Ph.D.
  L.H. Kooistra, D.V.M., Ph.D.