# References

1 Buck RC, Franklin J, Berger U, Conder JM, Cousins IT, de Voogt P, Jensen AA, Kannan K, Mabury SA, van Leeuwen SP. Perfluoroalkyl and polyfluoroalkyl substances in the environment: Terminology, classification, and origins. Integr Environ Assess Manag. 2011; 7(4):513–541. 10.1002/ieam.258 21793199
2 PubChem. Perfluorohexanoic acid. Bethesda, MD: National Library of Medicine, National Center for Biotechnology Information; 2019. https://pubchem.ncbi.nlm.nih.gov/compound/Undecafluorohexanoic_acid#section=Chemical-and-Physical-Properties [Accessed: February 25, 2019]
3 PubChem. Perfluorooctanoic acid. Bethesda, MD: National Library of Medicine, National Center for Biotechnology Information; 2019. https://pubchem.ncbi.nlm.nih.gov/compound/9554#section=Chemical-and-Physical-Properties [Accessed: February 25, 2019]
4 PubChem. Perfluorononanoic acid. Bethesda, MD: National Library of Medicine, National Center for Biotechnology Information; 2019. https://pubchem.ncbi.nlm.nih.gov/compound/67821#section=Chemical-and-Physical-Properties [Accessed: February 25, 2019]
5 PubChem. Perfluorodecanoic acid. Bethesda, MD: National Library of Medicine, National Center for Biotechnology Information; 2019. https://pubchem.ncbi.nlm.nih.gov/compound/9555#section=Chemical-and-Physical-Properties [Accessed: February 25, 2019]
6 Begley TH, White K, Honigfort P, Twaroski ML, Neches R, Walker RA. Perfluorochemicals: Potential sources of and migration from food packaging. Food Addit Contam. 2005; 22(10):1023–1031. 10.1080/02652030500183474 16227186
7 D’eon JC, Mabury SA. Production of perfluorinated carboxylic acids (PFCAs) from the biotransformation of polyfluoroalkyl phosphate surfactants (PAPS): Exploring routes of human contamination. Environ Sci Technol. 2007; 41(13):4799–4805. 10.1021/es070126x 17695932
8 National Health and Nutrition Examination Survey (NHANES). Fourth national report on human exposure to environmental chemicals, updated tables, Vol 1, March 2018. Washington, DC: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; 2018. https://www.cdc.gov/exposurereport/index.html
9 Ye X, Kato K, Wong L-Y, Jia T, Kalathil A, Latremouille J, Calafat AM. Per-and polyfluoroalkyl substances in sera from children 3 to 11 years of age participating in the National Health and Nutrition Examination Survey 2013–2014. Int J Hyg Environ Health. 2018; 221(1):9–16. 10.1016/j.ijheh.2017.09.011 28993126
10 Olsen GW, Mair DC, Lange CC, Harrington LM, Church TR, Goldberg CL, Herron RM, Hanna H, Nobiletti JB, Rios JA, et al. Per- and polyfluoroalkyl substances (PFAS) in American Red Cross adult blood donors, 2000-2015. Environ Res. 2017;157:87–95. 10.1016/j.envres.2017.05.013 28528142
11 Rankin K, Mabury SA, Jenkins TM, Washington JW. A North American and global survey of perfluoroalkyl substances in surface soils: Distribution patterns and mode of occurrence. Chemosphere. 2016;161:333–341. 10.1016/j.chemosphere.2016.06.109 27441993
12 Sedlak MD, Benskin JP, Wong A, Grace R, Greig DJ. Per- and polyfluoroalkyl substances (PFASs) in San Francisco Bay wildlife: Temporal trends, exposure pathways, and notable presence of precursor compounds. Chemosphere. 2017;185:1217–1226. 10.1016/j.chemosphere.2017.04.096 28477851
13 Daly ER, Chan BP, Talbot EA, Nassif J, Bean C, Cavallo SJ, Metcalf E, Simone K, Woolf AD. Per- and polyfluoroalkyl substance (PFAS) exposure assessment in a community exposed to contaminated drinking water, New Hampshire, 2015. Int J Hyg Environ Health. 2018; 221(3):569–577. 10.1016/j.ijheh.2018.02.007 29514764
14 Herrick RL, Buckholz J, Biro FM, Calafat AM, Ye X, Xie C, Pinney SM. Polyfluoroalkyl substance exposure in the Mid-Ohio River Valley, 1991-2012. Environ Pollut. 2017; 228:50–60. 10.1016/j.envpol.2017.04.092 28505513
15 U.S. Environmental Proctection Agency (USEPA). Drinking water health advisory for perfluorooctanoic Acid (PFOA). Washington, DC: U.S. Environmental Protection Agency, Office of Water, Health and Ecological Criteria Division; 2016. EPA Document Number: EPA/822/R-16/005.
16 Agency for Toxic Substances and Disease Registry (ATSDR). ATSDR’s Minimal Risk Levels (MRLs) and Environmental Media Evaluation Guides (EMEGs) for PFAS. Atlanta, GA: Centers for Disease Control and Prevention; 2018. https://www.atsdr.cdc.gov/pfas/mrl_pfas.html [Accessed: February 15, 2019]
17 European Food Safety Authority (EFSA). Risk to human health related to the presence of perfluorooctane sulfonic acid and perfluorooctanoic acid in food. EFSA J. 2018; 16(12):5194. 32625773
18 Kudo N, Katakura M, Sato Y, Kawashima Y. Sex hormone-regulated renal transport of perfluorooctanoic acid. Chem Biol Interact. 2002; 139(3):301–316. 10.1016/S0009-2797(02)00006-6 11879818
19 Andersen ME, Clewell HJ, Tan Y-M, Butenhoff JL, Olsen GW. Pharmacokinetic modeling of saturable, renal resorption of perfluoroalkylacids in monkeys—Probing the determinants of long plasma half-lives. Toxicology. 2006; 227(1):156–164. 10.1016/j.tox.2006.08.004 16978759
20 Lou I, Wambaugh JF, Lau C, Hanson RG, Lindstrom AB, Strynar MJ, Zehr RD, Setzer RW, Barton HA. Modeling single and repeated dose pharmacokinetics of PFOA in mice. Toxicol Sci. 2009; 107(2):331–341. 10.1093/toxsci/kfn234 19005225
21 Loccisano AE, Campbell JL Jr, Butenhoff JL, Andersen ME, Clewell HJ 3rd. Comparison and evaluation of pharmacokinetics of PFOA and PFOS in the adult rat using a physiologically based pharmacokinetic model. Reprod Toxicol. 2012; 33(4):452–467. 10.1016/j.reprotox.2011.04.006 21565266
22 Loccisano AE, Longnecker MP, Campbell JL Jr, Andersen ME, Clewell HJ 3rd. Development of PBPK models for PFOA and PFOS for human pregnancy and lactation life stages. J Toxicol Environ Health A. 2013; 76(1):25–57. 10.1080/15287394.2012.722523 23151209
23 Loccisano AE, Campbell JL Jr, Andersen ME, Clewell HJ 3rd. Evaluation and prediction of pharmacokinetics of PFOA and PFOS in the monkey and human using a PBPK model. Regul Toxicol Pharmacol. 2011; 59(1):157–175. 10.1016/j.yrtph.2010.12.004 21168463
24 Loccisano AE, Campbell JL Jr, Butenhoff JL, Andersen ME, Clewell HJ 3rd. Evaluation of placental and lactational pharmacokinetics of PFOA and PFOS in the pregnant, lactating, fetal and neonatal rat using a physiologically based pharmacokinetic model. Reprod Toxicol. 2012; 33(4):468–490. 10.1016/j.reprotox.2011.07.003 21872655
25 Dzierlenga AL, Robinson VG, Waidyanatha S, DeVito MJ, Eifrid MA, Gibbs ST, Granville CA, Blystone CR. Toxicokinetics of perfluorohexanoic acid (PFHxA), perfluorooctanoic acid (PFOA), and perfluorodecanoic acid (PFDA) in male and female Hsd:Sprague Dawley SD rats following intravenous or gavage administration. Xenobiotica. 2020; 50(6):722–732. 10.1080/00498254.2019.1683776 31680603
26 Huang MC, Dzierlenga AL, Robinson VG, Waidyanatha S, DeVito MJ, Eifrid MA, Granville CA, Gibbs ST, Blystone CR. Toxicokinetics of perfluorobutane sulfonate (PFBS), perfluorohexane-1-sulphonic acid (PFHxS), and perfluorooctane sulfonic acid (PFOS) in male and female Hsd:Sprague Dawley SD rats after intravenous and gavage administration. Toxicol Rep. 2019; 6:645–655. 10.1016/j.toxrep.2019.06.016 31334035
27 Chengelis CP, Kirkpatrick JB, Myers NR, Shinohara M, Stetson PL, Sved DW. Comparison of the toxicokinetic behavior of perfluorohexanoic acid (PFHxA) and nonafluorobutane-1-sulfonic acid (PFBS) in cynomolgus monkeys and rats. Reprod Toxicol. 2009; 27(3-4):400–406. 10.1016/j.reprotox.2009.01.013 19429410
28 Ohmori K, Kudo N, Katayama K, Kawashima Y. Comparison of the toxicokinetics between perfluorocarboxylic acids with different carbon chain length. Toxicology. 2003; 184(2-3):135–140. 10.1016/S0300-483X(02)00573-5 12499116
29 Vanden Heuvel JP, Kuslikis BI, Van Rafelghem MJ, Peterson RE. Tissue distribution, metabolism, and elimination of perfluorooctanoic acid in male and female rats. J Biochem Toxicol. 1991; 6(2):83–92. 10.1002/jbt.2570060202 1941903
30 Olsen GW, Burris JM, Ehresman DJ, Froehlich JW, Seacat AM, Butenhoff JL, Zobel LR. Half-life of serum elimination of perfluorooctanesulfonate, perfluorohexanesulfonate, and perfluorooctanoate in retired fluorochemical production workers. Environ Health Perspect. 2007; 115(9):1298–1305. 10.1289/ehp.10009 17805419
31 Gomis MI, Vestergren R, Nilsson H, Cousins IT. Contribution of direct and indirect exposure to human serum concentrations of perfluorooctanoic acid in an occupationally exposed group of ski waxers. Environ Sci Technol. 2016; 50(13):7037–7046. 10.1021/acs.est.6b01477 27304840
32 Li Y, Fletcher T, Mucs D, Scott K, Lindh CH, Tallving P, Jakobsson K. Half-lives of PFOS, PFHxS and PFOA after end of exposure to contaminated drinking water. Occup Environ Med. 2018; 75(1):46–51. 10.1136/oemed-2017-104651 29133598
33 Tatum-Gibbs K, Wambaugh JF, Das KP, Zehr RD, Strynar MJ, Lindstrom AB, Delinsky A, Lau C. Comparative pharmacokinetics of perfluorononanoic acid in rat and mouse. Toxicology. 2011; 281(1-3):48–55. 10.1016/j.tox.2011.01.003 21237237
34 Ylinen M, Auriola S. Tissue distribution and elimination of perfluorodecanoic acid in the rat after single intraperitoneal administration. Pharmacol Toxicol. 1990; 66(1):45–48. 10.1111/j.1600-0773.1990.tb00700.x 2308906
35 Permadi H, Lundgren B, Andersson K, DePierre JW. Effects of perfluoro fatty acids on xenobiotic-metabolizing enzymes, enzymes which detoxify reactive forms of oxygen and lipid peroxidation in mouse liver. Biochem Pharmacol. 1992; 44(6):1183–1191. 10.1016/0006-2952(92)90383-T 1417940
36 Kudo N, Yamazaki T, Sakamoto T, Sunaga K, Tsuda T, Mitsumoto A, Kawashima Y. Effects of perfluorinated fatty acids with different carbon chain length on fatty acid profiles of hepatic lipids in mice. Biol Pharm Bull. 2011; 34(6):856–864. 10.1248/bpb.34.856 21628884
37 Kudo N, Suzuki-Nakajima E, Mitsumoto A, Kawashima Y. Responses of the liver to perfluorinated fatty acids with different carbon chain length in male and female mice: In relation to induction of hepatomegaly, peroxisomal β-oxidation and microsomal 1-acylglycerophosphocholine acyltransferase. Biol Pharm Bull. 2006; 29(9):1952–1957. 10.1248/bpb.29.1952 16946516
38 Vanden Heuvel JP, Thompson JT, Frame SR, Gillies P. Differential activation of nuclear receptors by perfluorinated fatty acid analogs and natural fatty acids: A comparison of human, mouse, and rat peroxisome proliferator-activated receptor-α,-β, and-γ, liver X receptor-β, and retinoid X receptor-α. Toxicol Sci. 2006; 92(2):476–489. 10.1093/toxsci/kfl014 16731579
39 Wolf CJ, Takacs ML, Schmid JE, Lau C, Abbott BD. Activation of mouse and human peroxisome proliferator− Activated receptor alpha by perfluoroalkyl acids of different functional groups and chain lengths. Toxicol Sci. 2008; 106(1):162–171. 10.1093/toxsci/kfn166 18713766
40 Bjork JA, Wallace KB. Structure-activity relationships and human relevance for perfluoroalkyl acid-induced transcriptional activation of peroxisome proliferation in liver cell cultures. Toxicol Sci. 2009; 111(1):89–99. 10.1093/toxsci/kfp093 19407336
41 Cheng X, Klaassen CD. Perfluorocarboxylic acids induce cytochrome P450 enzymes in mouse liver through activation of PPAR-alpha and CAR transcription factors. Toxicol Sci. 2008; 106(1):29–36. 10.1093/toxsci/kfn147 18648086
42 Rosen MB, Lee JS, Ren H, Vallanat B, Liu J, Waalkes MP, Abbott BD, Lau C, Corton JC. Toxicogenomic dissection of the perfluorooctanoic acid transcript profile in mouse liver: Evidence for the involvement of nuclear receptors PPAR alpha and CAR. Toxicol Sci. 2008; 103(1):46–56. 10.1093/toxsci/kfn025 18281256
43 Loveless SE, Slezak B, Serex T, Lewis J, Mukerji P, O’Connor JC, Donner EM, Frame SR, Korzeniowski SH, Buck RC. Toxicological evaluation of sodium perfluorohexanoate. Toxicology. 2009; 264(1-2):32–44. 10.1016/j.tox.2009.07.011 19632293
44 Chengelis CP, Kirkpatrick JB, Radovsky A, Shinohara M. A 90-day repeated dose oral (gavage) toxicity study of perfluorohexanoic acid (PFHxA) in rats (with functional observational battery and motor activity determinations). Reprod Toxicol. 2009; 27(3-4):342–351. 10.1016/j.reprotox.2009.01.006 19429405
45 Iwai H, Hoberman AM. Oral (gavage) combined developmental and perinatal/postnatal reproduction toxicity study of ammonium salt of perfluorinated hexanoic acid in mice. Int J Toxicol. 2014; 33(3):219–237. 10.1177/1091581814529449 24700568
46 Perkins RG, Butenhoff JL, Kennedy GL Jr, Palazzolo MJ. 13-week dietary toxicity study of ammonium perfluorooctanoate (APFO) in male rats. Drug Chem Toxicol. 2004; 27(4):361–378. 10.1081/DCT-200039773 15573472
47 Butenhoff JL, Kennedy GL Jr, Frame SR, O’Connor JC, York RG. The reproductive toxicology of ammonium perfluorooctanoate (APFO) in the rat. Toxicology. 2004; 196(1-2):95–116. 10.1016/j.tox.2003.11.005 15036760
48 Lau C, Thibodeaux JR, Hanson RG, Narotsky MG, Rogers JM, Lindstrom AB, Strynar MJ. Effects of perfluorooctanoic acid exposure during pregnancy in the mouse. Toxicol Sci. 2006; 90(2):510–518. 10.1093/toxsci/kfj105 16415327
49 Mertens JJ, Sved DW, Marit GB, Myers NR, Stetson PL, Murphy SR, Schmit B, Shinohara M, Farr CH. Subchronic toxicity of S-111-S-WB in Sprague Dawley rats. Int J Toxicol. 2010; 29(4):358–371. 10.1177/1091581810370372 20519691
50 Stump DG, Holson JF, Murphy SR, Farr CH, Schmit B, Shinohara M. An oral two-generation reproductive toxicity study of S-111-S-WB in rats. Reprod Toxicol. 2008; 25(1):7–20. 10.1016/j.reprotox.2007.10.002 18022344
51 Das KP, Grey BE, Rosen MB, Wood CR, Tatum-Gibbs KR, Zehr RD, Strynar MJ, Lindstrom AB, Lau C. Developmental toxicity of perfluorononanoic acid in mice. Reprod Toxicol. 2015; 51:133–144. 10.1016/j.reprotox.2014.12.012 25543169
52 Harris MW, Birnbaum LS. Developmental toxicity of perfluorodecanoic acid in C57BL/6N mice. Fundam Appl Toxicol. 1989; 12(3):442–448. 10.1016/0272-0590(89)90018-3 2731659
53 Wen L-L, Lin L-Y, Su T-C, Chen P-C, Lin C-Y. Association between serum perfluorinated chemicals and thyroid function in US adults: The National Health and Nutrition Examination Survey 2007–2010. J Clin Endocrinol Metab. 2013; 98(9):E1456–E1464. 10.1210/jc.2013-1282 23864701
54 Rappazzo KM, Coffman E, Hines EP. Exposure to perfluorinated alkyl substances and health outcomes in children: A systematic review of the epidemiologic literature. Int J Environ Res Public Health. 2017; 14(7). 10.3390/ijerph14070691 28654008
55 Melzer D, Rice N, Depledge MH, Henley WE, Galloway TS. Association between serum perfluorooctanoic acid (PFOA) and thyroid disease in the U.S. National Health and Nutrition Examination Survey. Environ Health Perspect. 2010; 118(5):686–692. 10.1289/ehp.0901584 20089479
56 Lundin JI, Alexander BH, Olsen GW, Church TR. Ammonium perfluorooctanoate production and occupational mortality. Epidemiology. 2009; 20(6):921–928. 10.1097/EDE.0b013e3181b5f395 19797969
57 Sakr CJ, Symons JM, Kreckmann KH, Leonard RC. Ischaemic heart disease mortality study among workers with occupational exposure to ammonium perfluorooctanoate. Occup Environ Med. 2009; 66(10):699–703. 10.1136/oem.2008.041582 19553230
58 Steenland K, Zhao L, Winquist A, Parks C. Ulcerative colitis and perfluorooctanoic acid (PFOA) in a highly exposed population of community residents and workers in the mid-Ohio valley. Environ Health Perspect. 2013; 121(8):900–905. 10.1289/ehp.1206449 23735465
59 Geiger SD, Xiao J, Ducatman A, Frisbee S, Innes K, Shankar A. The association between PFOA, PFOS and serum lipid levels in adolescents. Chemosphere. 2014; 98:78–83. 10.1016/j.chemosphere.2013.10.005 24238303
60 Lopez-Espinosa MJ, Fletcher T, Armstrong B, Genser B, Dhatariya K, Mondal D, Ducatman A, Leonardi G. Association of perfluorooctanoic acid (PFOA) and perfluorooctane sulfonate (PFOS) with age of puberty among children living near a chemical plant. Environ Sci Technol. 2011; 45(19):8160–8166. 10.1021/es1038694 21534542
61 Zhou W, Zhang L, Tong C, Fang F, Zhao S, Tian Y, Tao Y, Zhang J, Study SBC. Plasma perfluoroalkyl and polyfluoroalkyl substances concentration and menstrual cycle characteristics in preconception women. Environ Health Perspect. 2017; 125(6):067012. 10.1289/EHP1203 28657892
62 Johnson PI, Sutton P, Atchley DS, Koustas E, Lam J, Sen S, Robinson KA, Axelrad DA, Woodruff TJ. The navigation guide - Evidence-based medicine meets environmental health: Systematic review of human evidence for PFOA effects on fetal growth. Environ Health Perspect. 2014; 122:1028–1039. 10.1289/ehp.1307893 24968388
63 Apelberg BJ, Witter FR, Herbstman JB, Calafat AM, Halden RU, Needham LL, Goldman LR. Cord serum concentrations of perfluorooctane sulfonate (PFOS) and perfluorooctanoate (PFOA) in relation to weight and size at birth. Environ Health Perspect. 2007; 115(11):1670–1676. 10.1289/ehp.10334 18008002
64 Stein CR, Savitz DA, Dougan M. Serum levels of perfluorooctanoic acid and perfluorooctane sulfonate and pregnancy outcome. Am J Epidemiol. 2009; 170(7):837–846. 10.1093/aje/kwp212 19692329
65 Granum B, Haug L, Namork E, Stølevik S, Thomsen C, Aaberge I, van Loveren H, Løvik M, Nygaard U. Pre-natal exposure to perfluoroalkyl substances may be associated with altered vaccine antibody levels and immune-related health outcomes in early childhood. J Immunotoxicol. 2013; 10(4):373–379. 10.3109/1547691X.2012.755580 23350954
66 Grandjean P, Clapp R. Perfluorinated alkyl substances: Emerging insights into health risks. New Solut. 2015; 25(2):147–163. 10.1177/1048291115590506 26084549
67 Mogensen U, Grandjean P, Heilmann C, Nielsen F, Weihe P, Budtz-Jørgensen E. Structural equation modeling of immunotoxicity associated with exposure to perfluorinated alkylates. Environ Health. 2015; 14:47. 10.1186/s12940-015-0032-9 26041029
68 Stein CR, McGovern KJ, Pajak AM, Maglione PJ, Wolff MS. Perfluoroalkyl and polyfluoroalkyl substances and indicators of immune function in children aged 12-19 y: National Health and Nutrition Examination Survey (NHANES). Pediatr Res. 2016; 79(2):348–357. 10.1038/pr.2015.213 26492286
69 National Toxicology Program (NTP). Monograph on immunotoxicity associated with exposure to perfluorooctanoic acid or perfluorooctane sulfonate. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health; 2016. https://ntp.niehs.nih.gov/pubhealth/hat/noms/pfoa/index.html
70 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for perfluoroalkyls: Draft for public comment. Atlanta, GA: U.S. Department of Health and Human Services; updated March 2020, released 2021. https://www.atsdr.cdc.gov/toxprofiles/tp200.pdf
71 C8 Science Panel. Probable link evaluation of preterm birth and low birthweight. Parkersburg, WV; 2011. http://www.c8sciencepanel.org/prob_link.html
72 C8 Science Panel. Probable link evaluation of miscarriage and stillbirths. Parkersburg, WV; 2011. http://www.c8sciencepanel.org/prob_link.html
73 C8 Science Panel. Probable link evaluation of pregnancy-induced hypertension and preeclampsia. Parkersburg, WV; 2011. http://www.c8sciencepanel.org/prob_link.html
74 C8 Science Panel. Probable link evaluation of birth defects. Parkersburg, WV; 2011. http://www.c8sciencepanel.org/prob_link.html
75 Klaunig JE, Shinohara M, Iwai H, Chengelis CP, Kirkpatrick JB, Wang Z, Bruner RH. Evaluation of the chronic toxicity and carcinogenicity of perfluorohexanoic acid (PFHxA) in Sprague-Dawley rats. Toxicol Pathol. 2015; 43(2):209–220. 10.1177/0192623314530532 25377447
76 Butenhoff JL, Kennedy GL Jr, Chang SC, Olsen GW. Chronic dietary toxicity and carcinogenicity study with ammonium perfluorooctanoate in Sprague-Dawley rats. Toxicology. 2012; 298(1-3):1–13. 10.1016/j.tox.2012.04.001 22531602
77 Hardisty JF, Willson GA, Brown WR, McConnell EE, Frame SR, Gaylor DW, Kennedy GL, Butenhoff JL. Pathology Working Group review and evaluation of proliferative lesions of mammary gland tissues in female rats fed ammonium perfluorooctanoate (APFO) in the diet for 2 years. Drug Chem Toxicol. 2010; 33(2):131–137. 10.3109/01480541003667610 20307141
78 Caverly Rae JM, Frame SR, Kennedy GL, Butenhoff JL, Chang SC. Pathology review of proliferative lesions of the exocrine pancreas in two chronic feeding studies in rats with ammonium perfluorooctanoate. Toxicol Rep. 2014;1:85–91. 10.1016/j.toxrep.2014.04.005 28962229
79 Biegel LB, Hurtt ME, Frame SR, O’Connor JC, Cook JC. Mechanisms of extrahepatic tumor induction by peroxisome proliferators in male CD rats. Toxicol Sci. 2001; 60(1):44–55. 10.1093/toxsci/60.1.44 11222872
80 Hardell E, Karrman A, van Bavel B, Bao J, Carlberg M, Hardell L. Case-control study on perfluorinated alkyl acids (PFAAs) and the risk of prostate cancer. Environ Int. 2014; 63:35–39. 10.1016/j.envint.2013.10.005 24246240
81 Steenland K, Tinker S, Shankar A, Ducatman A. Association of perfluorooctanoic acid (PFOA) and perfluorooctane sulfonate (PFOS) with uric acid among adults with elevated community exposure to PFOA. Environ Health Perspect. 2010; 118(2):229–233. 10.1289/ehp.0900940 20123605
82 Barry V, Winquist A, Steenland K. Perfluorooctanoic acid (PFOA) exposures and incident cancers among adults living near a chemical plant. Environ Health Perspect. 2013; 121(11-12):1313–1318. 10.1289/ehp.1306615 24007715
83 Vieira VM, Hoffman K, Shin H-M, Weinberg JM, Webster TF, Fletcher T. Perfluorooctanoic acid exposure and cancer outcomes in a contaminated community: A geographic analysis. Environ Health Perspect. 2013; 121(3):318–323. 10.1289/ehp.1205829 23308854
84 Eriksen KT, Sorensen M, McLaughlin JK, Lipworth L, Tjonneland A, Overvad K, Raaschou-Nielsen O. Perfluorooctanoate and perfluorooctanesulfonate plasma levels and risk of cancer in the general Danish population. J Natl Cancer Inst. 2009; 101(8):605–609. 10.1093/jnci/djp041 19351918
85 Bonefeld-Jorgensen EC, Long M, Bossi R, Ayotte P, Asmund G, Kruger T, Ghisari M, Mulvad G, Kern P, Nzulumiki P, et al. Perfluorinated compounds are related to breast cancer risk in Greenlandic Inuit: A case control study. Environ Health. 2011; 10:88. 10.1186/1476-069X-10-88 21978366
86 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of carcinogenic risks to humans, Vol. 110. Perfluorooctanoic acid. Lyon, France: IARC; 2016. https://monographs.iarc.fr/wp-content/uploads/2018/06/mono110-01.pdf [Accessed: February 25, 2019]
87 Buhrke T, Kibellus A, Lampen A. In vitro toxicological characterization of perfluorinated carboxylic acids with different carbon chain lengths. Toxicol Lett. 2013; 218(2):97–104. 10.1016/j.toxlet.2013.01.025 23391484
88 Fernandez Freire P, Perez Martin JM, Herrero O, Peropadre A, de la Pena E, Hazen MJ. In vitro assessment of the cytotoxic and mutagenic potential of perfluorooctanoic acid. Toxicol In Vitro. 2008; 22(5):1228–1233. 10.1016/j.tiv.2008.04.004 18499391
89 Godin CS, Myhr BC, Lawlor TE, Young RR, Murli H, Cifone MA. Assessment of the potential genotoxicity of perfluorodecanoic acid and chlorotrifluoroethylene trimer and tetramer acids. Fundam Appl Toxicol. 1992; 18(4):557–569. 10.1016/0272-0590(92)90115-X 1526368
90 Kim SC, Hong JT, Jang SJ, Kang WS, Yoo HS, Yun YP. Formation of 8-oxodeoxyguanosine in liver DNA and hepatic injury by peroxisome proliferator clofibrate and perfluorodecanoic acid in rats. J Toxicol Sci. 1998; 23(2):113–119. 10.2131/jts.23.2_113 9644651
91 Wielsøe M, Long M, Ghisari M, Bonefeld-Jørgensen EC. Perfluoroalkylated substances (PFAS) affect oxidative stress biomarkers in vitro. Chemosphere. 2015; 129:239–245. 10.1016/j.chemosphere.2014.10.014 25455676
92 Yao X, Zhong L. Genotoxic risk and oxidative DNA damage in HepG2 cells exposed to perfluorooctanoic acid. Mutat Res. 2005; 587(1-2):38–44. 10.1016/j.mrgentox.2005.07.010 16219484
93 Florentin A, Deblonde T, Diguio N, Hautemaniere A, Hartemann P. Impacts of two perfluorinated compounds (PFOS and PFOA) on human hepatoma cells: Cytotoxicity but no genotoxicity? Int J Hyg Environ Health. 2011; 214(6):493–499. 10.1016/j.ijheh.2011.05.010 21676652
94 Repine JE, Pfenninger OW, Talmage DW, Berger EM, Pettijohn DE. Dimethyl sulfoxide prevents DNA nicking mediated by ionizing radiation or iron/hydrogen peroxide-generated hydroxyl radical. Proc Natl Acad Sci USA. 1981; 78(2):1001–1003. 10.1073/pnas.78.2.1001 6940118
95 Yahia D, Haruka I, Kagashi Y, Tsuda S. 8‐Hydroxy‐2′‐deoxyguanosine as a biomarker of oxidative DNA damage induced by perfluorinated compounds in TK 6 cells. Environ Toxicol. 2016; 31(2):192–200. 10.1002/tox.22034 25113910
96 Jacquet N, Maire MA, Rast C, Bonnard M, Vasseur P. Perfluorooctanoic acid (PFOA) acts as a tumor promoter on Syrian hamster embryo (SHE) cells. Environ Sci Pollut Res Int. 2012; 19:2537–2549. 10.1007/s11356-012-0968-z 22828883
97 Lindeman B, Maass C, Duale N, Gutzkow KB, Brunborg G, Andreassen A. Effects of per- and polyfluorinated compounds on adult rat testicular cells following in vitro exposure. Reprod Toxicol. 2012; 33(4):531–537. 10.1016/j.reprotox.2011.04.001 21530637
98 Rogers AM, Andersen ME, Back KC. Mutagenicity of 2,3,7,8-tetrachlorodibenzo-p-dioxin and perfluoro-n-decanoic acid in L5178Y mouse-lymphoma cells. Mutat Res. 1982; 105(6):445–449. 10.1016/0165-7992(82)90192-0 7155164
99 Butenhoff JL, Kennedy GL, Jung R, Chang SC. Evaluation of perfluorooctanoate for potential genotoxicity. Toxicol Rep. 2014; 1:252–270. 10.1016/j.toxrep.2014.05.012 28962243
100 Takagi A, Sai K, Umemura T, Hasegawa R, Kurokawa Y. Short-term exposure to the peroxisome proliferators, perfluorooctanoic acid and perfluorodecanoic acid, causes significant increase of 8-hydroxydeoxyguanosine in liver DNA of rats. Cancer Lett. 1991; 57(1):55–60. 10.1016/0304-3835(91)90063-N 2025879
101 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of perfluorooctanoic acid (CAS No. 335-67-1) in Sprague Dawley (Hsd:Sprague Dawley SD) rats (perinatal and nonperinatal feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health; 2019. Technical Report Series No. 598. 10.22427/NTP-TR-598
102 Slotkin TA, MacKillop EA, Melnick RL, Thayer KA, Seidler FJ. Developmental neurotoxicity of perfluorinated chemicals modeled in vitro. Environ Health Perspect. 2008; 116(6):716–722. 10.1289/ehp.11253 18560525
103 Corsini E, Avogadro A, Galbiati V, dell’Agli M, Marinovich M, Galli CL, Germolec DR. In vitro evaluation of the immunotoxic potential of perfluorinated compounds (PFCs). Toxicol Appl Pharmacol. 2011; 250(2):108–116. 10.1016/j.taap.2010.11.004 21075133
104 Corsini E, Sangiovanni E, Avogadro A, Galbiati V, Viviani B, Marinovich M, Galli CL, Dell’Agli M, Germolec DR. In vitro characterization of the immunotoxic potential of several perfluorinated compounds (PFCs). Toxicol Appl Pharmacol. 2012; 258(2):248–255. 10.1016/j.taap.2011.11.004 22119708
105 Frawley RP, Smith M, Cesta MF, Hayes-Bouknight S, Blystone C, Kissling GE, Harris S, Germolec D. Immunotoxic and hepatotoxic effects of perfluoro-n-decanoic acid (PFDA) on female Harlan Sprague-Dawley rats and B6C3F1/N mice when administered by oral gavage for 28 days. J Immunotoxicol. 2018; 15(1):41–52. 10.1080/1547691X.2018.1445145 29514525
106 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
107 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
108 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
109 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
110 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero-dose control. Biometrics. 1971; 27:103–117. 10.2307/2528930 5547548
111 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28:519–531. 10.2307/2556164 5037867
112 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
113 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
114 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
115 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. 10.2307/2333011
116 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill Book Company, Inc.; 1957. p. 276–278, 412.
117 Girard DM, Sager DB. The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. 10.2307/2531963 3567307
118 Code of Federal Regulations (CFR). 21:Part 58.
119 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 S21:2–141. 10.1002/em.2850190603 1541260
120 MacGregor JT, Bishop ME, McNamee JP, Hayashi M, Asano N, Wakata A, Nakajima M, Saito J, Aidoo A, Moore MM, et al. Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: II. An efficient method of monitoring chromosomal damage in the rat. Toxicol Sci. 2006; 94(1):92–107. 10.1093/toxsci/kfl076 16888079
121 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry-and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
122 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
123 Igl BW, Bitsch A, Bringezu F, Chang S, Dammann M, Frotschl R, Harm V, Kellner R, Krzykalla V, Lott J, et al. The rat bone marrow micronucleus test: Statistical considerations on historical negative control data. Regul Toxicol Pharmacol. 2019; 102:13–22. 10.1016/j.yrtph.2018.12.009 30572081
124 National Toxicology Program (NTP). Toxicity studies of perfluorinated alkyl sulfonates (perfluorobutane sulfonic acid, perfluorohexane sulfonic acid potassium salt, and perfluorooctane sulfonic acid) administered by gavage to Sprague Dawley (Hsd:Sprague Dawley SD) rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health; 2019. Toxicity Study Report Series No. 96.
125 Vanden Heuvel JP, Kuslikis BI, Van Rafelghem MJ, Peterson RE. Disposition of perfluorodecanoic acid in male and female rats. Toxicol Appl Pharmacol. 1991; 107(3):450–459. 10.1016/0041-008X(91)90308-2 2000633
126 Chang ET, Adami HO, Boffetta P, Cole P, Starr TB, Mandel JS. A critical review of perfluorooctanoate and perfluorooctanesulfonate exposure and cancer risk in humans. Crit Rev Toxicol. 2014; 44 Suppl 1:1–81. 10.3109/10408444.2014.905767 24793953
127 Li K, Gao P, Xiang P, Zhang X, Cui X, Ma LQ. Molecular mechanisms of PFOA-induced toxicity in animals and humans: Implications for health risks. Environ Int. 2017; 99:43–54. 10.1016/j.envint.2016.11.014 27871799
128 Kawashima Y, Uy-Yu N, Kozuka H. Sex-related difference in the inductions by perfluoro-octanoic acid of peroxisomal beta-oxidation, microsomal 1-acylglycerophosphocholine acyltransferase and cytosolic long-chain acyl-CoA hydrolase in rat liver. Biochem J. 1989; 261(2):595–600. 10.1042/bj2610595 2570571
129 Yoshinari K, Sueyoshi T, Moore R, Negishi M. Nuclear receptor CAR as a regulatory factor for the sexually dimorphic induction of CYP2B1 gene by phenobarbital in rat livers. Mol Pharmacol. 2001; 59(2):278–284. 10.1124/mol.59.2.278 11160864
130 Post GB, Cohn PD, Cooper KR. Perfluorooctanoic acid (PFOA), an emerging drinking water contaminant: A critical review of recent literature. Environ Res. 2012;116:93–117. 10.1016/j.envres.2012.03.007 22560884
131 Lilienthal H, Dieter HH, Holzer J, Wilhelm M. Recent experimental results of effects of perfluoroalkyl substances in laboratory animals - Relation to current regulations and guidance values. Int J Hyg Environ Health. 2017; 220(4):766–775. 10.1016/j.ijheh.2017.03.001 28286084
132 Seacat AM, Thomford PJ, Hansen KJ, Olsen GW, Case MT, Butenhoff JL. Subchronic toxicity studies on perfluorooctanesulfonate potassium salt in cynomolgus monkeys. Toxicol Sci. 2002; 68(1):249–264. 10.1093/toxsci/68.1.249 12075127
133 Butenhoff J, Costa G, Elcombe C, Farrar D, Hansen K, Iwai H, Jung R, Kennedy G Jr, Lieder P, Olsen G, et al. Toxicity of ammonium perfluorooctanoate in male cynomolgus monkeys after oral dosing for 6 months. Toxicol Sci. 2002; 69(1):244–257. 10.1093/toxsci/69.1.244 12215680
134 Rosen MB, Das KP, Rooney J, Abbott B, Lau C, Corton JC. PPARalpha-independent transcriptional targets of perfluoroalkyl acids revealed by transcript profiling. Toxicology. 2017; 387:95–107. 10.1016/j.tox.2017.05.013 28558994
135 Thompson MB. Bile acids in the assessment of hepatocellular function. Toxicol Pathol. 1996; 24(1):62–71. 10.1177/019262339602400109 8839282
136 Ennulat D, Magid-Slav M, Rehm S, Tatsuoka KS. Diagnostic performance of traditional hepatobiliary biomarkers of drug-induced liver injury in the rat. Toxicol Sci. 2010; 116(2):397–412. 10.1093/toxsci/kfq144 20466777
137 Cattley RC, Cullen JM. Liver and gall bladder. In: Haschek WM, Rousseaux CG, Wallig MA, editors. Haschek and Rousseaux’s Handbook of Toxicologic Pathology. 3rd ed. London, UK: Elsevier; 2013. p. 1509–1566. 10.1016/B978-0-12-415759-0.00045-5
138 Ennulat D, Walker D, Clemo F, Magid-Slav M, Ledieu D, Graham M, Botts S, Boone L. Effects of hepatic drug-metabolizing enzyme induction on clinical pathology parameters in animals and man. Toxicol Pathol. 2010; 38(5):810–828. 10.1177/0192623310374332 20585144
139 Hall A, Elcombe C, Foster J, Harada T, Kaufmann W, Knippel A, Küttler K, Malarkey D, Maronpot R, Nishikawa A, et al. Liver hypertrophy: A review of adaptive (adverse and non-adverse) changes—conclusions from the 3rd International ESTP Expert Workshop. Toxicol Pathol. 2012; 40(7):971–994. 10.1177/0192623312448935 22723046
140 Kennedy GL Jr, Butenhoff JL, Olsen GW, O’Connor JC, Seacat AM, Perkins RG, Biegel LB, Murphy SR, Farrar DG. The toxicology of perfluorooctanoate. Crit Rev Toxicol. 2004; 34(4):351–384. 10.1080/10408440490464705 15328768
141 Konig B, Koch A, Spielmann J, Hilgenfeld C, Stangl GI, Eder K. Activation of PPARalpha lowers synthesis and concentration of cholesterol by reduction of nuclear SREBP-2. Biochem Pharmacol. 2007; 73(4):574–585. 10.1016/j.bcp.2006.10.027 17126302
142 Chen X, Matthews J, Zhou L, Pelton P, Liang Y, Xu J, Yang M, Cryan E, Rybczynski P, Demarest K. Improvement of dyslipidemia, insulin sensitivity, and energy balance by a peroxisome proliferator-activated receptor alpha agonist. Metabolism. 2008; 57(11):1516–1525. 10.1016/j.metabol.2008.06.005 18940388
143 Yan J, Chen B, Lu J, Xie W. Deciphering the roles of the constitutive androstane receptor in energy metabolism. Acta Pharmacol Sin. 2015; 36(1):62. 10.1038/aps.2014.102 25500869
144 Walker D, Tomlinson L. Lipids. In: Kurtz DM, Traylos GS, editors. The Clinical Chemistry of Laboratory Animals. Boca Raton, FL: CRC Press; 2018. p. 777–871.
145 Van Rafelghem MJ, Inhorn SL, Peterson RE. Effects of perfluorodecanoic acid on thyroid status in rats. Toxicol Appl Pharmacol. 1987; 87(3):430–439. 10.1016/0041-008X(87)90248-1 3564018
146 Lau C, Thibodeaux JR, Hanson RG, Rogers JM, Grey BE, Stanton ME, Butenhoff JL, Stevenson LA. Exposure to perfluorooctane sulfonate during pregnancy in rat and mouse. II: Postnatal evaluation. Toxicol Sci. 2003; 74(2):382–392. 10.1093/toxsci/kfg122 12773772
147 Thibodeaux JR, Hanson RG, Rogers JM, Grey BE, Barbee BD, Richards JH, Butenhoff JL, Stevenson LA, Lau C. Exposure to perfluorooctane sulfonate during pregnancy in rat and mouse. I: Maternal and prenatal evaluations. Toxicol Sci. 2003; 74(2):369–381. 10.1093/toxsci/kfg121 12773773
148 Chang SC, Thibodeaux JR, Eastvold ML, Ehresman DJ, Bjork JA, Froehlich JW, Lau C, Singh RJ, Wallace KB, Butenhoff JL. Thyroid hormone status and pituitary function in adult rats given oral doses of perfluorooctanesulfonate (PFOS). Toxicology. 2008; 243(3):330–339. 10.1016/j.tox.2007.10.014 18063289
149 Rosol TJ, Delellis RA, Harvey PW, Sutcliffe C. Endocrine system. In: Haschek WM, Rousseaux CG, Wallig MA, editors. Haschek and Rousseaux’s Handbook of Toxicologic Pathology. Vol. 3. London, UK: Elsevier; 2013. p. 2391–2492. 10.1016/B978-0-12-415759-0.00058-3
150 Luebker DJ, York RG, Hansen KJ, Moore JA, Butenhoff JL. Neonatal mortality from in utero exposure to perfluorooctanesulfonate (PFOS) in Sprague-Dawley rats: Dose-response, and biochemical and pharamacokinetic parameters. Toxicology. 2005; 215(1-2):149–169. 10.1016/j.tox.2005.07.019 16129535
151 Chang SC, Thibodeaux JR, Eastvold ML, Ehresman DJ, Bjork JA, Froehlich JW, Lau CS, Singh RJ, Wallace KB, Butenhoff JL. Negative bias from analog methods used in the analysis of free thyroxine in rat serum containing perfluorooctanesulfonate (PFOS). Toxicology. 2007; 234(1-2):21–33. 10.1016/j.tox.2007.01.020 17368689
152 Weiss JM, Andersson PL, Lamoree MH, Leonards PE, van Leeuwen SP, Hamers T. Competitive binding of poly-and perfluorinated compounds to the thyroid hormone transport protein transthyretin. Toxicol Sci. 2009; 109(2):206–216. 10.1093/toxsci/kfp055 19293372
153 Warner MH, Beckett GJ. Mechanisms behind the non-thyroidal illness syndrome: An update. J Endocrinol. 2010; 205(1):1–13. 10.1677/JOE-09-0412 20016054
154 Fry MM. Anemia of inflammatory, neoplastic, renal, and endocrine diseases. In: Weiss DJ, Wardrop KJ, editors. Schalm’s Veterinary Hematology. 6th ed. Hoboken, NJ: Wiley-Blackwell; 2010. p. 246–250.
155 Everds NE, Snyder PW, Bailey KL, Bolon B, Creasy DM, Foley GL, Rosol TJ, Sellers T. Interpreting stress responses during routine toxicity studies: A review of the biology, impact, and assessment. Toxicol Pathol. 2013; 41(4):560–614. 10.1177/0192623312466452 23475558
156 Creasy D, Bube A, de Rijk E, Kandori H, Kuwahara M, Masson R, Nolte T, Reams R, Regan K, Rehm S, et al. Proliferative and nonproliferative lesions of the rat and mouse male reproductive system. Toxicol Pathol. 2012; 40(6) Suppl:40s–121s. 10.1177/0192623312454337 22949412
157 Creasy DM. Pathogenesis of male reproductive toxicity. Toxicol Pathol. 2001; 29(1):64–76. 10.1080/019262301301418865 11215686
158 Creasy DM, Chapin RE. Male reproductive system. In: Haschek WM, Rousseaux CG, Wallig MA, editors. Haschek and Rousseaux’s Handbook of Toxicologic Pathology. Vol. 3. London, UK: Elsevier; 2013. p. 2493–2598. 10.1016/B978-0-12-415759-0.00059-5
159 Zhou Y, Hu L-W, Qian ZM, Chang J-J, King C, Paul G, Lin S, Chen P-C, Lee YL, Dong G-H. Association of perfluoroalkyl substances exposure with reproductive hormone levels in adolescents: By sex status. Environ Int. 2016;94:189–195. 10.1016/j.envint.2016.05.018 27258660
160 Chapin RE, Creasy DM. Assessment of circulating hormones in regulatory toxicity studies II. Male reproductive hormones. Toxicol Pathol. 2012; 40(7):1063–1078. 10.1177/0192623312443321 22552397
161 Damsch S, Eichenbaum G, Tonelli A, Lammens L, Van den Bulck K, Feyen B, Vandenberghe J, Megens A, Knight E, Kelley M. Gavage-related reflux in rats: Identification, pathogenesis, and toxicological implications [review]. Toxicol Pathol. 2011; 39(2):348–360. 10.1177/0192623310388431 21422261
162 Ling G, Gu J, Genter MB, Zhuo X, Ding X. Regulation of cytochrome P450 gene expression in the olfactory mucosa. Chem Biol Interact. 2004; 147(3):247–258. 10.1016/j.cbi.2004.02.003 15135081