# Discussion

Widespread exposure to per- and polyfluorinated alkyl substances (PFAS), combined with a lack of data for some of the less commonly detected class members, has underscored the need for class comparisons. Although a large amount of research has focused on the higher-production entities, perfluorooctane sulfonic acid (PFOS) and perfluorooctane octanoic acid (PFOA), few studies to date have compared toxicities across the class of straight-chained PFAS. Toxicity Study Report 96^124^ and this report, Toxicity Study Report 97, detail results from 28-day studies evaluating the toxicity of seven straight-chained sulfonate and carboxylate PFAS of varying chain length. Importantly, these studies included biosampling of PFAS concentrations in the plasma and liver (males only) to facilitate potency comparisons and future dose-response modeling. Wyeth-14,643 (WY) was included with the comparison studies as an indicator of potential peroxisome proliferator-activated receptor alpha (PPARα)-mediated toxicity. This section provides an overview of major endpoints of toxicity, a brief comparison across the evaluated PFAS, and a discussion of potential mechanisms of toxicity.

To aid in determining relative potency of PFAS, these studies evaluated the plasma and liver (males only) concentrations of perfluorohexanoic acid (PFHxA), PFOA, perfluorononanoic acid (PFNA), and perfluorodecanoic acid (PFDA) to provide a direct comparison of internal exposure. In general, the levels of each chemical followed a similar pattern to that described in the literature on the kinetics of that PFAS. Shorter-chain PFAS typically have shorter half-lives than do longer-chain PFAS,^25,28^ reflected herein by the higher plasma concentrations as chain length increased; for example, as illustrated with the dose-normalized plasma concentrations across the females (2 to 6 µM/mmol/kg in PFHxA compared to 70,000 to 100,000 mM/mmol/kg in PFDA). Longer-chain PFAS (PFNA, PFDA) are reported to have preferential biliary elimination over urinary elimination,^29,33^ and the higher liver levels and liver/plasma ratios in those PFAS compared to PFHxA and PFOA—which had liver/plasma ratios approximately 0.5 and 1, respectively—reflect this difference. Sex differences in the urinary elimination of PFAS in rodents have also been reported, specifically for the shorter-chain PFAS, with females exhibiting more rapid elimination than males.^27,125^ The plasma levels observed in male and female rats administered PFOA underscore this contrast (15,000 to 80,000 µM/mmol/kg in males compared to 80 to 200 µM/mmol/kg in females). In rats administered PFHxA, relatively low plasma levels precluded determination of sex-related differences in exposure. In general, the levels of PFAS measured in these studies were orders of magnitude higher than those measured in humans.^8^

The toxicity comparisons of a chemical could be evaluated from an exposure standpoint in several ways (e.g., comparing external dose versus internal dose as C_max_, area under the curve [AUC], or final blood measurements). In addition, each toxicity or effect may be better explained using a different exposure paradigm. An extensive evaluation of these possible exposure comparisons and response models is beyond the scope of this report, but a comparison of findings based on external dose (mmol/kg/day) and plasma levels on day 29 (µM) allows for a qualitative summary of the findings and highlights the challenges in potency estimations. Highlighted are select liver endpoints and thyroid hormone measurements graphed against plasma levels or administered dose (Figure 33, Figure 34, Figure 35, Figure 36, Figure 37, Figure 38, Figure 39, Figure 40, Figure 41, Figure 42, Figure 43, Figure 44) because these findings were generally present across all the chemicals. Briefly, toxicity comparisons based on dose administered generally show PFDA to be the most potently toxic of the four PFAS carboxylic acids and PFHxA to be the least potent, with PFNA and PFOA closer to PFDA in potency than PFHxA. These findings are described in more detail below.

Figure 33

Average Magnitude of Change for Cyp4a1 Expression (A, B), Cyp2b1 Expression (C, D), Liver Weight (E, F), and Hepatocellular Hypertrophy (G, H) in Male Sprague Dawley Rats Administered Perfluorohexanoic Acid, Perfluorooctanoic Acid, Perfluorononanoic Acid, or Perfluorodecanoic Acid by Gavage for 28 Days

PFHxA = perfluorohexanoic acid; PFOA = perfluorooctanoic acid; PFNA = perfluorononanoic acid; PFDA = perfluorodecanoic acid; WY = Wyeth-14,643.

Comparisons of a dose administered (mmol/kg/day) basis (A, C, E, G) versus a plasma level (µM) basis (B, D, F, H). Wyeth-14,643 (PPARα agonist) is used for comparison on a dose administered (mmol/kg/day) basis.

Figure 34

Average Magnitude of Change for Cyp4a1 Expression (A, B), Cyp2b1 Expression (C, D), Liver Weight (E, F), and Hepatocellular Hypertrophy (G, H) in Female Sprague Dawley Rats Administered Perfluorohexanoic Acid, Perfluorooctanoic Acid, Perfluorononanoic Acid, or Perfluorodecanoic Acid by Gavage for 28 Days

PFHxA = perfluorohexanoic acid; PFOA = perfluorooctanoic acid; PFNA = perfluorononanoic acid; PFDA = perfluorodecanoic acid; WY = Wyeth-14,643.

Comparisons of a dose administered (mmol/kg/day) basis (A, C, E, G) versus a plasma level (µM) basis (B, D, F, H). Wyeth-14,643 (PPARα agonist) is used for comparison on a dose administered (mmol/kg/day) basis.

Figure 35

Comparison of Magnitude of Change for Select Liver Endpoints in Sprague Dawley Rats Administered Perfluorohexanoic Acid by Gavage for 28 Days

Figure 36

Comparison of Magnitude of Change for Select Liver Endpoints in Sprague Dawley Rats Administered Perfluorooctanoic Acid by Gavage for 28 Days

Figure 37

Comparison of Magnitude of Change for Select Liver Endpoints in Sprague Dawley Rats Administered Perfluorononanoic Acid by Gavage for 28 Days

Figure 38

Comparison of Magnitude of Change for Select Liver Endpoints in Sprague Dawley Rats Administered Perfluorodecanoic Acid by Gavage for 28 Days

Figure 39

Average Magnitude of Change for Serum Levels of Thyroid Stimulating Hormone (A, B), Triiodothyronine (C, D), Thyroxine (E, F), and Free Thyroxine (G, H) in Male Sprague Dawley Rats Administered Perfluorohexanoic Acid, Perfluorooctanoic Acid, Perfluorononanoic Acid, or Perfluorodecanoic Acid by Gavage for 28 Days

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine; PFHxA = perfluorohexanoic acid; PFOA = perfluorooctanoic acid; PFNA = perfluorononanoic acid; PFDA = perfluorodecanoic acid; WY = Wyeth-14,643.

Comparisons of a dose administered (mmol/kg/day) basis (A, C, E, G) versus a plasma level (µM) basis (B, D, F, H). Wyeth-14,643 (PPARα agonist) is used for comparison on a dose administered (mmol/kg/day) basis.

Figure 40

Average Magnitude of Change for Serum Levels of Thyroid Stimulating Hormone (A, B), Triiodothyronine (C, D), Thyroxine (E, F), and Free Thyroxine (G, H) in Female Sprague Dawley Rats Administered Perfluorohexanoic Acid, Perfluorooctanoic Acid, Perfluorononanoic Acid, or Perfluorodecanoic Acid by Gavage for 28 Days

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine; PFHxA = perfluorohexanoic acid; PFOA = perfluorooctanoic acid; PFNA = perfluorononanoic acid; PFDA = perfluorodecanoic acid; WY = Wyeth-14,643.

Comparisons are made on a dose administered (mmol/kg/day) basis (A, C, E, G) and plasma level (µM) basis (B, D, F, H). Wyeth-14,643 (PPARα agonist) is used for comparison on a dose administered (mmol/kg/day) basis.

Figure 41

Comparison of Magnitude of Change for Thyroid Hormone Levels in Sprague Dawley Rats Administered Perfluorohexanoic Acid by Gavage for 28 Days

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine.

Figure 42

Comparison of Magnitude of Change for Thyroid Hormone Levels in Sprague Dawley Rats Administered Perfluorooctanoic Acid by Gavage for 28 Days

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine.

Figure 43

Comparison of Magnitude of Change for Thyroid Hormone Levels in Sprague Dawley Rats Administered Perfluorononanoic Acid by Gavage for 28 Days

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine.

Figure 44

Comparison of Magnitude of Change for Thyroid Hormone Levels in Sprague Dawley Rats Administered Perfluorodecanoic Acid by Gavage for 28 Days

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine.

A major target organ of toxicity for PFHxA, PFOA, PFNA, and PFDA was the liver (Figure 33, Figure 34), which is consistent with the greater PFAS class. Inclusion of WY allows for a direct comparison of a known PPARα with a PFAS, which have been shown to activate PPARα, constitutive androstane receptor (CAR), pregnane X receptor (PXR), and other receptors.^126,127^ Gene expression of Cyp4a1, Acox1, Cyp2b1, and Cyp2b2 was measured to probe specific nuclear receptor pathways: Cyp2b1/Cyp2b2 activation indicates CAR-mediated activity, and Acox1/Cyp4a1 activation suggests PPARα activity. All five chemicals, at the highest surviving dose, induced the expression of all four genes in males and females. Males generally had a higher magnitude of induction for Acox1/Cyp4a1 than females, and females exhibited a higher magnitude of induction for Cyp2b1/Cyp2b2 than males. Sexually dimorphic responses to PPARα and CAR activation in rats have been reported previously,^128,129^ thus different sensitivities to activation are not unexpected. When comparing the five chemicals using the administered dose as the exposure metric, PFHxA is the least potent and PFDA is generally the most potent for Cyp induction, with WY in between (Figure 33A–D, Figure 34A–D). Using plasma levels (molarity) as the exposure metric, there is a high degree of overlap in males, whereas PFHxA is the most potent in females. These patterns of potency were also reflective of the changes in liver weight and the occurrences of hepatocellular hypertrophy (Figure 33E–H, Figure 34E–H). Overall, the similarities in gene induction patterns suggest a high degree of overlap between PFAS and WY with respect to nuclear receptor activation. Several toxicity endpoints described below may be mediated by PPARα and/or CAR-related activity.

In the present studies, all four perfluoroalkyl carboxylates increased liver weights in males and females; however, histologic lesions in the liver varied somewhat across these chemicals and between sexes (Figure 35, Figure 36, Figure 37, and Figure 38). Hepatocyte cytoplasmic alteration and hepatocyte hypertrophy were observed in males and females administered PFHxA, PFOA, PFNA, or PFDA. In the short-chain PFAS, hepatocyte necrosis was only observed in one male administered 1,000 mg/kg/day PFHxA and one male administered 5 mg/kg/day PFOA. Necrosis was more frequently observed in PFNA- and PFDA-treated males and females and occurred in a dose-dependent manner. Hepatocyte hypertrophy and cytoplasmic alteration were also observed in the PPARα agonist WY, but hepatocyte necrosis was not. Hepatocyte hypertrophy observed with PFAS is likely due to the peroxisome proliferation. This is also supported by the elevated Acox1 and Cyp4a1 enzymes known to be inducible by PPARα agonists. Hepatocyte hypertrophy can also be partially mediated through CAR. It is worth noting that the current studies were not designed to evaluate the other possible mechanisms; however, attributing the effects of PFAS solely to PPARα activation would misrepresent the complexity of the biological activity of this chemical class.^130-134^ In short, it is possible that other mechanisms beyond PPARα- and CAR-mediated mechanisms are involved in the induction of hepatocyte hypertrophy.

Beyond histopathology, PFAS administration increased the levels of serum biomarkers associated with hepatobiliary injury. In general, total bile acid concentrations in PFDA and PFNA studies had greater than a threefold increase in the higher-dose groups compared to concurrent vehicle controls. Increases of this magnitude are indicative of impaired bile flow or (intrahepatic) cholestasis, the causes of which include physical disruption of bile flow through the biliary system or perturbation of bile acid formation and excretion at the cellular level.^135^ In addition, total bilirubin concentration, another marker of cholestasis, was substantially elevated in most high-dose PFNA and PFDA male and female groups; this change was driven by increases in both direct and indirect bilirubin. Increases in total bile acid concentration were also observed with PFOA and PFHxA (PFOA males and PFHxA males and females) but to a lesser extent, and a small increase in direct (but not total) bilirubin was observed in high-dose PFOA males. There were mild increases in alkaline phosphatase (ALP) activity in both sexes in all four carboxylate studies. ALP is considered a poor marker of cholestasis in rats^136,137^; thus, although the increases in ALP may be due to cholestasis, limited studies have shown an association between the administration of PPARα agonists and mild increases in serum ALP activity when the only histologic effect observed was centrilobular hypertrophy.^138^ In general, there were mild (≤onefold) increases in serum ALT, AST, and/or SDH activities in both sexes of the higher-dose groups of all the carboxylates. These enzymes are biomarkers of hepatocellular injury, and their increases correlate with the observed hepatocellular necrosis, as well as the finding of cholestasis as hepatocellular injury can occur secondary to cholestasis.^136^ In some cases, indications of cholestasis and histopathologic necrosis were not found, suggesting reversible hepatocellular injury resulting in leakage of these enzymes from the cytoplasm of the hepatocytes. Additionally, and similar to ALP activity, it has been shown that mild (≤1.5-fold) increases in hepatic and serum transaminases are associated with the administration of hepatic microsomal enzyme inducer compounds, including PPARα agonists.^136,138,139^ In addition to increases in liver enzyme activities, albumin concentrations were decreased in some dose groups across the four chemicals. These decreases may be related to the decreases in food intake and body weight, or they may be due to a functional perturbation of albumin metabolism by the liver. Hepatobiliary injury biomarker changes similar to those observed in the current study have been reported in the literature.^44,140^ Many of these markers of hepatic injury were present in WY-treated animals, including increased direct bilirubin and bile acids in males and increased ALT, ALP, SDH, and AST in males and females.

There were decreases in cholesterol concentrations in the PFHxA-, PFOA-, PFNA- and PFDA-dosed males, and the PFOA- and PFDA-dosed females. A decrease in triglyceride concentrations was also observed in PFOA, PFNA, and PFDA males. Changes in lipid markers are consistent with the known effects of PPARα activation on lipid metabolism, which includes increases in peroxisomal fatty acid β-oxidation and effects on lipid transport. Studies have shown that administration of PPARα agonists to rats, including carboxylated PFAS, results in lowered circulating triglyceride and cholesterol concentrations.^44,141,142^ CAR is also an important regulator of cholesterol homeostasis, and its activation may also be related to the observed lipid alterations.^143^ In addition, thyroid hormone triiodothyronine (T3) directly influences activities of critical enzymes in lipolytic pathways, and hypothyroidism in rats results in decreased blood triglyceride concentrations.^144^ Globulin concentrations were decreased in males and females in all four perfluoroalkyl carboxylate studies. In each case, the decrease in the globulin concentration contributed to an increase in the albumin/globulin (A/G) ratio. The globulin fraction of serum total protein consists of the α -, β-, and γ-globulins. In general, α- and β-globulins are produced by hepatocytes and the γ-globulins (immunoglobulins) by B-lymphocytes. It is not known whether these chemicals cause perturbation of the hepatic or lymphocytic production/metabolism of these proteins. WY-dosed animals did not exhibit the same alterations in cholesterol and triglyceride levels as PFAS-dosed animals; however, they did exhibit decreased globulin concentration and increased A/G ratio.

Changes in thyroid hormone concentrations were observed across the four perfluoroalkyl carboxylates (Figure 39, Figure 40, Figure 41, Figure 42, Figure 43 and Figure 44). Total thyroxine (T4) and free T4 were generally decreased in all animals administered carboxylated PFAS. Total T3 was not altered in a consistent manner across the chemicals or sexes, nor was thyroid stimulating hormone (TSH) increased in response to the lower T4 concentrations aside from females administered 100 mg/kg/day PFOA. Except for the high-dosed PFOA males and females, which exhibited thyroid gland follicular hypertrophy, there were no histopathologic changes in the thyroid gland. The few known studies evaluating effects of oral administration of these carboxylated PFAS (PFDA) on thyroid hormone status reported similar findings,^145^ and several studies of sulfonated PFAS reported decreases in thyroid hormones without compensatory increases in TSH.^132,146-148^ Production and release of thyroid hormones is regulated by thyroid-releasing hormone (hypothalamus) and TSH (pituitary) in what is referred to as the hypothalamic-pituitary-thyroid axis where decreases in circulating levels of free T4 and free T3 result in a compensatory increase in TSH. Archetypal xenobiotics that disrupt this axis in rats, causing decreases in thyroid hormones (either as a direct or indirect thyroid effect) with compensatory increases in TSH, and thyroid gland follicular cell hyperplasia, include sulfonamides, FD&C Red No. 3, and phenobarbital.^149^

The reason for a lack of TSH response in the face of substantially low thyroid hormone concentrations in these perfluoroalkyl carboxylate studies is not clear and not consistent with a disruption in the hypothalamic-pituitary-thyroid axis. It has been shown that PFAS can bind to proteins, including albumin and transthyretin (previously prealbumin), which are transport proteins for thyroid hormones. Several PFOS studies (rat and monkey) have shown low free T4 levels as measured by analog radioimmunoassays (RIA) (the method used in the present studies), but no change in free T4 levels when measured by equilibrium dialysis followed by RIA (ED-RIA).^132,148,150,151^ ED-RIA is considered the reference method for the determination of free T4 and is the standard by which other methods are compared. These findings are consistent with PFOS competing with T4 for binding to serum proteins, creating a negative bias in the (competitive binding) analog RIA method. A study evaluating the competitive binding of various PFAS to transthyretin confirmed the ability of these perfluoroalkyl carboxylates to bind to transthyretin.^152^ Nevertheless, decreases in total T4 were found in the aforementioned studies and in the current studies. It is plausible that the decreases in total T4 may be related to activation of PPARα and CAR, resulting in an increase in thyroxine-UDP glucuronosyltransferase and accelerated degradation of thyroxine by the liver. While the total T4 was decreased, the lack of a TSH response in most cases and the findings by several researchers of an unaffected free T4 by ED-RIA do not support a state of classical hypothyroidism, and the effect is more similar to the profile of nonthyroidal illness syndrome (a.k.a. euthyroid sick syndrome).^153^ Other researchers have also concluded, on the basis of the thyroid-related results of their studies, that the administration of PFAS (PFDA, PFOS) does not cause a classical hypothyroid state.^145,148,150^

Hematology parameters were also altered for these chemicals. In PFDA males and females and PFNA males, dose-dependent decreases in reticulocytes occurred, with their numbers being severely decreased in the higher-dose groups (≤10% of controls). In addition, increases in some erythron parameters characterized by increased erythrocyte counts, increased hematocrit, or increased hemoglobin concentration (in total indicative of hemoconcentration) were observed. The mean cell volume was decreased, which was driven by the severe decreases in the reticulocytes as reticulocytes are larger in size. Moderate to severe bone marrow hypocellularity in the higher-dose groups was also observed. The decreases in reticulocyte counts and the bone marrow hypocellularity are consistent with suppression of erythropoiesis. Because rat erythrocytes have a circulating life span of approximately 60 days and the study was 28 days, it may be that the hypocellularity in the bone marrow was not fully reflected in the circulating total red blood cell mass (i.e., erythrocyte count). The bone marrow suppression was due in part to chronic stress, especially at higher doses, as evidenced by the decreases in body weight; however, a direct effect cannot be ruled out. The hemoconcentration (and increases in blood urea nitrogen) was due to a decrease in water intake. Bone marrow hypocellularity and decreases in the erythron were observed in the PFOA male and female rats and were likely secondary to chronic stress. In addition, low thyroid hormones can cause decreases in the erythron.^154^

In the PFHxA-treated male and female rats there was a dose-dependent hypochromic, macrocytic regenerative decrease in the red blood cell mass (i.e., regenerative anemia). This particular combination of complete blood count (CBC) findings is indicative of either red blood cell loss (e.g., GI hemorrhage) or red blood cell destruction (hemolysis). Clinical observations and histopathologic evidence of hemorrhage were not observed. In general, hemolysis occurs within the vasculature (intravascular) or as erythrophagocytosis in the spleen or liver (extravascular). Indications of hemolysis were not seen on peripheral blood smears (e.g., Heinz bodies, blister cells), nor were indications of hemolysis observed on histopathology (e.g., increased pigment, erythrophagocytosis in the spleen). Thus, the basic underlying mechanism for the regenerative anemia is not known at this time. Similar hematology findings in PFHxA exposed rats have been reported in the literature.^44,75^ In PFNA and PFDA males and females, there were increases in thymic atrophy in the higher-dose groups. This change is most likely associated with stress as thymic atrophy is one of the commonly recognized stress responses in toxicity studies.^155^ In addition, atrophy in the lymphoid organs and decreases in the lymphocyte counts (males) observed in PFNA-treated animals is also very likely associated with stress.

Interstitial cell atrophy in the testis was present in PFNA- and PFDA-treated males. Interstitial cell atrophy is known to occur with reduced testosterone levels, and there was a significant reduction of testosterone in PFNA- and PFDA-treated males. Increased apoptosis of epididymal epithelium in PFNA-treated males also supports the possibility of reduced testosterone levels.^156^ However, other changes associated with reduced testosterone such as atrophy of accessory sex glands and the presence of increased numbers of apoptotic pachytene spermatocytes in Stage VII and VIII tubules were not observed.^157,158^ An epidemiology study found a negative association between PFAS and testosterone levels in humans.^159^ In addition to interstitial cell atrophy, there were degenerate changes, spermatid retention in the seminiferous tubules. These changes can result from either a reduced testosterone level or from Sertoli cell toxicity.^157^ The presence of exfoliated germ cells and hypospermia in the epididymis also supports the changes in the testis. Furthermore, testicular and epididymal weights were also significantly affected. In PFNA-treated males, there was an increase in the incidence of sperm granulomas in the epididymis. Damage to epididymal epithelium can result in reduced resorption of seminiferous tubule fluid and sperm granuloma formation.^157^ Sperm parameters at the respective highest doses assessed were concordantly affected (to varying degrees). Epididymal sperm counts at the highest dose assessed were similarly lowered by PFHxA, PFNA, or PFDA exposure. Spermatid counts were not affected or were minimally affected, and sperm motility was not affected by exposure to any of the chemicals. This minimal testicular response in spermatid counts is consistent with the observed histopathologic findings of retained spermatids offsetting the epithelial degeneration response. The sperm that subsequently enter the cauda epididymis are motile. If the dosing duration would have been longer, the spermatid counts would have been expected to be concomitantly decreased. The observed effects on spermatid number are consistent with the testosterone levels needed for normal spermatogenesis. Given the consistency of response in male endpoints affected, it appears that the mode of action for the testicular responses is consistent among the agents assessed. Irrespective of the mechanism(s) involved, it is possible that PFNA and PFDA target the testes. However, both PFNA and PFDA treatment also induced substantial decreases in the body weights. Therefore, the indirect effect of reduced body weight compared to controls as the cause of the testicular changes cannot be ruled out.^160^ Testicular toxicity was not observed in the animals treated with WY, which was used as a positive control for PPARα induction. Therefore, testicular toxicity observed in PFNA- and PFDA-treated animals is not likely related to PPARα activation. Unlike the response observed in males, females exhibited different chemical-related responses, ranging from no apparent effects on cyclicity (PFHxA) to sustained diestrus (PFDA).

Other sites of toxicity identified across the carboxylated PFAS include the nose, and forestomach. Olfactory epithelium degeneration, hyperplasia, and inflammation were observed in PFHxA, PFOA (females), and to a lesser extent in PFNA-exposed animals. The pattern of nasal pathology in this study was not suggestive of gavage-related reflux described in rats.^161^ Because the olfactory epithelium can metabolize xenobiotics,^162^ the changes could be a direct effect of administration of PFAS. However, it is not possible to determine the underlying mechanism with the available data. Hyperplasia of olfactory epithelium appeared to be a response to degeneration and loss of the olfactory epithelium. In addition to olfactory epithelial changes, the respiratory epithelium of the nasal cavity was also affected in animals treated with PFOA. Forestomach epithelium hyperplasia was observed in PFNA males and females and in PFDA males at the higher dose levels. This is most likely a result of mucosal irritation due to the administered chemical.

All four PFAS were negative in bacterial mutagenicity tests, similar to what has been reported for these chemicals in the literature, with the exception of PFOA, which gave nonreproducible responses over three independent trials in a single strain, leading to a call of equivocal. No indication of chromosomal damage, as measured in an erythrocyte micronucleus assay, was seen in male or female rats exposed to PFHxA, PFNA, PFDA, or WY or female rats exposed to PFOA. Although a positive response was indicated for male rats exposed to PFOA, the response was within the laboratory’s historical control range, and therefore the biologic significance of the increase is questionable. The bone marrow clearly was a target for these PFAS, as indicated by the changes in % PCEs observed in the micronucleus assay and hematological changes observed in clinical chemistry studies. The four PFAS showed differential effects on % PCEs. Whereas PFHxA increased the % PCE in male and female rats, PFOA did not affect % PCE in rats, and % PCE was severely reduced in male rats exposed to PFNA or PFDA, but not females. The stimulus of % PCE in rats exposed to PFHxA at the two highest doses and the reduction in % PCE with increasing chain length was consistent with hematological observations. Also, although PFOA did not appear to affect % PCE, hematological effects were observed in the clinical chemistry studies.

The studies reported here and in Toxicity Study Report 96^124^ provide data for a comparison of several members of the PFAS class. The liver and thyroid hormones were common targets for all seven PFAS evaluated in these studies. In addition, there were histopathologic findings in the forestomach and nose that were common between perfluoroalkyl sulfonates and carboxylates. Increases in PPARα- and CAR-related genes occurred in most doses for all seven PFAS. In some cases, this corresponded with increased liver weights at the lowest dose tested. With the inclusion of WY as a known PPARα agonist, toxicities that are present in animals administered PFAS, but not WY, may be attributed to mechanisms other than PPARα. This includes hematologic and reproductive toxicity, as well as several nasal and forestomach lesions. Complete quantitative comparisons of these chemicals will require a more in-depth evaluation of the exposures between chemicals that could include AUC or C_max_ evaluations. The 28-day studies discussed in this report help to provide exposure and mechanistic context to facilitate extrapolation of findings.