# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: http://doi.org/10.22427/NTP-OTHER-2.

## Twenty-eight-day Studies

### Perfluorohexanoic Acid (PFHxA)

All rats survived until the end of the study (Table 4). No clinical observations related to PFHxA administration were observed. Body weights of 1,000 mg/kg/day males were 12% and 13% less than those of the vehicle controls on days 22 and 29, respectively; body weights of female dose groups remained within 10% of the vehicle control body weights throughout the study (Table 4; Figure 1).

Table 4 Mean Body Weights and Survival of Rats in the 28-day Gavage Study of Perfluorohexanoic Acid^a^

Day | Vehicle Control | | 62.6 mg/kg/day | | | 125 mg/kg/day | | | 250 mg/kg/day | | | 500 mg/kg/day | | | 1,000 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 253 | 10 | 246 | 97 | 10 | 252 | 100 | 10 | 252 | 99 | 10 | 256 | 101 | 10 | 253 | 100 | 10
8 | 276 | 10 | 275 | 100 | 10 | 270 | 98 | 10 | 273 | 99 | 10 | 274 | 99 | 10 | 260 | 94 | 10
15 | 296 | 10 | 301 | 102 | 10 | 292 | 99 | 10 | 293 | 99 | 10 | 291 | 99 | 10 | 267 | 90 | 10
22 | 316 | 10 | 327 | 104 | 10 | 310 | 98 | 10 | 313 | 99 | 10 | 307 | 97 | 10 | 278 | 88 | 10
29 | 331 | 10 | 340 | 103 | 10 | 326 | 99 | 10 | 327 | 99 | 10 | 319 | 96 | 10 | 287 | 87 | 10
Female
1 | 198 | 10 | 195 | 99 | 10 | 196 | 99 | 10 | 197 | 100 | 10 | 195 | 99 | 10 | 195 | 98 | 10
8 | 203 | 10 | 205 | 101 | 10 | 209 | 103 | 10 | 209 | 103 | 10 | 207 | 102 | 10 | 202 | 100 | 10
15 | 219 | 10 | 216 | 99 | 10 | 214 | 98 | 10 | 218 | 100 | 10 | 214 | 98 | 10 | 212 | 97 | 10
22 | 230 | 10 | 225 | 98 | 10 | 225 | 98 | 10 | 228 | 99 | 10 | 222 | 97 | 10 | 219 | 95 | 10
29 | 225 | 10 | 227 | 101 | 10 | 229 | 102 | 10 | 228 | 102 | 10 | 223 | 99 | 10 | 220 | 98 | 10

^a^ One-half the dose was administered twice daily.

Figure 1

Growth Curves for Rats Administered Perfluorohexanoic Acid by Gavage for 28 Days

Plasma concentrations of PFHxA increased with increasing dose in both males and females (Table 5). Males generally had a higher (1.6- to threefold) plasma concentration compared to females across the dose groups. When normalized to dose administered (µM/mmol/kg), male plasma concentrations were generally similar (<twofold) across the 62.6 to 500 mg/kg/day dose groups, with a near twofold increase from the 62.6 mg/kg/day dose group to the 1,000 mg/kg/day dose group, which was greater than dose-proportional. Females exhibited a similar pattern with comparable values at the lower doses (<twofold) and a threefold increase from the 62.6 mg/kg/day dose group to the 1,000 mg/kg/day dose group.

Table 5 Perfluorohexanoic Acid Concentrations in Tissues of Rats in the 28-day Gavage Study of Perfluorohexanoic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day | 1,000 mg/kg/day
Millimolar Dose (mmol/kg/day) | 0 | 0.199 | 0.398 | 0.796 | 1.592 | 3.184
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Plasma
Plasma Concentration (ng/mL) | BD | 378 ± 178 | 503 ± 66 | 1,297 ± 265 | 3,339 ± 497 | 10,899 ± 2,516
Plasma Concentration (µM) | BD | 1.2 ± 0.6 | 1.6 ± 0.2 | 4.1 ± 0.8 | 10.6 ± 1.6 | 34.7 ± 8.0
Normalized Plasma Concentration (µM/mmol/kg) | NA | 6.0 ± 2.8 | 4.0 ± 0.5 | 5.2 ± 1.1 | 6.7 ± 1.0 | 10.9 ± 2.5
Liver
Liver Concentration (ng/g) | BD | BD | BD | 655 ± 148 | 1,552 ± 222 | 4,845 ± 1,056
Liver Concentration (µM)^b^ | BD | BD | BD | 2.1 ± 0.5 | 4.9 ± 0.7 | 15.4 ± 3.4
Normalized Liver Concentration (µM/mmol/kg) | NA | BD | BD | 2.6 ± 0.6 | 3.1 ± 0.4 | 4.8 ± 1.1
Liver/Plasma Ratio | NA | BD | BD | 0.52 ± 0.06 | 0.47 ± 0.01 | 0.44 ± 0.02
Female
Plasma
Plasma Concentration (ng/mL) | BD | 129 ± 16 | 292 ± 58 | 475 ± 77 | 1,668 ± 373 | 6,712 ± 841
Plasma Concentration (µM) | BD | 0.4 ± 0.1 | 0.9 ± 0.2 | 1.5 ± 0.2 | 5.3 ± 1.2 | 21.4 ± 2.7
Normalized Plasma Concentration (µM/mmol/kg) | NA | 2.1 ± 0.3 | 2.3 ± 0.5 | 1.9 ± 0.3 | 3.3 ± 0.7 | 6.7 ± 0.8

BD = below detection; group did not have over 20% of its values above the limit of quantification and no statistical analyses were conducted for the endpoint; NA = not applicable; value could not be calculated when dose value was 0.

^a^ Tissue concentration data are presented as mean ± standard error. If over 20% of the values in a group were above the limit of quantification (plasma LOQ = 25 ng/mL; liver LOQ = 500 ng/g), then values that were below the limit of quantification were substituted with one-half the limit of quantification value. One-half the dose was administered twice daily.

^b^ Density is assumed to be 1.0 g/mL.

Liver concentrations of PFHxA were measured in males only and were only quantifiable in 250, 500, and 1,000 mg/kg/day rats (Table 5). When normalized to dose administered, these values marginally increased with dose (2.6 to 4.8 µM/mmol/kg). The liver/plasma ratios in males were less than 1 across the dose groups with quantifiable PFHxA.

Dose-related increases were observed in the absolute and relative liver weights of male and female rats (Table 6). The mean absolute and relative liver weights of 500 and 1,000 mg/kg/day males and females and the mean relative liver weight of 250 mg/kg/day males were significantly greater than those of the respective vehicle control groups. The mean relative kidney weights of 500 and 1,000 mg/kg/day males and the mean absolute and relative kidney weights of 1,000 mg/kg/day females were significantly greater than those of the respective vehicle control groups. The mean absolute thymus weight was significantly decreased in male rats in the 1,000 mg/kg/day group.

Table 6 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day Gavage Study of Perfluorohexanoic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day | 1,000 mg/kg/day
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 331 ± 5 | 340 ± 5 | 326 ± 9 | 327 ± 5 | 319 ± 7 | 287 ± 8**
R. Kidney
Absolute | 1.01 ± 0.01 | 1.03 ± 0.03 | 1.01 ± 0.04 | 1.02 ± 0.03 | 1.09 ± 0.04 | 1.04 ± 0.03
Relative | 3.04 ± 0.04 | 3.04 ± 0.07 | 3.10 ± 0.03 | 3.11 ± 0.07 | 3.40 ± 0.09** | 3.61 ± 0.04**
Liver
Absolute | 11.41 ± 0.28 | 12.63 ± 0.85 | 12.01 ± 0.48 | 12.88 ± 0.22 | 14.49 ± 0.56** | 16.19 ± 0.60**
Relative | 34.44 ± 0.41 | 37.26 ± 2.62 | 36.70 ± 0.50 | 39.35 ± 0.29** | 45.33 ± 0.85** | 56.35 ± 1.07**
Thymus
Absolute | 0.41 ± 0.03 | 0.46 ± 0.03 | 0.41 ± 0.03 | 0.42 ± 0.02 | 0.41 ± 0.02 | 0.30 ± 0.01**
Relative | 1.25 ± 0.06 | 1.36 ± 0.09 | 1.24 ± 0.05 | 1.27 ± 0.07 | 1.28 ± 0.06 | 1.04 ± 0.02
Female
Necropsy body wt. | 225 ± 3 | 227 ± 2 | 229 ± 4 | 228 ± 5 | 223 ± 3 | 220 ± 4
R. Kidney
Absolute | 0.68 ± 0.02 | 0.67 ± 0.01 | 0.69 ± 0.01 | 0.69 ± 0.01 | 0.69 ± 0.02 | 0.74 ± 0.01**
Relative | 3.02 ± 0.07 | 2.95 ± 0.05 | 3.01 ± 0.06 | 3.02 ± 0.06 | 3.10 ± 0.08 | 3.37 ± 0.05**
Liver
Absolute | 7.24 ± 0.15 | 7.40 ± 0.19 | 7.53 ± 0.19 | 7.84 ± 0.21 | 8.26 ± 0.20** | 10.44 ± 0.29**
Relative | 32.18 ± 0.74 | 32.63 ± 0.67 | 32.82 ± 0.46 | 34.37 ± 0.94 | 37.06 ± 0.73** | 47.45 ± 0.99**

** Significantly different (p ≤ 0.01) from the vehicle control group by Williams’ or Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). One-half the dose was administered twice daily.

Dose-dependent significant decreases in the erythron—characterized by decreases in erythrocyte counts, hematocrit values, and hemoglobin concentrations—were seen in all male dose groups and in 250 mg/kg/day and greater females (Table 7). Reticulocytes were significantly increased in the most affected groups (i.e., high-dose groups), indicating a bone marrow response to the decreased erythron (regenerative response). Mean cell volumes were significantly increased in 250 mg/kg/day and greater males and 500 and 1,000 mg/kg/day females. Also, the mean cell hemoglobin concentrations were significantly decreased in 1,000 mg/kg/day males and females. Platelets were significantly increased in 500 mg/kg/day males and 1,000 mg/kg/day males and females; this is a common secondary finding to a highly regenerative bone marrow response. Blood smear findings in the high-dose groups included mild to moderate hypochromasia and anisocytosis, which were expected findings in light of the decreased erythron with regenerative response.

Table 7 Selected Hematology and Clinical Chemistry Data for Rats in the 28-day Gavage Study of Perfluorohexanoic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day | 1,000 mg/kg/day
Male
n | 10 | 10 | 9 | 10 | 10 | 10
Hematology
Hematocrit (%) | 51.9 ± 0.5 | 49.6 ± 0.7* | 48.6 ± 0.7** | 48.7 ± 0.6** | 43.3 ± 0.9** | 34.2 ± 1.8**
Manual Hematocrit (%) | 47 ± 0 | 45 ± 1 | 44 ± 1* | 44 ± 0** | 39 ± 1** | 33 ± 2**
Hemoglobin (g/dL) | 15.5 ± 0.2 | 15.0 ± 0.2* | 14.7 ± 0.2** | 14.6 ± 0.2** | 12.6 ± 0.3** | 9.3 ± 0.6**
Erythrocytes (10^6^/μL) | 8.69 ± 0.08 | 8.28 ± 0.11* | 8.24 ± 0.12** | 7.91 ± 0.10** | 6.68 ± 0.22** | 4.56 ± 0.32**
Reticulocytes (10^3^/μL) | 207.9 ± 6.0 | 196.5 ± 8.7 | 176.3 ± 7.6 | 238.6 ± 9.6 | 523.7 ± 71.7** | 947.7 ± 43.0**
Mean Cell Volume (fL) | 59.7 ± 0.4 | 59.9 ± 0.4 | 59.0 ± 0.7 | 61.6 ± 0.5* | 65.2 ± 1.1** | 75.8 ± 1.9**
Mean Cell Hemoglobin Concentration (g/dL) | 29.9 ± 0.1 | 30.2 ± 0.1 | 30.2 ± 0.1 | 30.0 ± 0.1 | 29.1 ± 0.3 | 27.0 ± 0.3**
Platelets (10^3^/μL) | 927 ± 26 | 913 ± 28 | 979 ± 40 | 939 ± 36 | 1,115 ± 44** | 1,381 ± 69**
Clinical Chemistry
Total Protein (g/dL) | 6.5 ± 0.1 | 6.2 ± 0.1 | 6.1 ± 0.1** | 6.1 ± 0.1** | 5.9 ± 0.1**^b^ | 5.2 ± 0.1**
Albumin (g/dL) | 4.0 ± 0.1 | 3.9 ± 0.1 | 3.8 ± 0.0* | 3.9 ± 0.0 | 4.0 ± 0.0^b^ | 3.7 ± 0.1**
Globulin (g/dL) | 2.5 ± 0.1 | 2.3 ± 0.1 | 2.3 ± 0.1* | 2.1 ± 0.1** | 1.9 ± 0.1**^b^ | 1.5 ± 0.1**
Albumin/Globulin Ratio | 1.6 ± 0.1 | 1.7 ± 0.1 | 1.7 ± 0.1 | 1.9 ± 0.1** | 2.1 ± 0.1**^b^ | 2.6 ± 0.2**
Cholesterol (mg/dL) | 126 ± 4 | 101 ± 4** | 105 ± 4** | 105 ± 3** | 103 ± 5** | 98 ± 5**
Alanine Aminotransferase (IU/L) | 48 ± 1^b^ | 50 ± 2 | 50 ± 2 | 52 ± 2 | 61 ± 1** | 79 ± 3**
Alkaline Phosphatase (IU/L) | 200 ± 8 | 191 ± 6 | 195 ± 6 | 203 ± 11 | 245 ± 10** | 301 ± 19**^b^
Aspartate Aminotransferase (IU/L) | 57 ± 2^b^ | 59 ± 2 | 58 ± 2^c^ | 61 ± 1 | 67 ± 2** | 78 ± 3**
Sorbitol Dehydrogenase (IU/L) | 3 ± 0^b^ | 4 ± 1 | 4 ± 1 | 4 ± 1 | 3 ± 1 | 5 ± 1*
Total Bile Acids (µmol/L) | 11.1 ± 3.5 | 9.9 ± 2.6 | 8.4 ± 1.9 | 13.8 ± 3.1 | 16.8 ± 2.5 | 24.2 ± 2.6**
Testosterone (ng/mL) | 3.82 ± 0.81 | 3.53 ± 0.53 | 3.63 ± 1.02 | 3.61 ± 0.46 | 3.56 ± 0.59 | 2.93 ± 0.71
Thyroid Stimulating Hormone (ng/mL) | 23.08 ± 2.63 | 25.16 ± 3.38^b^ | 24.28 ± 3.04 | 24.47 ± 3.00 | 20.95 ± 2.85 | 18.29 ± 3.56
Triiodothyronine (ng/dL) | 84.17 ± 5.25 | 68.88 ± 3.76* | 62.16 ± 3.51** | 71.59 ± 3.90* | 71.03 ± 4.09* | 60.07 ± 4.74**
Free Thyroxine (ng/dL) | 2.88 ± 0.09 | 2.16 ± 0.17** | 1.78 ± 0.12** | 1.74 ± 0.09** | 1.30 ± 0.07** | 0.77 ± 0.10**
Total Thyroxine (µg/dL) | 4.26 ± 0.15 | 3.40 ± 0.23** | 2.93 ± 0.16** | 2.90 ± 0.17** | 2.37 ± 0.10** | 1.77 ± 0.17**
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Hematology
Hematocrit (%) | 45.1 ± 0.5 | 44.8 ± 0.3 | 45.1 ± 0.4 | 42.1 ± 0.3** | 41.7 ± 0.7** | 37.6 ± 1.2**
Manual Hematocrit (%) | 41 ± 1 | 41 ± 1 | 41 ± 0 | 38 ± 0** | 38 ± 1** | 35 ± 1**
Hemoglobin (g/dL) | 14.0 ± 0.2 | 14.0 ± 0.1 | 13.9 ± 0.1 | 13.1 ± 0.1** | 12.9 ± 0.2** | 11.3 ± 0.4**
Erythrocytes (10^6^/μL) | 7.66 ± 0.09 | 7.61 ± 0.07 | 7.78 ± 0.11 | 7.10 ± 0.09** | 6.88 ± 0.15** | 5.64 ± 0.18**
Reticulocytes (10^3^/μL) | 177.9 ± 17.2 | 177.9 ± 11.5 | 173.7 ± 14.5 | 213.3 ± 17.5 | 335.8 ± 28.1** | 574.2 ± 38.2**
Mean Cell Volume (fL) | 58.8 ± 0.2 | 58.8 ± 0.5 | 57.9 ± 0.6 | 59.4 ± 0.6 | 60.7 ± 0.6* | 66.6 ± 0.7**
Mean Cell Hemoglobin Concentration (g/dL) | 31.2 ± 0.1 | 31.2 ± 0.1 | 30.9 ± 0.1 | 31.1 ± 0.1 | 31.0 ± 0.1 | 30.1 ± 0.1**
Platelets (10^3^/μL) | 976 ± 20 | 998 ± 39 | 1,049 ± 28 | 985 ± 21 | 1,021 ± 45 | 1,151 ± 55*
Clinical Chemistry
Total Protein (g/dL) | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.3 ± 0.1 | 6.3 ± 0.1 | 5.9 ± 0.1**
Albumin (g/dL) | 4.5 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.5 ± 0.1 | 4.6 ± 0.1
Globulin (g/dL) | 1.9 ± 0.1 | 1.8 ± 0.1 | 1.9 ± 0.1 | 1.8 ± 0.0 | 1.8 ± 0.1 | 1.4 ± 0.1**
Albumin/Globulin Ratio | 2.4 ± 0.1 | 2.6 ± 0.1 | 2.5 ± 0.1 | 2.6 ± 0.1 | 2.6 ± 0.1 | 3.3 ± 0.2**
Alanine Aminotransferase (IU/L) | 40 ± 1 | 44 ± 2 | 46 ± 2 | 44 ± 3 | 54 ± 2** | 57 ± 3**
Alkaline Phosphatase (IU/L) | 138 ± 4 | 149 ± 8 | 163 ± 7 | 141 ± 5 | 147 ± 7 | 190 ± 10**
Aspartate Aminotransferase (IU/L) | 56 ± 3 | 55 ± 2 | 56 ± 1 | 56 ± 1 | 62 ± 1** | 66 ± 3**
Total Bile Acids (µmol/L) | 10.1 ± 2.5 | 13.0 ± 3.3 | 10.9 ± 2.5 | 12.4 ± 2.6 | 11.8 ± 2.2 | 26.5 ± 3.3**
Thyroid Stimulating Hormone (ng/mL) | 17.32 ± 1.40 | 14.75 ± 1.17 | 15.8 ± 0.90^b^ | 15.73 ± 1.06 | 24.18 ± 9.46 | 15.69 ± 0.77
Triiodothyronine (ng/dL) | 98.19 ± 8.94 | 97.12 ± 6.10 | 92.57 ± 6.16 | 101.26 ± 7.50 | 111.58 ± 6.37 | 94.95 ± 7.91
Free Thyroxine (ng/dL) | 1.97 ± 0.13 | 1.96 ± 0.13 | 1.89 ± 0.13 | 2.14 ± 0.19 | 1.90 ± 0.13 | 1.61 ± 0.15
Total Thyroxine (µg/dL) | 3.62 ± 0.30 | 3.38 ± 0.23 | 3.210 ± 0.180 | 3.45 ± 0.28 | 3.30 ± 0.16 | 2.95 ± 0.21

* Significantly different (p ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. One-half the dose was administered twice daily.

^b^ n = 9.

^c^ n = 10.

Significant, dose-dependent decreases in total protein and globulin concentrations were observed in 125 mg/kg/day and greater males compared to the vehicle control group; decreases in these two endpoints were also observed in the 1,000 mg/kg/day females (Table 7). Albumin concentrations decreased inconsistently in males. The overall effect of these changes resulted in significant increases in the albumin/globulin ratios in 250 mg/kg/day and greater males and in 1,000 mg/kg/day females. Cholesterol concentrations were significantly decreased in all male dose groups compared to the vehicle control group.

The enzymatic activities of alanine aminotransferase (ALT), aspartate aminotransferase (AST) and alkaline phosphatase (ALP) were significantly elevated in 500 and 1,000 mg/kg/day males compared to the vehicle control group; sorbitol dehydrogenase (SDH) activity and total bile acid concentrations were also significantly elevated in the 1,000 mg/kg/day group (Table 7). In female rats, ALT and AST activities were significantly elevated at 500 and 1,000 mg/kg/day, and ALP activity and total bile acid concentration were elevated at 1,000 mg/kg/day.

Total thyroxine (T4), free T4, and triiodothyronine (T3) concentrations were significantly decreased in all male dose groups (Table 7). There was no change in the female thyroid hormone concentrations.

Male and female rats administered PFHxA exhibited significant increases in gene expression for Acox1, Cyp4a1, Cyp2b1, and Cyp2b2 compared to controls, suggesting significant increases in PPARα constitutive androstane receptor (CAR) activities (Table 8). Except for Acox1 in males and females and Cyp4a1 in females, the expression of genes of interest were increased compared to controls in all dose groups examined. Females exhibited a greater fold increase in CAR-related genes (Cyp2b1 and Cyp2b2) compared to controls than did males compared to controls. Acyl-CoA oxidase activity was increased compared to controls in the 250, 500, and 1,000 mg/kg/day males.

Table 8 Hepatic Parameters for Rats in the 28-day Gavage Study of Perfluorohexanoic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day | 1,000 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Enzyme Activity
Acyl-CoA Oxidase (nmol/min/mg) | 2.204 ± 0.073 | 2.166 ± 0.092 | 2.596 ± 0.155 | 5.303 ± 0.174** | 8.436 ± 0.367** | 16.080 ± 0.797**
Gene Expression
Acox1 | 1.02 ± 0.06 | 1.09 ± 0.05 | 1.09 ± 0.06 | 1.22 ± 0.08 | 1.53 ± 0.15** | 2.01 ± 0.16**
Cyp4a1 | 1.03 ± 0.09 | 2.81 ± 0.33** | 4.76 ± 0.33** | 6.81 ± 0.66** | 10.08 ± 1.15** | 12.54 ± 1.12**
Cyp2b1 | 1.29 ± 0.35 | 2.65 ± 0.32** | 2.88 ± 0.39** | 3.71 ± 0.51** | 7.41 ± 1.63** | 7.01 ± 1.54**
Cyp2b2 | 1.16 ± 0.20 | 2.22 ± 0.25** | 2.64 ± 0.30** | 2.79 ± 0.25** | 3.29 ± 0.25** | 3.01 ± 0.29**
Female
n | 10 | 10 | 10 | 10 | 9 | 10
Gene Expression
Acox1 | 1.01 ± 0.06 | 1.11 ± 0.17 | 1.04 ± 0.09 | 1.19 ± 0.10 | 1.54 ± 0.17** | 1.58 ± 0.11**
Cyp4a1 | 1.04 ± 0.09 | 1.10 ± 0.20 | 1.00 ± 0.12 | 1.17 ± 0.09 | 1.84 ± 0.32* | 2.58 ± 0.23**
Cyp2b1 | 1.83 ± 0.62 | 4.66 ± 1.22* | 9.95 ± 3.36* | 23.28 ± 4.99** | 53.48 ± 8.17** | 124.02 ± 29.12**
Cyp2b2 | 1.95 ± 0.72 | 6.32 ± 1.32* | 13.06 ± 3.61** | 29.78 ± 4.62** | 68.07 ± 7.23** | 81.98 ± 8.60**

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Gene expression data are presented as fold change values from the base-signal values. One-half the dose was administered twice daily.

Cauda epididymal sperm counts in male rats administered 1,000 mg/kg/day were significantly lower (25%) than vehicle controls and occurred in the presence of a slight decrease in epididymal weight (5%) (Table 9). When normalized to total sperm count/g of cauda epididymis, the counts/g were 18% lower than vehicle controls. An epididymal histopathologic finding (exfoliated germ cells) was noted in one rat administered 1,000 mg/kg/day (Table 11). Testis weights and spermatid counts in the PFHxA-treated rats were similar to vehicle controls. Seminiferous tubule spermatid retention of the testis was observed in two rats administered 1,000 mg/kg/day and in one vehicle control rat (Table 11). Males administered PFHxA had testosterone levels similar to those of the vehicle controls (Table 7).

Table 9 Summary of Reproductive Tissue Evaluations for Male Rats in the 28-day Gavage Study of Perfluorohexanoic Acid^a^

| Vehicle Control | 250 mg/kg/day | 500 mg/kg/day | 1,000 mg/kg/day
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy Body Wt. | 331 ± 5 | 327 ± 5 | 319 ± 7 | 287 ± 8**
L. Cauda Epididymis | 0.190 ± 0.005 | 0.195 ± 0.005 | 0.186 ± 0.005 | 0.176 ± 0.005
L. Epididymis | 0.527 ± 0.010 | 0.523 ± 0.013 | 0.524 ± 0.011 | 0.496 ± 0.014
L. Testis | 1.814 ± 0.035 | 1.821 ± 0.028 | 1.851 ± 0.057 | 1.798 ± 0.043
Spermatid Measurements
Spermatid Heads (10^6^/testis) | 377.0 ± 7.9 | 356.5 ± 11.0 | 376.0 ± 11.6 | 352.3 ± 12.4
Spermatid Heads (10^6^/g testis) | 208.3 ± 4.8 | 195.9 ± 5.4 | 203.9 ± 6.1 | 196.0 ± 5.0
Epididymal Spermatozoal Measurements
Sperm Motility (%) | 87.9 ± 0.4 | 87.8 ± 0.3 | 87.2 ± 0.4 | 87.4 ± 0.4
Sperm (10^6^/cauda epididymis) | 111.9 ± 8.4 | 102.5 ± 5.2 | 105.1 ± 4.3 | 83.7 ± 4.7**
Sperm (10^6^/g cauda epididymis) | 586.4 ± 34.9 | 526.7 ± 25.8 | 566.4 ± 20.2 | 478.3 ± 28.2

** Significantly different (p ≤ 0.01) from the vehicle control group by Williams’ or Dunnett’s test (weights) or Shirley’s or Dunn’s test (epididymal spermatozoal measurements).

^a^ Data are presented as mean ± standard error. One-half the dose was administered twice daily.

Table 11 Incidences of Selected Nonneoplastic Lesions in Rats in the 28-day Gavage Study of Perfluorohexanoic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day | 1,000 mg/kg/day
Male
Liver^b^ | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration^c^ | 0 | 0 | 0 | 0 | 2 (1.5)^d^ | 10** (1.8)
Hepatocyte, Hypertrophy | 0 | 0 | 0 | 0 | 9** (1.2) | 10** (1.8)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Degeneration | 0 | 0 | 1 (1.0) | 6** (1.0) | 6** (1.7) | 6** (2.7)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 6** (1.0) | 5* (1.0) | 6** (1.2)
Olfactory Epithelium, Inflammation, Suppurative | 0 | 0 | 0 | 0 | 3 (1.0) | 6** (2.2)
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Increased Extramedullary Hematopoiesis | 0 | 0 | 0 | 0 | 6** (1.3) | 10** (1.6)
Epididymis | (10) | (0) | (0) | (0) | (10) | (10)
Duct, Exfoliated Germ Cell | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Testes | (10) | (10) | (10) | (10) | (10) | (10)
Seminiferous Tubule, Spermatid Retention | 1 (1.0) | 0 | 0 | 0 | 0 | 2 (1.5)
Female
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration | 0 | 0 | 0 | 0 | 0 | 9** (1.1)
Hepatocyte, Hypertrophy | 0 | 0 | 0 | 0 | 0 | 9** (1.1)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Degeneration | 0 | 1 (1.0) | 3 (1.0) | 9** (1.1) | 9** (1.7) | 6** (2.5)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 3 (1.0) | 4* (1.0) | 7** (1.0) | 3 (1.0)
Olfactory Epithelium, Inflammation, Suppurative | 0 | 0 | 0 | 1 (1.0) | 5* (1.0) | 8** (1.5)
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Increased Extramedullary Hematopoiesis | 0 | 0 | 0 | 0 | 2 (1.0) | 9** (1.4)
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Nephropathy, Chronic Progressive | 2 (1.0) | 4 (1.0) | 4 (1.0) | 1 (1.0) | 3 (1.0) | 8* (1.1)

* Significantly different (p ≤ 0.05) from the vehicle control group by the Fisher exact test.

** p ≤ 0.01.

^a^ One-half the dose was administered twice daily.

^b^ Number of animals with tissue examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Inspection of the daily vaginal cytology data indicated that the vehicle control rats did not cycle as expected (e.g., mean length of 7.2 days versus normal length of ~4.5 days; the vehicle control females showed disproportionately more time spent in diestrus and less time in estrus than expected); the PFHxA-treated females cycled as would generally be expected (Table 10). Given this limitation, the summary statistics and Markov analyses are not used for drawing conclusions (Table A-1; Figure A-1). There were no apparent PFHxA-related changes in female testosterone levels.

Table 10 Estrous Cycle Characterization for Female Rats in the 28-day Gavage Study of Perfluorohexanoic Acid^a^

| Vehicle Control | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
Number Weighed at Necropsy | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 225 ± 3 | 229 ± 4 | 228 ± 5 | 223 ± 3
Proportion of Regular Cycling Females^b^ | 6/9 | 9/10 | 10/10 | 10/10
Estrous Cycle Length (days) | 7.2 ± 1.45 | 5.0 ± 0.12 | 5.0 ± 0.13 | 4.8 ± 0.20
Estrous Stages (% of cycle)
Diestrus | 61.8 | 53.1 | 55.0 | 52.5
Proestrus | 3.5 | 8.1 | 4.4 | 6.9
Estrus | 29.2 | 36.9 | 37.5 | 36.9
Metestrus | 2.8 | 0.6 | 2.5 | 3.8
Uncertain | 2.8 | 1.3 | 0.6 | 0.0

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated that 125, 250, and 500 mg/kg/day females had extended estrus and 125 and 250 mg/kg/day females had extended diestrus. One-half the dose was administered twice daily.

^b^ Number of females with a regular cycle/number of females cycling.

#### Pathology

The morphologic features of the lesions discussed in this section are presented in the Histopathologic Descriptions section following the Wyeth-14,643 results.

Liver: The incidences of hepatocyte cytoplasmic alteration in 1,000 mg/kg/day males and females were significantly increased compared to those of the vehicle control groups (Table 11). The incidences of hepatocyte hypertrophy were significantly increased in 500 mg/kg/day males and 1,000 mg/kg/day males and females. Hepatocyte cytoplasmic alteration and hepatocyte hypertrophy were generally of minimal to mild severity.

Nose: The incidences of olfactory epithelium degeneration were significantly increased in males and females administered 250 mg/kg/day or greater compared to the vehicle controls (Table 11). The incidences of olfactory epithelium hyperplasia were significantly increased in males administered 250 mg/kg/day or greater and females administered 250 or 500 mg/kg/day. The incidences of olfactory epithelium suppurative inflammation were significantly increased in 1,000 mg/kg/day males and in females administered 500 or 1,000 mg/kg/day. The olfactory epithelial lesions ranged from minimal to moderate severity.

Spleen: The incidences of increased extramedullary hematopoiesis were significantly increased in 500 mg/kg/day males and 1,000 mg/kg/day males and females compared to the vehicle control groups (Table 11). Increased extramedullary hematopoiesis was generally of minimal to mild severity.

Kidney: The incidence of minimal chronic progressive nephropathy in 1,000 mg/kg/day females was significantly increased compared to the vehicle control group (Table 11).

### Perfluorooctanoic Acid (PFOA)

All rats survived to the end of the study with the exception of one female in the 100 mg/kg/day group (Table 12). The one female that died was ataxic, lethargic, and appeared thin immediately prior to death. There were no significant treatment-related clinical observations in male or female rats. The mean body weights of 0.625, 1.25, and 2.5 mg/kg/day males and all treated females were within 10% of the respective vehicle control groups throughout the study (Table 12; Figure 2). Mean body weights of the 5 and 10 mg/kg/day males were 12% to 19% lower, respectively, than those of the vehicle control group by the end of the study.

Table 12 Mean Body Weights and Survival of Rats in the 28-day Gavage Study of Perfluorooctanoic Acid

Day | Vehicle Control | | 0.625 mg/kg/day | | | 1.25 mg/kg/day | | | 2.5 mg/kg/day | | | 5 mg/kg/day | | | 10 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 257 | 10 | 254 | 99 | 10 | 255 | 99 | 10 | 258 | 101 | 10 | 254 | 99 | 10 | 255 | 99 | 10
8 | 286 | 10 | 283 | 99 | 10 | 284 | 99 | 10 | 284 | 99 | 10 | 276 | 97 | 10 | 261 | 91 | 10
15 | 309 | 10 | 310 | 100 | 10 | 307 | 99 | 10 | 296 | 96 | 10 | 279 | 90 | 10 | 268 | 87 | 10
22 | 329 | 10 | 327 | 100 | 10 | 320 | 97 | 10 | 305 | 93 | 10 | 292 | 89 | 10 | 270 | 82 | 10
29 | 347 | 10 | 344 | 99 | 10 | 331 | 95 | 10 | 317 | 91 | 10 | 304 | 88 | 10 | 280 | 81 | 10
Day | Vehicle Control | | 6.25 mg/kg/day | | | 12.5 mg/kg/day | | | 25 mg/kg/day | | | 50 mg/kg/day | | | 100 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Female
1 | 194 | 10 | 194 | 100 | 10 | 193 | 99 | 10 | 195 | 100 | 10 | 196 | 101 | 10 | 193 | 99 | 10
8 | 205 | 10 | 205 | 100 | 10 | 202 | 99 | 10 | 200 | 98 | 10 | 202 | 99 | 10 | 196 | 96 | 9
15 | 218 | 10 | 213 | 98 | 10 | 213 | 98 | 10 | 210 | 96 | 10 | 211 | 97 | 10 | 208 | 96 | 9
22 | 222 | 10 | 219 | 99 | 10 | 216 | 97 | 10 | 214 | 96 | 10 | 214 | 96 | 10 | 207 | 93 | 9
29 | 227 | 10 | 226 | 100 | 10 | 226 | 100 | 10 | 219 | 97 | 10 | 221 | 98 | 10 | 215 | 95 | 9

Figure 2

Growth Curves for Rats Administered Perfluorooctanoic Acid by Gavage for 28 Days

Plasma concentrations of PFOA increased with increasing dose in both males and females (Table 13). Although females were administered a 10-fold higher dose of PFOA, males had a higher plasma concentration compared to females across the dose groups. When normalized to dose administered (µM/mmol/kg), males had a 1,000-fold higher level at the lowest dose compared, but this difference decreased with increasing dose. The difference at the highest dose was 63-fold. Males exhibited a decreasing normalized plasma concentration with dose, whereas females exhibited the opposite response.

Table 13 Perfluorooctanoic Acid Concentrations in Tissues of Rats in the 28-day Gavage Study of Perfluorooctanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
Millimolar Dose (mmol/kg/day) | 0 | 0.0015 | 0.003 | 0.006 | 0.0121 | 0.0242
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Plasma
Plasma Concentration (ng/mL) | 98 ± 6 | 50,690 ± 2,207** | 73,480 ± 3,206** | 95,430 ± 4,036** | 110,720 ± 3,891** | 148,570 ± 15,405**
Plasma Concentration (µM) | 0.2 ± 0.0 | 122.4 ± 5.3** | 177.5 ± 7.7** | 230.5 ± 9.7** | 267.4 ± 9.4** | 358.8 ± 37.2**
Normalized Plasma Concentration (µM/mmol/kg) | NA | 81,104.0 ± 3,531.6 | 58,784.0 ± 2,564.7 | 38,172.0 ± 1,614.4 | 22,144.0 ± 778.2 | 14,857.0 ± 1,540.5
Liver
Liver Concentration (ng/mL) | BD | 54,610 ± 2,233 | 85,220 ± 3,186 | 110,740 ± 4,467 | 109,030 ± 3,557 | 124,470 ± 9,251
Liver Concentration (µM)^b^ | BD | 131.9 ± 5.4 | 205.8 ± 7.7 | 267.4 ± 10.8 | 263.3 ± 8.6 | 300.6 ± 22.3
Normalized Liver Concentration (µM/mmol/kg) | NA | 87,376.0 ± 3,572.0 | 68,176.0 ± 2,548.4 | 44,296.0 ± 1,786.7 | 21,806.0 ± 711.4 | 12,447.0 ± 925.1
Liver/Plasma Ratio | NA | 1.08 ± 0.02 | 1.16 ± 0.02 | 1.17 ± 0.03 | 0.99 ± 0.03 | 0.87 ± 0.05
| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day | 100 mg/kg/day
Millimolar Dose (mmol/kg/day) | 0 | 0.0151 | 0.0302 | 0.0604 | 0.121 | 0.242
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Plasma
Plasma Concentration (ng/mL) | BD | 491 ± 72 | 1,153 ± 187 | 2,960 ± 481 | 9,326 ± 1,821 | 23,444 ± 3,247
Plasma Concentration (µM) | BD | 1.2 ± 0.2 | 2.8 ± 0.5 | 7.1 ± 1.2 | 22.5 ± 4.4 | 56.6 ± 7.8
Normalized Plasma Concentration (µM/mmol/kg) | NA | 78.5 ± 11.5 | 92.2 ± 15.0 | 118.4 ± 19.2 | 186.5 ± 36.4 | 234.4 ± 32.5

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s or Dunn’s test.

BD=below detection; group did not have over 20% of its values above the limit of quantification and no statistical analyses were conducted for the endpoint. NA=not applicable; value could not be calculated when dose value was 0.

^a^ Tissue concentration data are presented as mean ± standard error. If over 20% of the values in a group were above the limit of quantification (plasma LOQ = 25 ng/mL; liver LOQ = 500 ng/g), values that were below the limit of quantification were substituted with one-half the limit of quantification value.

^b^ Density is assumed to be 1.0 g/mL.

Liver concentrations of PFOA were measured in males only and increased with dose, but when normalized to dose administered, these values (µM/mol/kg) decreased with increasing dose (Table 13). The liver/plasma ratios ranged from 0.87 to 1.08.

There were dose-related increases in the absolute and relative liver weights in male and female rats (Table 14). The absolute and relative liver weights of all male dose groups were significantly greater than those of the vehicle control group; the absolute and relative liver weights of 25, 50, and 100 mg/kg/day females were significantly greater than those of the vehicle control group. The mean absolute kidney weights of males administered 1.25, 2.5, or 5 mg/kg/day and the mean relative kidney weights of males administered 0.625 mg/kg/day or greater were significantly greater than those of the vehicle controls. The mean relative kidney weights of 50 mg/kg/day females and the absolute and relative kidney weights of 100 mg/kg/day females were significantly greater than those of the vehicle control group. The mean absolute spleen weights of males administered 2.5 mg/kg/day or greater were significantly less than those of the vehicle control group. Absolute thymus weights were decreased in 10 mg/kg/day males, and relative thyroid gland weights were increased in male groups administered 1.25 mg/kg/day and greater. Absolute thyroid weight was only significantly increased in the 2.5 mg/kg/day group.

Table 14 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day Gavage Study of Perfluorooctanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy Body Wt. | 347 ± 5 | 344 ± 7 | 331 ± 4 | 317 ± 7** | 304 ± 8** | 280 ± 10**
R. Kidney
Absolute | 0.97 ± 0.03 | 1.07 ± 0.02 | 1.13 ± 0.03** | 1.14 ± 0.03** | 1.09 ± 0.02* | 1.06 ± 0.03
Relative | 2.80 ± 0.06 | 3.10 ± 0.02** | 3.41 ± 0.06** | 3.59 ± 0.06** | 3.59 ± 0.06** | 3.81 ± 0.10**
Liver
Absolute | 12.96 ± 0.41 | 14.94 ± 0.32** | 15.80 ± 0.29** | 16.44 ± 0.64** | 16.70 ± 0.46** | 17.22 ± 0.38**
Relative | 37.34 ± 0.72 | 43.41 ± 0.55** | 47.80 ± 0.54** | 51.75 ± 1.09** | 55.01 ± 0.89** | 62.05 ± 2.23**
Spleen
Absolute | 0.704 ± 0.020 | 0.656 ± 0.037 | 0.645 ± 0.020 | 0.619 ± 0.040* | 0.581 ± 0.022** | 0.533 ± 0.024**
Relative | 2.03 ± 0.04 | 1.90 ± 0.08 | 1.95 ± 0.06 | 1.94 ± 0.09 | 1.91 ± 0.05 | 1.90 ± 0.04
Thymus
Absolute | 0.429 ± 0.022 | 0.419 ± 0.015 | 0.420 ± 0.019 | 0.415 ± 0.031 | 0.385 ± 0.031 | 0.318 ± 0.035*
Relative | 1.24 ± 0.06 | 1.21 ± 0.03 | 1.27 ± 0.06 | 1.30 ± 0.08 | 1.26 ± 0.08 | 1.11 ± 0.10
Thyroid Gland
Absolute | 0.0209 ± 0.0010 | 0.0231 ± 0.0013 | 0.0245 ± 0.0017 | 0.0274 ± 0.0016** | 0.0208 ± 0.0010 | 0.0214 ± 0.0014
Relative | 0.06 ± 0.00 | 0.07 ± 0.00 | 0.07 ± 0.01** | 0.09 ± 0.00** | 0.07 ± 0.00** | 0.08 ± 0.00**
| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day | 100 mg/kg/day
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Necropsy Body Wt. | 227 ± 5 | 226 ± 3 | 226 ± 4 | 219 ± 2 | 221 ± 3 | 215 ± 4
R. Kidney
Absolute | 0.71 ± 0.03 | 0.71 ± 0.02 | 0.70 ± 0.01 | 0.72 ± 0.01 | 0.74 ± 0.01 | 0.79 ± 0.02**
Relative | 3.12 ± 0.10 | 3.13 ± 0.06 | 3.09 ± 0.05 | 3.31 ± 0.07 | 3.35 ± 0.05* | 3.66 ± 0.10**
Liver
Absolute | 7.77 ± 0.34 | 8.13 ± 0.19 | 8.21 ± 0.20 | 8.58 ± 0.14* | 9.79 ± 0.27** | 12.07 ± 0.40**
Relative | 34.20 ± 0.98 | 36.06 ± 0.65 | 36.44 ± 0.58 | 39.12 ± 0.54** | 44.22 ± 0.88** | 56.00 ± 1.09**

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Erythrocyte count, hematocrit, manual hematocrit, and hemoglobin concentrations were significantly decreased in 1.25 mg/kg/day and higher males compared to the vehicle control group (Table 15). The reticulocyte count was significantly decreased in all male dose groups compared to the vehicle control group. The combination of these changes resulted in a small but significant decrease in the mean cell volume in the 10 mg/kg/day males. Significant decreases in the female rat erythron were observed, most consistently starting at 12.5 mg/kg/day, characterized by decreases in the hematocrit, hemoglobin concentrations, and erythrocyte counts compared to the vehicle control group.

Table 15 Selected Hematology and Clinical Chemistry Data for Rats in the 28-day Gavage Study of Perfluorooctanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Hematology
Hematocrit (%) | 53.3 ± 0.6 | 52.1 ± 0.6 | 50.5 ± 0.5** | 50.9 ± 0.5** | 49.3 ± 0.6** | 48.3 ± 0.5**
Manual Hematocrit (%) | 48 ± 1 | 47 ± 1 | 46 ± 0* | 46 ± 0* | 45 ± 1** | 44 ± 0**
Hemoglobin (g/dL) | 16.0 ± 0.1 | 15.6 ± 0.1 | 15.2 ± 0.2** | 15.3 ± 0.1** | 14.9 ± 0.2** | 14.5 ± 0.1**
Erythrocytes (10^6^/μL) | 8.80 ± 0.13 | 8.50 ± 0.10 | 8.27 ± 0.09** | 8.51 ± 0.12* | 8.28 ± 0.13* | 8.28 ± 0.08**
Reticulocytes (10^3^/μL) | 188.8 ± 8.2 | 161.6 ± 2.9** | 148.7 ± 6.8** | 144.5 ± 7.3** | 161.6 ± 11.1** | 131.0 ± 10.9**
Mean Cell Volume (fL) | 60.6 ± 0.5 | 61.3 ± 0.3 | 61.2 ± 0.4 | 59.9 ± 0.5 | 59.6 ± 0.4 | 58.3 ± 0.6**
Clinical Chemistry
Urea Nitrogen (mg/dL) | 16.6 ± 0.4 | 15.9 ± 0.7 | 20.3 ± 0.5** | 19.6 ± 1.0** | 18.1 ± 0.9* | 20.1 ± 1.2*
Creatinine (mg/dL) | 0.77 ± 0.04 | 0.70 ± 0.00* | 0.69 ± 0.01** | 0.70 ± 0.01* | 0.65 ± 0.02** | 0.65 ± 0.02**
Glucose (mg/dL) | 196 ± 8 | 183 ± 9 | 187 ± 8 | 168 ± 8* | 156 ± 4** | 141 ± 5**
Total Protein (g/dL) | 6.6 ± 0.1 | 6.0 ± 0.1** | 5.9 ± 0.1** | 6.0 ± 0.1** | 5.8 ± 0.1** | 5.8 ± 0.2**
Albumin (g/dL) | 4.3 ± 0.0 | 4.3 ± 0.1 | 4.4 ± 0.1 | 4.5 ± 0.1 | 4.5 ± 0.1 | 4.5 ± 0.1
Globulin (g/dL) | 2.3 ± 0.1 | 1.7 ± 0.1** | 1.6 ± 0.1** | 1.5 ± 0.0** | 1.3 ± 0.1** | 1.4 ± 0.1**
Albumin/Globulin Ratio | 1.9 ± 0.0 | 2.5 ± 0.1** | 2.8 ± 0.1** | 3.0 ± 0.1** | 3.4 ± 0.1** | 3.3 ± 0.1**
Direct Bilirubin (mg/dL) | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00*
Cholesterol (mg/dL) | 114 ± 6 | 72 ± 2** | 79 ± 4** | 76 ± 3** | 80 ± 5** | 100 ± 5
Triglycerides (mg/dL) | 138 ± 12 | 101 ± 8* | 83 ± 7** | 82 ± 6** | 82 ± 5** | 78 ± 5**
Alanine Aminotransferase (IU/L) | 57 ± 3 | 68 ± 3* | 65 ± 3* | 73 ± 5** | 70 ± 2** | 84 ± 11**
Alkaline Phosphatase (IU/L) | 207 ± 9 | 233 ± 8* | 238 ± 12* | 316 ± 11** | 356 ± 12** | 392 ± 40**
Aspartate Aminotransferase (IU/L) | 67 ± 3 | 71 ± 2 | 68 ± 2 | 82 ± 5** | 74 ± 3* | 93 ± 14**
Total Bile Acids (µmol/L) | 12.3 ± 2.8 | 9.6 ± 2.4 | 22.5 ± 3.5 | 22.0 ± 3.6 | 28.0 ± 3.6** | 55.4 ± 16.1**
Testosterone (ng/mL) | 4.03 ± 1.45 | 4.59 ± 1.14 | 4.99 ± 1.14 | 2.79 ± 0.67 | 4.79 ± 1.49 | 3.12 ± 1.21
Thyroid Stimulating Hormone (ng/mL) | 21.76 ± 2.66 | 23.74 ± 2.34 | 15.50 ± 1.94 | 15.85 ± 2.43 | 12.63 ± 1.20** | 15.07 ± 2.04*
Triiodothyronine (ng/dL) | 88.55 ± 5.58 | 53.52 ± 1.45** | 56.93 ± 2.48** | 61.47 ± 3.64* | 58.98 ± 3.52** | 85.33 ± 6.72
Free Thyroxine (ng/dL) | 2.14 ± 0.13 | 0.44 ± 0.04** | 0.36 ± 0.02** | 0.32 ± 0.01** | 0.34 ± 0.02** | 0.33 ± 0.02**
Total Thyroxine (µg/dL) | 2.34 ± 0.24 | 0.21 ± 0.05** | 0.17 ± 0.06** | 0.07 ± 0.05** | 0.11 ± 0.06** | 0.39 ± 0.15**
| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day | 100 mg/kg/day
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Hematology
Hematocrit (%) | 47.2 ± 0.5 | 45.8 ± 0.3* | 45.7 ± 0.3* | 45.4 ± 0.4** | 45.8 ± 0.5* | 43.2 ± 0.6**
Manual Hematocrit (%) | 42 ± 1 | 42 ± 1 | 41 ± 0 | 41 ± 1 | 42 ± 1 | 40 ± 1*
Hemoglobin (g/dL) | 14.4 ± 0.1 | 14.0 ± 0.1 | 14.0 ± 0.1* | 13.9 ± 0.1** | 13.9 ± 0.1** | 13.1 ± 0.2**
Erythrocytes (10^6^/μL) | 7.78 ± 0.08 | 7.63 ± 0.10 | 7.67 ± 0.07 | 7.53 ± 0.07 | 7.63 ± 0.10 | 7.20 ± 0.11**
Clinical Chemistry
Urea Nitrogen (mg/dL) | 16.5 ± 0.9 | 17.3 ± 0.6 | 16.5 ± 0.5 | 18.4 ± 0.6 | 19.7 ± 1.3 | 23.3 ± 2.1**
Albumin (g/dL) | 4.5 ± 0.1 | 4.6 ± 0.1 | 4.7 ± 0.1 | 4.8 ± 0.1** | 5.0 ± 0.1** | 5.0 ± 0.1**
Globulin (g/dL) | 1.9 ± 0.1 | 1.8 ± 0.1 | 1.7 ± 0.1* | 1.7 ± 0.0** | 1.7 ± 0.1* | 1.5 ± 0.1**
Albumin/Globulin Ratio | 2.4 ± 0.1 | 2.6 ± 0.1 | 2.8 ± 0.1** | 2.9 ± 0.1** | 3.1 ± 0.1** | 3.5 ± 0.1**
Cholesterol (mg/dL) | 96 ± 5 | 108 ± 5 | 96 ± 5 | 100 ± 3 | 112 ± 3* | 114 ± 3**
Triglycerides (mg/dL) | 66 ± 7 | 61 ± 3 | 74 ± 6 | 74 ± 6 | 84 ± 7* | 106 ± 10**
Alanine Aminotransferase (IU/L) | 43 ± 3 | 47 ± 2 | 46 ± 2 | 47 ± 2 | 48 ± 1* | 52 ± 2**
Alkaline Phosphatase (IU/L) | 132 ± 8 | 154 ± 7* | 161 ± 8** | 143 ± 4* | 148 ± 7* | 176 ± 6**
Thyroid Stimulating Hormone (ng/mL) | 10.05 ± 0.81 | 14.08 ± 1.17** | 12.99 ± 1.27* | 14.00 ± 1.49*^b^ | 17.81 ± 1.72** | 15.83 ± 2.20**^c^
Triiodothyronine (ng/dL) | 109.10 ± 6.72 | 115.25 ± 6.41 | 94.87 ± 5.94 | 116.46 ± 6.33 | 114.41 ± 5.31 | 104.70 ± 4.14
Free Thyroxine (ng/dL) | 1.63 ± 0.18 | 1.95 ± 0.15 | 1.48 ± 0.11 | 1.56 ± 0.2.0^b^ | 1.51 ± 0.13 | 1.13 ± 0.14*
Total Thyroxine (µg/dL) | 2.10 ± 0.36 | 2.43 ± 0.28 | 1.56 ± 0.24 | 2.03 ± 0.33 | 1.56 ± 0.23 | 1.11 ± 0.24*

* Significantly different (p ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ n = 9.

^c^ n = 8.

In general, urea nitrogen concentrations were significantly increased and creatinine concentrations significantly decreased in 1.25 mg/kg/day and higher males compared to the vehicle control group (Table 15). Urea nitrogen concentration was significantly increased in 100 mg/kg/day females. Glucose concentrations were decreased in 2.5 mg/kg/day and greater males compared to the vehicle control group. The decreases in creatinine and glucose concentrations in male rats were likely related to the decreased food intake and body weight. In male rats, cholesterol and triglyceride concentrations were decreased in most dose groups compared to the vehicle control group. Cholesterol and triglyceride concentrations were increased in 50 and 100 mg/kg/day females compared to the vehicle control group.

Total protein and globulin concentrations were decreased in all male dose groups compared to the vehicle control group, which resulted in significant increases in the albumin/globulin ratio in all male dose groups (Table 15). Globulin concentrations were significantly decreased in 12.5 mg/kg/day and greater females and albumin concentrations significantly increased in 25 mg/kg/day and greater females; these changes resulted in increases in the albumin/globulin ratios in the 12.5 mg/kg/day and greater females.

ALT and ALP activities were significantly increased in all male dose groups, and AST activity was increased in 2.5 mg/kg/day and greater males compared to the vehicle control group (Table 15). Total bile acid concentrations were increased in 5 and 10 mg/kg/day males, and the direct bilirubin concentration was increased in 10 mg/kg/day males compared to the vehicle control group. Creatine kinase activity was significantly decreased in 2.5 mg/kg/day and greater males, which was considered to be of unknown toxicological relevance. ALT activity was significantly increased in 50 and 100 mg/kg/day females, and ALP activity was significantly increased in all female dose groups compared to the vehicle control group.

T4, free T4, and T3 concentrations were significantly decreased in all male dose groups (except T3 at 10 mg/kg/day) compared to the vehicle control group, with thyroid stimulating hormone (TSH) being significantly decreased in 5 and 10 mg/kg/day males (Table 15). TSH concentrations were significantly increased in all female dose groups compared to the vehicle control group.

Male and female rats administered PFOA exhibited significant increases in gene expression of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2 compared to controls, suggesting increases in PPARα and CAR activities (Table 16). Of the four genes evaluated, female rats displayed the greatest fold increase for the CAR-related genes Cyp2b1 and Cyp2b2 compared to respective controls. Males exhibited the greatest fold increase for Cyp4a1 and Cyp2b1 compared to respective controls. Acyl-CoA oxidase activity was increased in all male dose groups.

Table 16 Hepatic Parameters for Rats in the 28-day Gavage Study of Perfluorooctanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10 | 9
Enzyme Activity
Acetyl-CoA (nmol/min/mg) | 1.843 ± 0.060 | 5.797 ± 0.362** | 10.489 ± 0.535** | 12.701 ± 0.456** | 14.970 ± 0.568** | 16.010 ± 0.670**^b^
Gene Expression
Acox1 | 1.09 ± 0.15 | 3.78 ± 0.41** | 5.69 ± 0.35** | 6.20 ± 0.53** | 5.01 ± 0.28** | 5.94 ± 0.63**
Cyp4a1 | 1.07 ± 0.13 | 22.17 ± 2.17** | 32.54 ± 2.10** | 29.08 ± 1.99** | 22.21 ± 1.26** | 25.31 ± 2.68**
Cyp2b1 | 1.26 ± 0.27 | 5.75 ± 1.39** | 11.81 ± 2.21** | 10.38 ± 2.33** | 10.45 ± 2.19** | 22.11 ± 7.13**
Cyp2b2 | 1.09 ± 0.15 | 3.88 ± 0.50** | 4.94 ± 0.40** | 4.14 ± 0.31** | 3.16 ± 0.27 | 4.33 ± 0.52**
| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day | 100 mg/kg/day
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Gene Expression
Acox1 | 1.02 ± 0.06 | 1.03 ± 0.05 | 1.29 ± 0.08* | 1.66 ± 0.16** | 2.69 ± 0.25** | 3.94 ± 0.28**
Cyp4a1 | 1.03 ± 0.08 | 1.13 ± 0.08 | 1.21 ± 0.09 | 1.41 ± 0.14* | 3.19 ± 0.44** | 7.81 ± 0.78**
Cyp2b1 | 1.29 ± 0.21 | 6.18 ± 1.76* | 9.58 ± 1.90** | 18.64 ± 5.59** | 39.99 ± 5.85** | 91.67 ± 15.04**
Cyp2b2 | 1.42 ± 0.35 | 5.87 ± 1.68* | 12.40 ± 2.53** | 16.56 ± 3.94** | 34.57 ± 5.07** | 47.83 ± 2.59**

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Gene expression data are presented as fold change values from the base-signal values.

Male rats assessed for reproductive toxicity were administered 0, 2.5, 5, or 10 mg PFOA/kg/day for 28 days, which is much less than the time needed to make a full assessment of the effect on spermatogenesis. Epididymal weights were lower in the rats administered 5 or 10 mg/kg/day compared to the vehicle control group (6% and 9% respectively; statistically significant at 10 mg/kg); caudal epididymal weight was also lower in these groups (11%; both statistically significant) (Table 17). Cauda epididymal sperm count in the 10 mg/kg/day group was lower compared to the vehicle control group (24%; statistically significant). When normalized to total sperm count/g cauda epididymis, the count in the 10 mg/kg/day group was 15% lower compared to the vehicle control group. Histopathologic findings in the epididymis were noted in one rat each in the 5 and 10 mg/kg/day groups (hypospermia, exfoliated germ cells) (Table 18). Testis weights and spermatid counts in the PFOA-dosed animals were similar to the vehicle controls. Males administered 10 mg/kg/day displayed lower serum testosterone levels (22% lower; did not attain statistical significance) (Table 15).

Table 17 Summary of Reproductive Tissue Evaluations for Male Rats in the 28-day Gavage Study of Perfluorooctanoic Acid^a^

| Vehicle Control | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy Body Wt. | 347 ± 5 | 317 ± 7** | 304 ± 8** | 280 ± 10**
L. Cauda Epididymis | 0.192 ± 0.006 | 0.187 ± 0.005 | 0.170 ± 0.003** | 0.171 ± 0.005**
L. Epididymis | 0.523 ± 0.012 | 0.506 ± 0.012 | 0.492 ± 0.012 | 0.474 ± 0.012**
L. Testis | 1.866 ± 0.033 | 1.798 ± 0.049 | 1.834 ± 0.051 | 1.755 ± 0.036
Spermatid Measurements
Spermatid Heads (10^6^/testis) | 234.2 ± 9.9 | 229.6 ± 7.0 | 240.5 ± 8.2 | 223.4 ± 8.2
Spermatid Heads (10^6^/g testis) | 125.5 ± 4.6 | 128.5 ± 5.2 | 131.1 ± 2.2 | 127.6 ± 4.9
Epididymal Spermatozoal Measurements
Sperm Motility (%) | 86.6 ± 0.8 | 86.1 ± 0.9 | 85.5 ± 0.7 | 85.2 ± 0.6
Sperm (10^6^/cauda epididymis) | 109.0 ± 6.9 | 98.1 ± 6.2 | 107.4 ± 7.3 | 83.0 ± 5.5*
Sperm (10^6^/g cauda epididymis) | 572.0 ± 41.4 | 524.3 ± 31.0 | 630.8 ± 41.1 | 486.6 ± 29.8

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test (weights) or Shirley’s or Dunn’s test (epididymal spermatozoal measurements).

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

Table 18 Incidences of Selected Nonneoplastic Lesions in Rats in the 28-day Gavage Study of Perfluorooctanoic Acid

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
Male
Liver^a^ | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration^b^ | 0 | 4* (1.0)^c^ | 9** (1.0) | 10** (1.3) | 10** (2.2) | 10** (2.6)
Hepatocyte, Hypertrophy | 0 | 0* | 6** (1.0) | 10** (1.8) | 10** (2.5) | 10** (3.2)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Respiratory Epithelium, Hyperplasia | 0 | 4* (1.3) | 2 (1.0) | 3 (1.3) | 5* (1.4) | 4* (1.3)
Respiratory Epithelium, Inflammation Chronic Active | 0 | 5* (1.0) | 3 (1.0) | 2 (1.0) | 5* (1.0) | 4* (1.0)
Bone Marrow | (10) | (10) | (10) | (9) | (10) | (10)
Hypocellularity | 1 (1.0) | 0 | 0 | 0 | 2 (1.0) | 6* (1.0)
Thyroid Gland | (10) | (10) | (10) | (10) | (10) | (10)
Follicular Cell Hypertrophy | 0 | 0 | 0 | 0 | 0 | 3 (1.0)
Epididymis | (10) | (0) | (0) | (10) | (10) | (10)
Hypospermia | 0 | 0 | 0 | 0 | 1 (2.0) | 1 (2.0)
Duct, Exfoliated Germ Cell | 0 | 0 | 0 | 0 | 1 (2.0) | 1 (2.0)
| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day | 100 mg/kg/day
Female
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration | 0 | 0 | 0 | 10** (1.0) | 10** (1.0) | 10** (1.9)
Hepatocyte, Hypertrophy | 0 | 0 | 0 | 0 | 2 (1.5) | 10** (2.0)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 4* (1.0) | 0 | 3 (1.0) | 8** (1.6)
| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day | 100 mg/kg/day
Respiratory Epithelium, Inflammation Chronic Active | 0 | 0 | 4* (1.0) | 1 (1.0) | 6** (1.0) | 9** (1.4)
Olfactory Epithelium, Degeneration | 0 | 0 | 0 | 2 (1.0) | 8** (1.4) | 9** (1.8)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 2 (1.0) | 8** (1.1) | 0
Olfactory Epithelium, Suppurative Inflammation | 0 | 0 | 0 | 0 | 1 (1.0) | 6** (1.5)
Thyroid Gland | (10) | (10) | (10) | (10) | (10) | (10)
Follicular Cell Hypertrophy | 0 | 0 | 0 | 0 | 1 (1.0) | 8** (1.0)

* Significantly different (p ≤ 0.05) from the vehicle control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Female rats assessed for reproductive toxicity were administered 0, 25, 50, or 100 mg/kg/day for 28 days. Inspection of the daily vaginal cytology data indicated that PFOA-dosed rats were generally cycling similar to the vehicle controls but with the 100 mg/kg/day dose group spending ~20% more time in diestrus (Table A-2). Markov analyses demonstrated that rats administered 100 mg/kg/day of PFOA also had higher probability than the control group of transitioning from normal cycling to extended diestrus (Table A-2 and Table A-3; Figure A-2). There were no apparent PFOA-related changes in female testosterone levels.

#### Pathology

The morphologic features of the lesions discussed in this section are presented in the Histopathologic Descriptions section following the Wyeth-14,643 results.

Liver: The incidences of hepatocyte cytoplasmic alteration were significantly increased in all male dose groups and 25 mg/kg/day or greater females compared to the vehicle control groups (Table 18). The incidences of hepatocyte hypertrophy were significantly increased in 1.25 mg/kg/day or greater males and in 100 mg/kg/day females. The severities of hepatocyte cytoplasmic alteration and hepatocyte hypertrophy increased with increasing dose. Hepatocyte cytoplasmic alteration and hepatocyte hypertrophy were of minimal to marked severity.

Nose: The incidences of respiratory epithelium, hyperplasia were significantly increased in males administered 0.625, 5, or 10 mg/kg/day and in females administered 12.5 or 100 mg/kg/day compared to the vehicle control groups (Table 18). The incidences of respiratory epithelium, inflammation chronic active were significantly increased in 0.625, 5, and 10 mg/kg/day males and 12.5, 50, and 100 mg/kg/day females compared to the respective vehicle control groups. Respiratory epithelium, hyperplasia and respiratory epithelium, inflammation chronic active were primarily of minimal to mild severity. The incidences of olfactory epithelium degeneration were significantly increased in 50 and 100 mg/kg/day females compared to the vehicle control group; two incidences of this lesion occurred in 25 mg/kg/day females (Table 18). The incidence of olfactory epithelium hyperplasia was significantly increased in 50 mg/kg/day females compared to the vehicle control group, and two incidences occurred in 25 mg/kg/day females. The incidence of olfactory epithelium suppurative inflammation was significantly increased in 100 mg/kg/day females compared to the vehicle control group. Olfactory epithelium degeneration, hyperplasia, and suppurative inflammation were primarily of minimal to mild severity.

Bone Marrow: The incidence of bone marrow hypocellularity was significantly increased in 10 mg/kg/day males compared to the vehicle control group (Table 18). Bone marrow hypocellularity was minimal in severity in males. There were two incidences in females.

Thyroid Gland: The incidence of thyroid gland follicular cell hypertrophy was increased, but not significantly in 10 mg/kg/day males and significantly increased in 100 mg/kg/day females compared to the vehicle control groups (Table 18). Follicle cell hypertrophy was of minimal severity.

### Perfluorononanoic Acid (PFNA)

Survival of 5 and 10 mg/kg/day males and 12.5 and 25 mg/kg/day females was significantly less than that of the respective vehicle control groups (Table 19). Eight 5 mg/kg/day males, all 10 mg/kg/day males, nine 12.5 mg/kg/day females, and all 25 mg/kg/day females died before the end of the study. The rats in these dose groups were described as thin. The final mean body weights of the 1.25, 2.5, and 5 mg/kg/day males were 17%, 44%, and 55% less than that of the vehicle control group, respectively (Table 19; Figure 3). The final mean body weights of the 6.25 and the 12.5 mg/kg/day females were 10% and 23% less than that of the vehicle control group, respectively.

Table 19 Mean Body Weights and Survival of Rats in the 28-day Gavage Study of Perfluorononanoic Acid

Day | Vehicle Control | | 0.625 mg/kg/day | | | 1.25 mg/kg/day | | | 2.5 mg/kg/day | | | 5 mg/kg/day | | | 10 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 267 | 10 | 269 | 101 | 10 | 268 | 100 | 10 | 266 | 100 | 10 | 268 | 100 | 10 | 266 | 100 | 10
8 | 289 | 10 | 293 | 101 | 10 | 292 | 101 | 10 | 288 | 99 | 10 | 260 | 90 | 10 | 220 | 76 | 10
15 | 307 | 10 | 314 | 102 | 10 | 305 | 99 | 10 | 267 | 87 | 10 | 210 | 69 | 10 | 155 | 51 | 8
22 | 329 | 10 | 331 | 101 | 10 | 299 | 91 | 10 | 233 | 71 | 10 | 156 | 48 | 10 | – | – | 0
29 | 344 | 10 | 332 | 97 | 10 | 286 | 83 | 10 | 193 | 56 | 10 | 155 | 45 | 2 | – | – | 0
| Vehicle Control | | 1.56 mg/kg/day | | | 3.12 mg/kg/day | | | 6.25 mg/kg/day | | | 12.5 mg/kg/day | | | 25 mg/kg/day
| Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Female
1 | 195 | 10 | 200 | 102 | 10 | 196 | 100 | 10 | 196 | 101 | 10 | 196 | 100 | 10 | 200 | 102 | 10
8 | 204 | 10 | 210 | 103 | 10 | 201 | 98 | 10 | 196 | 96 | 10 | 161 | 79 | 10 | 150 | 73 | 10
15 | 215 | 10 | 218 | 101 | 10 | 210 | 97 | 10 | 196 | 91 | 10 | 146 | 68 | 6 | – | – | 0
22 | 222 | 10 | 226 | 102 | 10 | 212 | 96 | 10 | 200 | 90 | 10 | 130 | 59 | 4 | – | – | 0
29 | 230 | 10 | 231 | 100 | 10 | 217 | 94 | 10 | 207 | 90 | 10 | 178 | 77 | 1 | – | – | 0

Figure 3

Growth Curves for Rats Administered Perfluorononanoic Acid by Gavage for 28 Days

Plasma concentrations of PFNA were higher with increasing dose in both males and females (Table 20). Plasma concentrations normalized to dose generally increased with dose in males except for the 5.0 mg/kg/day group, which might be due to only two animals available to sample. Normalized concentrations in females were similar across the available doses (1.56 to 6.25 mg/kg/day). Normalized plasma concentrations were generally five- to ninefold higher in males compared to females (adjusting for the 2.5-fold higher dose compared to males).

Table 20 Perfluorononanoic Acid Concentrations in Tissues of Rats in the 28-day Gavage Study of Perfluorononanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day
Millimolar Dose (mmol/kg/day) | 0 | 0.0013 | 0.0027 | 0.0054 | 0.0108
Male
n | 10 | 10 | 10 | 10 | 2
Plasma
Plasma Concentration (ng/mL) | 55 ± 12 | 56,730 ± 1,878** | 161,000 ± 4,928** | 380,000 ± 15,639** | 358,000 ± 54,000**
Plasma Concentration (μM) | 0.1 ± 0.0 | 122.2 ± 4.0** | 346.9 ± 10.6** | 818.8 ± 33.7** | 771.4 ± 116.4**
Normalized Plasma Concentration (µM/mmol/kg) | NA | 90,768.0 ± 3,005.4 | 128,800.0 ± 3,942.7 | 152,000.0 ± 6,255.6 | 71,600.0 ± 10,800.0
Liver
Liver Concentration (ng/mL) | 762 ± 33 | 145,500 ± 2,684** | 249,200 ± 4,692** | 311,400 ± 7,449** | 313,000 ± 59,000**
Liver Concentration (µM)^b^ | 1.6 ± 0.1 | 313.5 ± 5.8** | 537.0 ± 10.1** | 671.0 ± 16.1** | 674.5 ± 127.1**
Normalized Liver Concentration (µM/mmol/kg) | NA | 232,800.0 ± 4,294.9 | 199,360.0 ± 3,753.8 | 124,560.0 ± 2,979.8 | 62,600.0 ± 11,800.0
Liver/Plasma Ratio | 16.36 ± 1.53 | 2.59 ± 0.10** | 1.56 ± 0.06** | 0.83 ± 0.04** | 0.87 ± 0.03**
| Vehicle Control | 1.56 mg/kg/day | 3.12 mg/kg/day | 6.25 mg/kg/day | 12.5 mg/kg/day
Millimolar Dose (mmol/kg/day) | 0 | 0.0034 | 0.0067 | 0.0135 | 0.0269
Female
n | 10 | 10 | 10 | 10 | 1^c^
Plasma
Plasma Concentration (ng/mL) | 98 ± 11 | 26,400 ± 1,085** | 54,360 ± 2,486** | 112,200 ± 9,772** | –
Plasma Concentration (µM) | 0.2 ± 0.0 | 56.9 ± 2.3** | 117.1 ± 5.4** | 241.8 ± 21.1** | –
Normalized Plasma Concentration (µM/mmol/kg) | NA | 16,923.1 ± 695.8 | 17,423.1 ± 796.9 | 17,952.0 ± 1,563.6 | –

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s or Dunn’s test.

^a^ Tissue concentration data are presented as mean ± standard error. If over 20% of the values in a group were above the limit of quantification (plasma LOQ = 25 ng/mL; liver LOQ = 500 ng/g), then values that were below the limit of quantification were substituted with one-half the limit of quantification value. NA=not applicable; value could not be calculated when dose value was 0.

^b^ Density is assumed to be 1.0 g/mL.

^c^ Statistical tests were not performed due to there being only one survivor.

Liver concentrations (measured in males only) increased with dose, and when normalized to dose administered (µM/mmol/kg), these values decreased with dose (Table 20). The liver/plasma ratio ranged from 0.87 to 2.59.

The mean absolute and relative liver weights of 0.625 and 1.25 mg/kg/day males and the mean relative liver weight of 2.5 mg/kg/day males were significantly greater than those of the vehicle control group (Table 21). The mean absolute and relative liver weights of 1.56, 3.12, and 6.25 mg/kg/day females were significantly greater than those of the vehicle control group.

Table 21 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day Gavage Study of Perfluorononanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
Male
n | 10 | 10 | 10 | 10
Necropsy Body Wt. | 344 ± 6 | 332 ± 6 | 286 ± 5** | 193 ± 9**
R. Adrenal Gland
Absolute | 0.0220 ± 0.0009 | 0.0187 ± 0.0006** | 0.0179 ± 0.0010** | 0.0175 ± 0.0006**
Relative | 0.06 ± 0.00 | 0.06 ± 0.00 | 0.06 ± 0.00 | 0.09 ± 0.00**
R. Kidney
Absolute | 1.02 ± 0.02 | 1.14 ± 0.03 | 1.04 ± 0.02 | 0.82 ± 0.03**
Relative | 2.97 ± 0.05 | 3.43 ± 0.05** | 3.64 ± 0.07** | 4.26 ± 0.06**
Liver
Absolute | 11.73 ± 0.23 | 13.99 ± 0.33* | 15.58 ± 0.27** | 12.33 ± 0.92
Relative | 34.14 ± 0.3 | 42.12 ± 0.58** | 54.47 ± 0.59** | 63.37 ± 1.86**
Spleen
Absolute | 0.674 ± 0.015 | 0.615 ± 0.035 | 0.496 ± 0.017** | 0.286 ± 0.021**
Relative | 1.96 ± 0.03 | 1.85 ± 0.09 | 1.73 ± 0.05* | 1.48 ± 0.06**
R. Testis
Absolute | 1.870 ± 0.045 | 1.793 ± 0.035 | 1.757 ± 0.032 | 1.493 ± 0.055**
Thymus
Absolute | 0.389 ± 0.021 | 0.427 ± 0.022 | 0.268 ± 0.012** | 0.087 ± 0.017**
Relative | 1.13 ± 0.06 | 1.29 ± 0.07 | 0.93 ± 0.03* | 0.43 ± 0.06**
Thyroid Gland
Absolute | 0.0226 ± 0.0010 | 0.0251 ± 0.0016 | 0.0210 ± 0.0009 | 0.0161 ± 0.0009**
Relative | 0.07 ± 0.00 | 0.08 ± 0.00 | 0.07 ± 0.00 | 0.09 ± 0.01**
| Vehicle Control | 1.56 mg/kg/day | 3.12 mg/kg/day | 6.25 mg/kg/day
Female
n | 10 | 10 | 10 | 10
Necropsy Body Wt. | 230 ± 5 | 231 ± 3 | 217 ± 3* | 207 ± 4**
R. Kidney
Absolute | 0.66 ± 0.01 | 0.71 ± 0.02* | 0.73 ± 0.01** | 0.73 ± 0.02**
Relative | 2.89 ± 0.06 | 3.10 ± 0.04* | 3.38 ± 0.04** | 3.53 ± 0.08**
Liver
Absolute | 7.67 ± 0.29 | 9.30 ± 0.30** | 9.74 ± 0.22** | 10.12 ± 0.28**
Relative | 33.29 ± 0.70 | 40.30 ± 0.91** | 44.95 ± 0.74** | 48.92 ± 0.68**
Spleen
Absolute | 0.598 ± 0.018 | 0.609 ± 0.022 | 0.533 ± 0.013* | 0.481 ± 0.019**
Relative | 2.60 ± 0.05 | 2.64 ± 0.07 | 2.46 ± 0.04 | 2.32 ± 0.06**

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). No data presented for the 5 or 10 (males) or 12.5 or 25 (females) mg/kg/day groups due to high mortality.

The mean absolute adrenal gland weights of 0.625, 1.25, and 2.5 mg/kg/day males were significantly less than that of the vehicle control group (Table 21). The mean relative adrenal gland weights of 2.5 mg/kg/day males were significantly greater than that of the vehicle control group.

The mean absolute kidney weight of 2.5 mg/kg/day males was significantly less than that of the vehicle control group (Table 21). The mean relative kidney weights of 0.625, 1.25, and 2.5 mg/kg/day males were significantly greater than that of the vehicle control group. The mean absolute and relative kidney weights of 1.56, 3.12, and 6.25 mg/kg/day females were significantly greater than those of the vehicle control group.

The mean absolute and relative spleen and thymus weights of 1.25 and 2.5 mg/kg/day males were significantly less than those of the vehicle control group (Table 21). The mean absolute spleen weight of 3.12 mg/kg/day females and the absolute and relative spleen weights of 6.25 mg/kg/day females were significantly less than those of the vehicle control group (Table 21). The decreases in the spleen and thymus weights had histologic correlates of lymphocyte atrophy and were attributed to stress.

The mean absolute thyroid gland weights of 2.5 and 5 mg/kg/day males were significantly less than that of the vehicle control group (Table 21). The mean relative thyroid gland weights of the 2.5 and 5 mg/kg/day males were significantly greater than that of the vehicle control group.

The mean absolute testis weight of 2.5 mg/kg/day males was significantly less than that of the vehicle control group (Table 21).

There was no clinical pathology interpretation for 5 or 10 mg/kg/day male rats or 12.5 or 25 mg/kg/day female rats due to high mortality in these groups. A significant, dose-dependent decrease in the reticulocyte count was observed in male rats, with the 2.5 mg/kg/day group decreased by 95% of the vehicle controls (Table 22). As a result of these decreased reticulocyte counts, the mean cell volume was significantly decreased, and the mean cell hemoglobin concentration significantly increased in the 2.5 mg/kg/day males. The leukocyte count was significantly decreased in the 2.5 mg/kg males compared to the vehicle control group; the decrease was mostly a result of a significantly decreased lymphocyte count.

Table 22 Hematology and Clinical Chemistry Data for Rats in the 28-day Gavage Study of Perfluorononanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
Male
Hematology
n | 10 | 10 | 10 | 10
Reticulocytes (10^3^/μL) | 168.3 ± 6.5 | 135.5 ± 8.1* | 85.3 ± 6.7** | 8.2 ± 1.7**
Mean Cell Volume (fL) | 60.2 ± 0.4 | 60.5 ± 0.6 | 59.7 ± 0.3 | 56.9 ± 0.4**
Mean Cell Hemoglobin Concentration (g/dL) | 30.0 ± 0.1 | 30.1 ± 0.1 | 30.1 ± 0.1 | 30.7 ± 0.1**
Leukocytes (10^3^/μL) | 10.92 ± 0.36 | 11.01 ± 0.76 | 9.74 ± 0.57 | 5.66 ± 0.74**
Lymphocytes (10^3^/μL) | 9.17 ± 0.29 | 9.53 ± 0.70 | 8.53 ± 0.52 | 4.22 ± 0.62**
Clinical Chemistry
n | 10 | 10 | 10 | 10
Urea Nitrogen (mg/dL) | 18.5 ± 0.9 | 21.6 ± 0.6* | 24.8 ± 0.7** | 27.6 ± 1.5**
Creatinine (mg/dL) | 0.73 ± 0.02 | 0.72 ± 0.01 | 0.69 ± 0.02 | 0.62 ± 0.02**
Glucose (mg/dL) | 188 ± 8 | 202 ± 7 | 168 ± 6.0 | 104 ± 5**
Total Protein (g/dL) | 6.6 ± 0.0 | 6.0 ± 0.1** | 5.5 ± 0.1** | 4.3 ± 0.1**
Albumin (g/dL) | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.1 ± 0.1** | 3.2 ± 0.1**
Globulin (g/dL) | 2.2 ± 0.0 | 1.5 ± 0.0** | 1.4 ± 0.1** | 1.1 ± 0.0**
Albumin/Globulin Ratio | 2.0 ± 0.0 | 2.9 ± 0.1** | 3.1 ± 0.1** | 3.1 ± 0.1**
Total Bilirubin (mg/dL) | 0.2 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0* | 0.7 ± 0.1**
Direct Bilirubin (mg/dL) | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.05 ± 0.00** | 0.32 ± 0.04**
Indirect Bilirubin (mg/dL) | 0.132 ± 0.009 | 0.114 ± 0.009 | 0.150 ± 0.009 | 0.398 ± 0.040**
Cholesterol (mg/dL) | 117 ± 5 | 86 ± 2** | 91 ± 4** | 108 ± 9
Triglycerides (mg/dL) | 120 ± 9 | 59 ± 9** | 81 ± 6** | 59 ± 4**
Alanine Aminotransferase (IU/L) | 58 ± 2^b^ | 75 ± 5 | 86 ± 4** | 59 ± 4
Alkaline Phosphatase (IU/L) | 207 ± 5 | 247 ± 15 | 397 ± 25** | 204 ± 31
Aspartate Aminotransferase (IU/L) | 85 ± 23 | 74 ± 3 | 96 ± 3** | 119 ± 11**
Sorbitol Dehydrogenase (IU/L) | 9 ± 1^b^ | 12 ± 1 | 13 ± 1* | 13 ± 1*
Total Bile Acids (µmol/L) | 13.1 ± 2.4 | 27.6 ± 3.1** | 71.0 ± 7.8** | 221.9 ± 16.1**
Thyroid Stimulating Hormone (ng/mL) | 20.33 ± 2.31 | 13.70 ± 1.27 | 10.97 ± 1.22**^b^ | 10.16 ± 3.35**^c^
Triiodothyronine (ng/dL) | 78.21 ± 4.54 | 58.54 ± 2.11 | 84.93 ± 2.94 | 111.79 ± 10.16*^b^
Free Thyroxine (ng/dL) | 2.16 ± 0.15 | 0.55 ± 0.02** | 0.33 ± 0.01** | 0.30 ± 0.00**^d^
Total Thyroxine (µg/dL) | 2.36 ± 0.27 | 0.21 ± 0.07** | 0.38 ± 0.07** | 1.49 ± 0.13
Testosterone (ng/mL) | 4.48 ± 1.31 | 4.86 ± 1.33 | 3.23 ± 1.38 | 0.85 ± 0.51**^b^
| Vehicle Control | 1.56 mg/kg/day | 3.12 mg/kg/day | 6.25 mg/kg/day
Female
Clinical Chemistry
n | 10 | 10 | 10 | 10
Urea Nitrogen (mg/dL) | 17.2 ± 1.0 | 18.1 ± 0.5 | 21.3 ± 0.8** | 22.1 ± 1.4**
Total Protein (g/dL) | 6.3 ± 0.1 | 6.6 ± 0.1* | 6.7 ± 0.1** | 6.7 ± 0.1**
Albumin (g/dL) | 4.4 ± 0.1 | 4.9 ± 0.1** | 5.1 ± 0.1** | 5.2 ± 0.1**
Globulin (g/dL) | 1.9 ± 0.1 | 1.6 ± 0.1* | 1.6 ± 0.1** | 1.5 ± 0.0**
Albumin/Globulin Ratio | 2.4 ± 0.1 | 3.0 ± 0.1** | 3.2 ± 0.1** | 3.5 ± 0.1**
Direct Bilirubin (mg/dL) | 0.02 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00*
Alanine Aminotransferase (IU/L) | 45 ± 3 | 47 ± 1 | 53 ± 1** | 59 ± 3**
Alkaline Phosphatase (IU/L) | 144 ± 7 | 159 ± 5 | 183 ± 8** | 199 ± 13**
Sorbitol Dehydrogenase (IU/L) | 7 ± 1 | 9 ± 1* | 9 ± 1** | 10 ± 1**
Total Bile Acids (µmol/L) | 9.9 ± 2.1 | 15.1 ± 2.4 | 21.1 ± 1.5** | 28.0 ± 4.5**
Thyroid Stimulating Hormone (ng/mL) | 14.64 ± 1.66 | 15.52 ± 1.53 | 14.11 ± 1.13 | 14.33 ± 1.08
Triiodothyronine (ng/dL) | 93.70 ± 6.03 | 84.10 ± 4.15 | 83.26 ± 2.67 | 89.90 ± 6.82
Free Thyroxine (ng/dL) | 1.70 ± 0.20 | 1.47 ± 0.15 | 1.10 ± 0.10* | 0.80 ± 0.10**
Total Thyroxine (µg/dL) | 4.37 ± 0.41 | 3.57 ± 0.28 | 2.81 ± 0.17** | 2.61 ± 0.24**
Testosterone (ng/mL) | 0.30 ± 0.02 | 0.39 ± 0.03* | 0.44 ± 0.04** | 0.49 ± 0.04**

* Significantly different (p ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. No data are reported for the 5 or 10 (male) or 12.5 or 25 (female) mg/kg/day groups due to high mortality.

^b^ n = 9.

^c^ n = 4.

^d^ n = 7.

Urea nitrogen concentrations were significantly increased in all male dose groups (except 5 mg/kg/day) and in 3.12 and 6.25 mg/kg/day females compared to the vehicle control groups (Table 22). In males, the creatinine and glucose concentrations were significantly decreased at 2.5 mg/kg/day compared to the vehicle control group; these decreases were likely related to the decreased food intake and body weight. Cholesterol and triglyceride concentrations were significantly decreased in the majority of the dose groups compared to the vehicle control group.

Total protein and globulin concentrations were significantly decreased in all male dose groups and the albumin concentrations were significantly decreased in 1.25 and 2.5 mg/kg/day males compared to the vehicle control group (Table 22). These changes resulted in an increase in the albumin/globulin ratio in all the dose groups. Globulin concentrations were significantly decreased and total protein and albumin concentrations significantly increased in all female dose groups (except 12.5 mg/kg/day) compared to the vehicle control group; the combination of these changes resulted in significant increases in the albumin/globulin ratio of all the female dose groups.

Total bilirubin concentrations (driven by both direct and indirect bilirubin) and AST and SDH activities were significantly increased in 1.25 and 2.5 mg/kg/day males compared to the vehicle control group (Table 22). ALT and ALP activities were significantly increased in 1.25 mg/kg males compared to the vehicle control group, and total bile acid concentrations were significantly increased in all dose groups. In females, ALT and ALP activities and total bile acid concentrations were significantly increased at 3.12 and 6.25 mg/kg/day compared to the vehicle control group; direct bilirubin was increased in the 6.25 mg/kg/day females compared to the vehicle control group. SDH activities were significantly increased in all female dose groups compared to the vehicle control group.

Free T4 concentrations were significantly decreased in all male dose groups compared to the vehicle control group, and total T4 concentrations were decreased in 0.625 and 1.25 mg/kg/day males (Table 22). TSH concentration was significantly decreased, and T3 concentration was significantly increased in 2.5 mg/kg/day males. Free T4 and total T4 concentrations were significantly decreased in 3.12 and 6.25 mg/kg/day females compared to the vehicle control group. Testosterone concentrations were significantly decreased in 2.5 mg/kg males and increased in all female dose groups compared to the respective vehicle control groups.

Male and female rats administered PFNA exhibited a significant increase in gene expression of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2 compared to respective controls, suggesting a significant increase in PPARα and CAR activity (Table 23). Male rats exhibited the highest fold change for Cyp4a1 and in female rats, it was Cyp2b1 when compared to respective controls. Cyp2b1 and Cyp2b2 had the lowest fold change in males compared to controls, indicating weaker CAR activation. Acyl-CoA oxidase activity was increased in all dosed males.

Table 23 Hepatic Parameters for Rats in the 28-day Gavage Study of Perfluorononanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 2
Enzyme Activity
Acetyl-CoA (nmol/min/mg) | 2.179 ± 0.049 | 10.694 ± 0.390** | 15.400 ± 0.374** | 13.060 ± 0.306** | 10.600 ± 0.200**
Gene Expression
Acox1 | 1.06 ± 0.13 | 4.33 ± 0.67** | 4.96 ± 0.56** | 6.26 ± 0.71** | 6.62 ± 1.34**
Cyp4a1 | 1.11 ± 0.16 | 22.08 ± 4.87** | 24.10 ± 4.88** | 20.56 ± 2.73** | 22.62 ± 6.93*
Cyp2b1 | 1.40 ± 0.32 | 9.01 ± 2.13** | 9.45 ± 1.36** | 5.69 ± 0.80* | 4.18 ± 0.02
Cyp2b2 | 1.22 ± 0.27 | 3.85 ± 0.48** | 4.98 ± 0.52** | 3.94 ± 0.77** | 4.66 ± 1.67*
| Vehicle Control | 1.56 mg/kg/day | 3.12 mg/kg/day | 6.25 mg/kg/day | 12.5 mg/kg/day
Female
n | 10 | 10 | 10 | 10 | 1
Gene Expression
Acox1 | 1.02 ± 0.06 | 3.13 ± 0.57** | 4.13 ± 0.48** | 5.27 ± 0.99** | 4.92^b^
Cyp4a1 | 1.05 ± 0.10 | 8.08 ± 3.36** | 10.64 ± 3.83** | 13.82 ± 3.05** | 18.77
Cyp2b1 | 2.68 ± 1.37 | 29.83 ± 9.57** | 38.20 ± 9.24** | 36.40 ± 8.65** | 33.85
Cyp2b2 | 2.06 ± 0.85 | 14.42 ± 1.50** | 21.28 ± 2.17** | 22.95 ± 3.82** | 27.65

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Gene expression data are presented as fold change values from the base-signal values. No data available for the 10 (males) or 25 (females) mg/kg/day groups due to 100% mortality.

^b^ Statistical tests were not performed due to there being only one survivor.

Male rats assessed for reproductive toxicity were administered 0, 0.625, 1.25, or 2.5 mg PFNA/kg/day for 28 days, which is much less than the time needed to make a full assessment of the effect on spermatogenesis. Cauda epididymal weights were lower in the rats administered to 1.25 or 2.5 mg/kg/day compared to the vehicle controls (11% and 33% respectively; statistically significant) (Table 24). Cauda epididymal sperm counts in these rats were also lower (18% and 31%, respectively; statistically significant). When normalized to total sperm count/g cauda epididymis, counts in dosed rats were similar to vehicle controls. Histopathologic findings in the epididymis were noted in multiple rats administered 2.5 mg/kg/day or greater (hypospermia, exfoliated germ cells, apoptosis of the epididymal epithelium, granuloma sperm) (Table 26). Rats administered 1.25 or 2.5 mg/kg/day had lower testis weights than vehicle controls (7% and 20%, respectively; statistically significant). Testicular spermatid counts and normalized counts were variable (no apparent dose responses). Multiple histopathologic findings in the testis were noted in rats administered 2.5 mg/kg/day or greater (degeneration, spermatid retention, interstitial cell atrophy) (Table 26). Males administered 1.25, and 2.5 mg/kg/day displayed lower serum testosterone levels (28% and 81%, lower) (Table 22).

Table 24 Summary of Reproductive Tissue Evaluations for Male Rats in the 28-day Gavage Study of Perfluorononanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy Body Wt. | 344 ± 6 | 332 ± 6 | 286 ± 5** | 193 ± 9**
L. Cauda Epididymis | 0.195 ± 0.005 | 0.189 ± 0.005 | 0.173 ± 0.004** | 0.130 ± 0.008**
L. Epididymis | 0.555 ± 0.013 | 0.515 ± 0.010* | 0.482 ± 0.005** | 0.363 ± 0.022**
L. Testis | 1.885 ± 0.041 | 1.820 ± 0.035 | 1.762 ± 0.031* | 1.507 ± 0.052**
Spermatid Measurements
Spermatid Heads (10^6^/testis) | 230.2 ± 10.7 | 192.5 ± 7.1* | 220.8 ± 10.8 | 205.1 ± 9.5
Spermatid Heads (10^6^/g testis) | 121.9 ± 4.3 | 105.8 ± 3.6 | 125.3 ± 5.8 | 136.4 ± 5.3
Epididymal Spermatozoal Measurements
Sperm Motility (%) | 85.2 ± 0.5 | 85.9 ± 0.4 | 86.4 ± 0.7 | 85.8 ± 0.6
Sperm (10^6^/cauda epididymis) | 142.3 ± 9.4 | 136.2 ± 7.9 | 116.0 ± 6.3* | 98.1 ± 9.0**
Sperm (10^6^/g cauda epididymis) | 731.2 ± 49.2 | 725.7 ± 47.7 | 674.4 ± 40.4 | 753.5 ± 47.2

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test (weights) or Shirley’s or Dunn’s test (spermatid and epididymal spermatozoal measurements).

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

Table 26 Incidences of Selected Nonneoplastic Lesions in Rats in the 28-day Gavage Study of Perfluorononanoic Acid

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
Male
Liver^a^ | (10) | (10) | (10) | (10) | (9) | (10)
Hepatocyte, Cytoplasmic Alteration^b^ | 0 | 10** (1.5)^c^ | 10** (3.7) | 10** (4.0) | 9** (3.1) | 10** (2.1)
Hepatocyte, Hypertrophy | 0 | 7** (2.3) | 10** (4.0) | 10** (4.0) | 9** (3.6) | 10** (3.0)
Hepatocyte, Necrosis | 0 | 0 | 1 (1.0) | 5* (1.2) | 6** (2.0) | 9** (1.8)
Hepatocyte, Vacuolization, Cytoplasmic | 0 | 0 | 6** (1.5) | 9** (3.7) | 0 | 0
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium Degeneration | 0 | 0 | 0 | 0 | 1 (1.0) | 3 (1.3)
Bone Marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hypocellularity | 0 | 0 | 0 | 10** (3.4) | 10** (4.0) | 10** (3.1)
Spleen | (10) | (10) | (10) | (10) | (8) | (10)
Atrophy | 0 | 0 | 0 | 0 | 7** (3.6) | 9** (4.0)
Thymus | (10) | (10) | (10) | (10) | (10) | (8)
Atrophy | 0 | 0 | 0 | 10** (3.3) | 10** (4.0) | 8** (4.0)
Lymph Node, Mandibular | (10) | (10) | (10) | (10) | (7) | (10)
Atrophy | 0 | 0 | 0 | 2 (1.5) | 5** (3.8) | 5* (2.2)
Lymph Node, Mesenteric | (10) | (10) | (10) | (10) | (8) | (10)
Atrophy | 0 | 0 | 0 | 3 (3.0) | 6** (3.7) | 9** (3.2)
Stomach, Forestomach | (10) | (10) | (10) | (10) | (8) | (10)
Epithelium, Hyperplasia | 0 | 0 | 0 | 6** (2.3) | 6** (1.8) | 8** (1.8)
Inflammation, Chronic Active | 0 | 0 | 0 | 5* (2.0) | 0 | 0
Testes | (10) | (10) | (10) | (10) | (9) | (10)
Germinal Epithelium, Degeneration | 0 | 0 | 0 | 6** (2.2) | 9** (3.1) | 10** (3.7)
Interstitial Cell, Atrophy | 0 | 0 | 1 (1.0) | 10** (1.7) | 9** (3.1) | 10** (3.5)
Seminiferous Tubule, Spermatid Retention | 0 | 0 | 0 | 6** (2.8) | 9** (3.0) | 10** (3.0)
Epididymis | (10) | (10) | (10) | (10) | (9) | (10)
Hypospermia | 0 | 0 | 0 | 2 (2.5) | 9** (3.7) | 10** (2.9)
Duct, Exfoliated Germ Cell | 0 | 0 | 0 | 6** (2.7) | 9** (3.7) | 10** (3.6)
Epithelium, Apoptosis | 0 | 0 | 0 | 0 | 8** (2.0) | 10** (2.1)
Granuloma Sperm | 0 | 0 | 0 | 0 | 0 | 4* (2.0)
| Vehicle Control | 1.56 mg/kg/day | 3.12 mg/kg/day | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
Female
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration | 0 | 5* (1.0) | 10** (1.0) | 10** (2.4) | 9** (1.6) | 0
Hepatocyte, Hypertrophy | 0 | 0 | 2 (1.0) | 10** (4.0) | 10** (3.0) | 10** (2.6)
Hepatocyte, Necrosis | 0 | 0 | 0 | 0 | 4* (1.3) | 3 (1.0)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium Degeneration | 0 | 0 | 0 | 0 | 0 | 5* (2.0)
Olfactory Epithelium, Inflammation, Suppurative | 0 | 0 | 0 | 0 | 0 | 3 (1.7)
Bone Marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hypocellularity | 0 | 0 | 0 | 0 | 10** (3.8) | 10** (3.1)
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Atrophy | 0 | 0 | 0 | 0 | 8** (4.0) | 10** (4.0)
Thymus | (10) | (10) | (10) | (10) | (10) | (10)
Atrophy | 0 | 0 | 0 | 0 | 9** (4.0) | 10** (4.0)
Lymph Node, Mandibular | (10) | (10) | (10) | (10) | (8) | (9)
Atrophy | 0 | 0 | 0 | 0 | 8** (3.4) | 9** (3.1)
Lymph Node, Mesenteric | (10) | (10) | (10) | (10) | (9) | (10)
Atrophy | 0 | 0 | 0 | 0 | 8** (4.0) | 9** (2.9)
Stomach, Forestomach | (10) | (10) | (10) | (10) | (10) | (10)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 7** (2.0) | 6** (1.5)

* Significantly different (p ≤ 0.05) from the vehicle control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Female rats assessed for reproductive toxicity were administered 0, 1.56, 3.12, or 6.25 mg PFNA/kg/day. Inspection of daily vaginal cytology data indicated that the rats were cycling similar to vehicle controls ([REMOVED REF FIELD]Table 25 and Table A-4). Females in the 6.25 mg/kg/day dose group had fewer mean cycles (1.3 versus 1.7 in vehicle controls) and fewer were cycling (6 versus 9 in vehicle controls). Female rats in the 1.56, 3.12, and 6.25 mg/kg/day groups displayed 34%, 49%, and 66% higher testosterone levels (Table 22), the precursor of 17β-estradiol via aromatase, than vehicle controls.

Table 25 Estrous Cycle Characterization for Female Rats in the 28-day Gavage Study of Perfluorononanoic Acid^a^

| Vehicle Control | 1.56 mg/kg/day | 3.12 mg/kg/day | 6.25 mg/kg/day
Number Weighed at Necropsy | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 230 ± 5 | 231 ± 3 | 217 ± 3* | 207 ± 4**
Proportion of Regular Cycling Females^b^ | 9/10 | 10/10 | 9/10 | 6/10
Estrous Cycle Length (days) | 5.1 ± 0.10 | 5.7 ± 0.71 | 5.1 ± 0.11 | 5.0 ± 0.00
Mean Number of Cycles | 1.7 | 1.9 | 2.0 | 1.3
Estrous Stages (% of cycle)
Diestrus | 67.5 | 60.6 | 61.3 | 75.0
Proestrus | 5.0 | 9.4 | 8.8 | 5.0
Estrus | 27.5 | 30.0 | 29.4 | 18.8
Metestrus | 0.0 | 0.0 | 0.0 | 1.3
Uncertain | 0.0 | 0.0 | 0.6 | 0.0

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test (body weight).

** p ≤ 0.01.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated that 3.12 mg/kg/day females had extended diestrus.

^b^ Number of females with a regular cycle/number of females cycling.

#### Pathology

The morphologic features of the lesions discussed in this section are presented in the Histopathologic Descriptions section following the Wyeth-14,643 results.

Liver: Compared to the respective vehicle control groups, the incidences of hepatocyte cytoplasmic alteration were significantly increased in all male dose groups and in 1.56, 3.12, 6.25, and 12.5 mg/kg/day female groups (Table 26) compared to the respective vehicle control groups. The incidences of hepatocyte hypertrophy were significantly increased in all dosed males and in 6.25 mg/kg/day or greater females compared to the respective vehicle control groups. The incidences of hepatocyte necrosis were significantly increased in 2.5 mg/kg/day or greater males and 12.5 mg/kg/day females compared to the respective vehicle control groups. The incidences of cytoplasmic vacuolization were significantly increased at 1.25 and 2.5 mg/kg/day in males compared to the vehicle control group. Severity of the hepatocellular lesions generally varied from minimal to marked among the dosed rats.

Nose: The incidence of olfactory epithelium degeneration was increased in 10 mg/kg/day males and significantly increased in 25 mg/kg/day females compared to the respective vehicle control groups (Table 26). The incidence of olfactory epithelium suppurative inflammation was increased in 25 mg/kg/day females compared to the vehicle control group; however, the increase was not statistically significant.

Bone marrow: The incidences of bone marrow hypocellularity were significantly increased in 2.5 mg/kg/day or greater males and 12.5 and 25 mg/kg/day females compared to the respective vehicle control groups (Table 26). The severity of bone marrow hypocellularity varied from moderate to marked among dosed rats.

Spleen: The incidences of splenic atrophy were significantly increased in 5 and 10 mg/kg/day males and 12.5 and 25 mg/kg/day females compared to the respective vehicle control groups (Table 26). The severity was moderate to marked.

Thymus: The incidences of atrophy were significantly increased in males administered 2.5 mg/kg/day or greater and in 12.5 and 25 mg/kg/day females compared to the respective vehicle control groups (Table 26). The severity was generally marked.

Mandibular and Mesenteric Lymph Nodes: The incidences of atrophy were significantly increased in 5 and 10 mg/kg/day males and 12.5 and 25 mg/kg/day females compared to the respective vehicle control groups (Table 26). Severities ranged from moderate to marked.

Forestomach: The incidences of epithelial hyperplasia were significantly increased in 2.5 mg/kg/day or greater males and 12.5 and 25 mg/kg/day females compared to the respective vehicle control groups (Table 26). Average severities ranged from minimal to mild. The incidence of chronic inflammation was significantly increased compared to the vehicle control group with mild severity in 2.5 mg/kg/day males.

Testes: The incidences of germinal epithelium degeneration, interstitial cell atrophy, and spermatid retention in the seminiferous tubule were significantly increased in 2.5 mg/kg/day or greater males compared to those of the vehicle control group (Table 26). In general, the severities of the testicular lesions ranged from mild to marked.

Epididymis: The incidences of hypospermia and epithelial apoptosis in the 5 and 10 mg/kg/day dose groups and the incidences of duct, exfoliated germ cells in males administered 2.5 mg/kg/day or greater were significantly increased compared to those of the vehicle control group (Table 26). The incidence of granuloma sperm was significantly increased in the 10 mg/kg/day group compared to the vehicle control group. In general, the severities of the epididymal lesions ranged from mild to marked.

### Perfluorodecanoic Acid (PFDA)

All rats survived to the end of the study (Table 27). No clinical observations related to chemical exposure were observed. The final mean body weights of the 1.25 and the 2.5 mg/kg/day males were 21% and 38% less, respectively, than that of the vehicle control group; the mean body weights of 1.25 and 2.5 mg/kg/day females were 12% and 36% less, respectively, than that of the vehicle control group (Table 27; Figure 4).

Table 27 Mean Body Weights and Survival of Rats in the 28-day Gavage Study of Perfluorodecanoic Acid

Day | Vehicle Control | | 0.156 mg/kg/day | | | 0.312 mg/kg/day | | | 0.625 mg/kg/day | | | 1.25 mg/kg/day | | | 2.5 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 265 | 10 | 265 | 100 | 10 | 263 | 99 | 10 | 263 | 99 | 10 | 264 | 100 | 10 | 266 | 100 | 10
8 | 286 | 10 | 287 | 100 | 10 | 284 | 99 | 10 | 285 | 100 | 10 | 285 | 100 | 10 | 283 | 99 | 10
15 | 304 | 10 | 310 | 102 | 10 | 301 | 99 | 10 | 306 | 101 | 10 | 291 | 96 | 10 | 264 | 87 | 10
22 | 323 | 10 | 329 | 102 | 10 | 317 | 98 | 10 | 313 | 97 | 10 | 273 | 85 | 10 | 236 | 73 | 10
29 | 333 | 10 | 344 | 103 | 10 | 331 | 99 | 10 | 322 | 97 | 10 | 263 | 79 | 10 | 207 | 62 | 10
Female
1 | 193 | 10 | 196 | 102 | 10 | 195 | 101 | 10 | 193 | 100 | 10 | 194 | 101 | 10 | 194 | 101 | 10
8 | 202 | 10 | 209 | 104 | 10 | 208 | 103 | 10 | 204 | 101 | 10 | 203 | 101 | 10 | 199 | 99 | 10
15 | 211 | 10 | 219 | 104 | 10 | 212 | 101 | 10 | 212 | 101 | 10 | 208 | 99 | 10 | 178 | 84 | 10
22 | 219 | 10 | 226 | 103 | 10 | 225 | 103 | 10 | 222 | 101 | 10 | 205 | 94 | 10 | 164 | 75 | 10
29 | 227 | 10 | 237 | 104 | 10 | 236 | 104 | 10 | 227 | 100 | 10 | 199 | 88 | 10 | 145 | 64 | 10

Figure 4

Growth Curves for Rats Administered Perfluorodecanoic Acid by Gavage for 28 Days

Plasma concentrations of PFDA increased with increasing dose in both males and females and were marginally higher in females (30% or less) compared to males across the corresponding dose groups (Table 28). Normalized plasma concentrations (µM/mmol/kg) in males and females increased with dose, with a 1.9-fold increase in males and a 1.4-fold increase in females from lowest to highest dose.

Table 28 Perfluorodecanoic Acid Concentrations in Tissues of Rats in the 28-day Gavage Study of Perfluorodecanoic Acid^a^

| Vehicle Control | 0.156 mg/kg/day | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
Millimolar Dose (mmol/kg/day) | 0 | 0.0003 | 0.00061 | 0.0012 | 0.0024 | 0.0049
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Plasma
Plasma Concentration (ng/mL) | 22 ± 4 | 8,505 ± 578** | 23,030 ± 1,771** | 42,720 ± 2,960** | 101,580 ± 4,009** | 259,400 ± 20,196**
Plasma Concentration (µM) | 0.0 ± 0.0 | 16.5 ± 1.1** | 44.8 ± 3.4** | 83.1 ± 5.8** | 197.6 ± 7.8** | 504.6 ± 39.3**
Normalized Plasma Concentration (µM/mmol/kg) | NA | 54,519.2 ± 3,703.9 | 73,814.1 ± 5,674.7 | 68,352.0 ± 4,735.9 | 81,264.0 ± 3,207.4 | 103,760.0 ± 8,078.5
Liver
Liver Concentration (ng/mL)^b^ | BD | 44,680 ± 1,485 | 87,150 ± 1,675 | 163,900 ± 2,799 | 308,800 ± 8,177 | 403,600 ± 13,838
Liver Concentration (µM) | BD | 86.9 ± 2.9 | 169.5 ± 3.3 | 318.8 ± 5.4 | 600.7 ± 15.9 | 785.1 ± 26.9
Normalized Liver Concentration (µM/mmol/kg) | NA | 286,410.3 ± 9,521.8 | 279,326.9 ± 5,367.3 | 262,240.0 ± 4,477.8 | 247,040.0 ± 6,541.5 | 161,440.0 ± 5,535.2
Liver/Plasma Ratio | BD | 5.49 ± 0.43 | 4.04 ± 0.40 | 4.00 ± 0.27 | 3.09 ± 0.15 | 1.63 ± 0.12
Female
n | 10 | 9 | 10 | 10 | 10 | 8
Plasma
Plasma Concentration (ng/mL) | 42 ± 17 | 11,208 ± 436** | 25,700 ± 1,048** | 50,290 ± 3,309** | 117,150 ± 6,498** | 246,875 ± 13,291**
Plasma Concentration (µM) | 0.1 ± 0.0 | 21.8 ± 0.8** | 50.0 ± 2.0** | 97.8 ± 6.4** | 227.9 ± 12.6** | 480.2 ± 25.9**
Normalized Plasma Concentration (µM/mmol/kg) | NA | 71,844.7 ± 2,796.2 | 82,371.8 ± 3,359.5 | 80,464.0 ± 5,294.5 | 93,720.0 ± 5,198.5 | 98,750.0 ± 5,316.5

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s or Dunn’s test.

BD = below detection; group did not have more than 20% of its values above the limit of quantification and no statistical analyses were conducted for the endpoint; NA = not applicable; value could not be calculated when dose value was 0.

^a^ Tissue concentration data are presented as mean ± standard error. If more than 20% of the values in a group were above the limit of quantification (plasma LOQ = 25 ng/mL; liver LOQ = 500 ng/g), values that were below the limit of quantification were substituted with one-half the limit of quantification value.

^b^ Density is assumed to be 1.0 g/mL.

Liver concentrations of PFDA were measured in males only and increased with dose, but when normalized to dose (µM/mol/kg), these values decreased with increasing dose (Table 28). Liver/plasma ratios in males decreased with dose from 5.29 to 1.63.

There were dose-related, significant increases in the mean absolute and relative liver weights in treated male and female rats compared to those of the respective vehicle control groups (Table 29).

Table 29 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day Gavage Study of Perfluorodecanoic Acid^a^

| Vehicle Control | 0.156 mg/kg/day | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy Body Wt. | 333 ± 6 | 344 ± 7 | 331 ± 6 | 322 ± 5 | 263 ± 4** | 207 ± 8**
R. Adrenal Gland
Absolute | 0.0214 ± 0.0007 | 0.0182 ± 0.0007* | 0.0200 ± 0.0007* | 0.0185 ± 0.0009** | 0.0169 ± 0.0006** | 0.0176 ± 0.0009**
Relative | 0.06 ± 0.00 | 0.05 ± 0.00 | 0.06 ± 0.00 | 0.06 ± 0.00 | 0.06 ± 0.00 | 0.09 ± 0.01**
R. Kidney
Absolute | 0.96 ± 0.03 | 1.01 ± 0.02 | 0.95 ± 0.02 | 1.04 ± 0.02 | 0.94 ± 0.03 | 0.86 ± 0.02*
Relative | 2.87 ± 0.04 | 2.93 ± 0.04 | 2.87 ± 0.04 | 3.22 ± 0.07** | 3.56 ± 0.09** | 4.17 ± 0.07**
Liver
Absolute | 11.87 ± 0.51 | 13.54 ± 0.40* | 14.10 ± 0.38** | 14.65 ± 0.35** | 14.40 ± 0.20** | 14.11 ± 0.70**
Relative | 35.50 ± 0.97 | 39.32 ± 0.53** | 42.61 ± 0.56** | 45.56 ± 0.84** | 54.77 ± 0.68** | 67.90 ± 1.19**
Spleen
Absolute | 0.624 ± 0.023 | 0.691 ± 0.030 | 0.622 ± 0.018 | 0.596 ± 0.020 | 0.460 ± 0.013** | 0.319 ± 0.023**
Relative | 1.87 ± 0.05 | 2.00 ± 0.05 | 1.88 ± 0.04 | 1.86 ± 0.06 | 1.75 ± 0.05 | 1.52 ± 0.06**
R. Testis
Absolute | 1.777 ± 0.057^b^ | 1.797 ± 0.048 | 1.742 ± 0.038 | 1.740 ± 0.030 | 1.695 ± 0.034 | 1.553 ± 0.062**
Thymus
Absolute | 0.393 ± 0.013 | 0.397 ± 0.010 | 0.392 ± 0.022 | 0.391 ± 0.011 | 0.221 ± 0.015** | 0.099 ± 0.014**
Relative | 1.18 ± 0.03 | 1.16 ± 0.03 | 1.18 ± 0.05 | 1.22 ± 0.03 | 0.84 ± 0.05** | 0.46 ± 0.05**
Thyroid
Absolute | 0.0239 ± 0.0012 | 0.0236 ± 0.0013 | 0.0242 ± 0.0029 | 0.0253 ± 0.0017 | 0.0268 ± 0.0012 | 0.0207 ± 0.0010
Relative | 0.07 ± 0.00 | 0.07 ± 0.00 | 0.07 ± 0.01 | 0.08 ± 0.01 | 0.10 ± 0.01** | 0.10 ± 0.00**
Female
Necropsy Body Wt. | 227 ± 4 | 237 ± 4 | 236 ± 3 | 227 ± 5.1 | 199 ± 4** | 145 ± 4**
R. Adrenal Gland
Absolute | 0.0275 ± 0.0009 | 0.0286 ± 0.0017 | 0.0277 ± 0.0015 | 0.0289 ± 0.0005 | 0.0239 ± 0.0014 | 0.0176 ± 0.0010**
Relative | 0.12 ± 0.00 | 0.12 ± 0.01 | 0.12 ± 0.01 | 0.13 ± 0.00 | 0.12 ± 0.01 | 0.12 ± 0.01
R. Kidney
Absolute | 0.68 ± 0.01 | 0.72 ± 0.01 | 0.74 ± 0.01** | 0.78 ± 0.01** | 0.72 ± 0.02 | 0.58 ± 0.01**
Relative | 3.00 ± 0.06 | 3.06 ± 0.04 | 3.15 ± 0.05 | 3.44 ± 0.06** | 3.61 ± 0.08** | 4.01 ± 0.08**
Liver
Absolute | 7.63 ± 0.28 | 8.94 ± 0.36** | 9.46 ± 0.16** | 10.06 ± 0.31** | 10.09 ± 0.18** | 9.85 ± 0.32**
Relative | 33.52 ± 0.75 | 37.66 ± 0.89** | 40.08 ± 0.56** | 44.25 ± 0.82** | 50.84 ± 0.67** | 67.75 ± 0.90**
Spleen
Absolute | 0.591 ± 0.017 | 0.596 ± 0.021 | 0.582 ± 0.021 | 0.538 ± 0.017 | 0.377 ± 0.019** | 0.264 ± 0.018**
Relative | 2.60 ± 0.04 | 2.52 ± 0.06 | 2.46 ± 0.07 | 2.36 ± 0.05* | 1.89 ± 0.06** | 1.81 ± 0.10**
Thymus
Absolute | 0.290 ± 0.016 | 0.304 ± 0.020 | 0.342 ± 0.035 | 0.316 ± 0.016 | 0.233 ± 0.017 | 0.102 ± 0.015**
Relative | 1.28 ± 0.07 | 1.29 ± 0.09 | 1.44 ± 0.14 | 1.39 ± 0.06 | 1.18 ± 0.10 | 0.69 ± 0.09**
Thyroid
Absolute | 0.0253 ± 0.0010 | 0.0288 ± 0.0019 | 0.0336 ± 0.0016** | 0.0340 ± 0.0022** | 0.0321 ± 0.0023* | 0.0236 ± 0.0012
Relative | 0.11 ± 0.00 | 0.12 ± 0.01 | 0.14 ± 0.01* | 0.15 ± 0.01** | 0.16 ± 0.01** | 0.16 ± 0.01**

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 9.

The mean relative kidney weights of males and females administered 0.625 mg/kg/day or greater were significantly greater than those of the respective vehicle control groups (Table 29). The mean absolute kidney weights of 2.5 mg/kg/day males and females were significantly less than those of the respective vehicle control groups; however, those of 0.312 and 0.625 mg/kg/day females were significantly greater.

The mean absolute spleen weight of 1.25 mg/kg/day males and the mean absolute and relative spleen weights of 2.5 mg/kg/day males were significantly less than those of the vehicle control group (Table 29). The mean relative spleen weight of 0.625 mg/kg/day females and the absolute and relative spleen weights of 1.25 and 2.5 mg/kg/day females were significantly less than those of the vehicle control group.

The mean absolute and relative thymus weights of 1.25 and 2.5 mg/kg/day males and 2.5 mg/kg/day females were significantly less than those of the respective vehicle control groups (Table 29).

The mean relative thyroid gland weights of the 1.25 and 2.5 mg/kg/day males were significantly greater than that of the vehicle control group (Table 29). The mean absolute and relative thyroid gland weights of 0.312, 0.625, and 1.25 mg/kg/day females and mean relative thyroid gland weight of 2.5 mg/kg/day females were significantly greater than those of the vehicle control group.

The mean absolute adrenal gland weights of all dosed males and 2.5 mg/kg/day females were significantly decreased compared to their respective control groups. The mean relative adrenal gland weight of 2.5 mg/kg/day males was significantly increased compared to that of the respective vehicle control group (Table 29).

The mean absolute testis weight of 2.5 mg/kg/day males was significantly less than that of the vehicle control group (Table 29).

In male and female rats, reticulocyte counts were significantly decreased in the 1.25 and 2.5 mg/kg/day dose groups, decreasing by approximately 90% in the 2.5 mg/kg/day groups compared to the respective vehicle control groups (Table 30). These decreases generally caused significant decreases in the mean cell volumes and significant increases in the mean cell hemoglobin concentrations in the same dose groups. In addition, the erythrocyte count was increased in 2.5 mg/kg/day male rats compared to the vehicle control group; the erythrocyte counts, hematocrit, and hemoglobin concentrations were significantly increased in 1.25 and 2.5 mg/kg/day females compared to the vehicle control group. The platelet count was decreased in the 2.5 mg/kg/day females compared to the vehicle control group.

Table 30 Selected Hematology and Clinical Chemistry Data for Rats in the 28-day Gavage Study of Perfluorodecanoic Acid^a^

| Vehicle Control | 0.156 mg/kg/day | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
Male
Hematology
n | 10 | 10 | 10 | 10 | 10 | 10
Erythrocytes (10^6^/μL) | 8.62 ± 0.09 | 8.72 ± 0.08 | 8.56 ± 0.08 | 8.77 ± 0.09 | 8.91 ± 0.17 | 9.78 ± 0.26**
Reticulocytes (10^3^/μL) | 152.8 ± 9.5 | 164.2 ± 6.2 | 143.3 ± 6.2 | 137.5 ± 7.0 | 69.7 ± 9.4** | 13.0 ± 3.1**
Mean Cell Volume (fL) | 60.6 ± 0.4 | 60.7 ± 0.4 | 60.3 ± 0.3 | 59.7 ± 0.5 | 58.6 ± 0.4** | 56.4 ± 0.4**
Mean Cell Hemoglobin Concentration (g/dL) | 30.3 ± 0.1 | 30.6 ± 0.1 | 30.7 ± 0.1 | 30.8 ± 0.1** | 31.1 ± 0.1** | 31.3 ± 0.2**
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 9
Urea Nitrogen (mg/dL) | 18.2 ± 0.9 | 16.5 ± 0.4 | 15.9 ± 0.4 | 19.1 ± 0.6 | 22.8 ± 0.9** | 22.8 ± 1.5*
Creatinine (mg/dL) | 0.71 ± 0.02 | 0.71 ± 0.02 | 0.74 ± 0.02 | 0.65 ± 0.02 | 0.63 ± 0.02* | 0.63 ± 0.02*
Glucose (mg/dL) | 214 ± 21 | 203 ± 17 | 252 ± 24 | 180 ± 9 | 148 ± 10.0** | 119 ± 6**
Total Protein (g/dL) | 6.4 ± 0.1 | 6.2 ± 0.1* | 6.1 ± 0.1* | 5.8 ± 0.1** | 5.3 ± 0.1** | 4.6 ± 0.1**
Albumin (g/dL) | 4.2 ± 0.0 | 4.3 ± 0.1 | 4.3 ± 0.1 | 4.2 ± 0.1 | 3.9 ± 0.1** | 3.3 ± 0.1**
Globulin (g/dL) | 2.2 ± 0.1 | 1.9 ± 0.0** | 1.8 ± 0.1** | 1.6 ± 0.1** | 1.4 ± 0.1** | 1.3 ± 0.1**
Albumin/Globulin Ratio | 1.9 ± 0.1 | 2.2 ± 0.1** | 2.5 ± 0.1** | 2.7 ± 0.2** | 2.9 ± 0.2** | 2.6 ± 0.1**
Total Bilirubin (mg/dL) | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0** | 0.6 ± 0.1**
Direct Bilirubin (mg/dL) | 0.03 ± 0.00 | 0.02 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.05 ± 0.01** | 0.23 ± 0.04**
Indirect Bilirubin (mg/dL) | 0.108 ± 0.007 | 0.120 ± 0.008 | 0.116 ± 0.006 | 0.128 ± 0.012 | 0.148 ± 0.007** | 0.383 ± 0.054**^c^
Cholesterol (mg/dL) | 107 ± 5 | 78 ± 3* | 66 ± 2** | 78 ± 2** | 94 ± 4 | 92 ± 8
Triglycerides (mg/dL) | 112 ± 10 | 128 ± 12 | 109 ± 10 | 88 ± 7 | 72 ± 6** | 53 ± 8**
Alanine Aminotransferase (IU/L) | 58 ± 4 | 70 ± 3 | 84 ± 9* | 84 ± 5** | 74 ± 6 | 62 ± 4
Alkaline Phosphatase (IU/L) | 196 ± 8 | 213 ± 10 | 240 ± 8** | 276 ± 11** | 372 ± 32** | 275 ± 18**
Aspartate Aminotransferase (IU/L) | 65 ± 3 | 74 ± 3* | 77 ± 5* | 81 ± 3** | 88 ± 5** | 93 ± 3**
Total Bile Acids (µmol/L) | 16.9 ± 3.7 | 8.0 ± 1.7 | 10.3 ± 2.0 | 23.2 ± 3.6 | 91.2 ± 11.6** | 220.8 ± 30.9**^b^
Thyroid Stimulating Hormone (ng/mL) | 19.79 ± 3.75 | 16.16 ± 1.88 | 17.73 ± 2.70 | 15.52 ± 2.50 | 11.63 ± 1.18^c^ | 8.97 ± 2.28^d^
Triiodothyronine (ng/dL) | 95.86 ± 4.01 | 72.87 ± 2.66 | 66.14 ± 2.84 | 74.74 ± 5.45 | 147.95 ± 9.69 | 179.99 ± 13.73^e^
Free Thyroxine (ng/dL) | 2.02 ± 0.21 | 1.90 ± 0.22 | 1.17 ± 0.11** | 1.13 ± 0.06** | 0.65 ± 0.05** | 0.36 ± 0.05**^e^
Total Thyroxine (µg/dL) | 4.36 ± 0.32 | 4.27 ± 0.23 | 3.24 ± 0.18* | 3.82 ± 0.09 | 4.59 ± 0.26 | 4.64 ± 0.15
Testosterone (ng/mL) | 2.59 ± 0.65 | 6.36 ± 1.69 | 3.42 ± 0.87 | 1.94 ± 0.41 | 0.93 ± 0.19* | 0.65 ± 0.26*^e^
Female
Hematology
n | 10 | 8 | 10 | 10 | 10 | 10
Hematocrit (%) | 47.7 ± 0.6 | 46.5 ± 0.6 | 46.6 ± 0.4 | 47.6 ± 0.4 | 50.5 ± 0.7* | 54.4 ± 1.3**
Manual Hematocrit (%) | 43 ± 1 | 42 ± 1 | 42 ± 0 | 43 ± 1 | 46 ± 1** | 50 ± 1**^c^
Hemoglobin (g/dL) | 14.8 ± 0.2 | 14.5 ± 0.2 | 14.5 ± 0.1 | 14.7 ± 0.1 | 15.8 ± 0.2** | 17.6 ± 0.5**
Erythrocytes (10^6^/μL) | 7.90 ± 0.09 | 7.80 ± 0.11 | 7.74 ± 0.05 | 7.91 ± 0.07 | 8.61 ± 0.16* | 9.70 ± 0.23**
Reticulocytes (10^3^/μL) | 190.3 ± 14.6 | 180.8 ± 8.6 | 183.2 ± 12.1 | 179.1 ± 11.0 | 71.6 ± 7.6** | 19.3 ± 5.3**
Mean Cell Volume (fL) | 60.4 ± 0.4 | 59.6 ± 0.3 | 60.2 ± 0.4 | 60.2 ± 0.4 | 58.7 ± 0.5* | 56.1 ± 0.5**
Mean Cell Hemoglobin Concentration (g/dL) | 31.1 ± 0.1 | 31.3 ± 0.1 | 31.2 ± 0.2 | 30.8 ± 0.1 | 31.2 ± 0.2 | 32.4 ± 0.3**
Platelets (K/µL) | 1,010 ± 36 | 1,000 ± 17 | 1,002 ± 31 | 944 ± 25 | 918 ± 23 | 706 ± 85**
Clinical Chemistry
n | 9 | 9 | 10 | 10 | 10 | 7
Urea Nitrogen (mg/dL) | 16.7 ± 0.8 | 16.0 ± 0.7 | 16.3 ± 0.6 | 18.5 ± 1.3 | 23.1 ± 0.5** | 25.0 ± 1.5**
Creatinine (mg/dL) | 0.77 ± 0.02 | 0.74 ± 0.02 | 0.73 ± 0.02 | 0.75 ± 0.02 | 0.74 ± 0.02 | 0.69 ± 0.03*
Glucose (mg/dL) | 210 ± 7 | 192 ± 9 | 187 ± 10 | 204 ± 10 | 145 ± 7** | 103 ± 8**
Total Protein (g/dL) | 6.3 ± 0.1 | 6.5 ± 0.2 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.2 ± 0.1 | 5.6 ± 0.3
Albumin (g/dL) | 4.4 ± 0.0 | 4.7 ± 0.1 | 4.9 ± 0.1** | 5.0 ± 0.1** | 4.7 ± 0.1 | 4.0 ± 0.1
Globulin (g/dL) | 1.9 ± 0.1 | 1.7 ± 0.1 | 1.5 ± 0.1** | 1.5 ± 0.1** | 1.5 ± 0.1** | 1.6 ± 0.2**
Albumin/Globulin Ratio | 2.4 ± 0.1 | 2.8 ± 0.1** | 3.2 ± 0.1** | 3.5 ± 0.1** | 3.2 ± 0.1** | 2.7 ± 0.4**
Total Bilirubin (mg/dL) | 0.1 ± 0.0^f^ | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0* | 0.6 ± 0.1**
Direct Bilirubin (mg/dL) | 0.02 ± 0.00^f^ | 0.02 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.05 ± 0.00** | 0.19 ± 0.06**
Indirect Bilirubin (mg/dL) | 0.101 ± 0.003^f^ | 0.094 ± 0.008 | 0.090 ± 0.005 | 0.087 ± 0.006 | 0.111 ± 0.004 | 0.379 ± 0.026**
Cholesterol (mg/dL) | 99 ± 4 | 100 ± 7 | 91 ± 4 | 99 ± 4 | 91 ± 5 | 65 ± 8**
Alanine Aminotransferase (IU/L) | 48 ± 3 | 47 ± 1 | 49 ± 3 | 54 ± 2 | 69 ± 4** | 57 ± 5*
Alkaline Phosphatase (IU/L) | 136 ± 6 | 156 ± 8 | 183 ± 12** | 184 ± 11** | 281 ± 23** | 262 ± 23**
Aspartate Aminotransferase (IU/L) | 63 ± 3^f^ | 60 ± 2 | 58 ± 1 | 63 ± 2 | 82 ± 3** | 113 ± 9**
Sorbitol Dehydrogenase (IU/L) | 6.4 ± 0.6 | 5.6 ± 0.8 | 5.7 ± 0.6 | 7.7 ± 0.7 | 8.6 ± 0.7 | 14.7 ± 2.2**
Creatine Kinase (IU/L) | 87 ± 4 | 82 ± 5 | 87 ± 3 | 91 ± 3 | 107 ± 5** | 158 ± 15**
Total Bile Acids (µmol/L) | 13.0 ± 3.5 | 12.2 ± 2.9 | 20.2 ± 1.9 | 17.4 ± 3.2 | 39.7 ± 7.3** | 98.6 ± 31.4**
Thyroid Stimulating Hormone (ng/mL) | 12.10 ± 0.96 | 15.44 ± 1.23 | 15.36 ± 1.21 | 12.50 ± 0.99 | 16.28 ± 2.34 | 15.42 ± 1.72^g^
Triiodothyronine (ng/dL) | 100.68 ± 8.81 | 107.27 ± 6.41 | 97.14 ± 4.51 | 106.02 ± 5.72 | 124.45 ± 10.26* | 210.61 ± 37.65**^d^
Free Thyroxine (ng/dL) | 1.78 ± 0.22 | 2.14 ± 0.19 | 2.35 ± 0.16 | 1.95 ± 0.22 | 1.093 ± 0.08* | 0.47 ± 0.02*^d^
Total Thyroxine (µg/dL) | 3.87 ± 0.35 | 4.28 ± 0.31 | 4.20 ± 0.25 | 3.92 ± 0.37 | 3.53 ± 0.21 | 4.39 ± 0.14
Testosterone (ng/mL) | 0.31 ± 0.02 | 0.36 ± 0.02 | 0.41 ± 0.03* | 0.54 ± 0.06** | 0.76 ± 0.09** | 1.41 ± 0.19**^h^

* Significantly different (p ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ n = 8.

^c^ n = 9.

^d^ n = 3.

^e^ n = 6.

^f^ n = 10.

^g^ n = 2.

^h^ n = 4.

Urea nitrogen concentrations were increased in 1.25 and 2.5 mg/kg/day males and females compared to the vehicle control groups (Table 30). Glucose concentrations were decreased in 1.25 and 2.5 mg/kg/day males and females compared to the vehicle control groups, and creatinine concentrations were significantly decreased in 1.25 mg/kg/day males and 2.5 mg/kg/day males and females; these decreases were likely related to the decreased food intake and body weight. In males, the cholesterol concentrations were decreased in all dose groups, although not to the level of significance in the two highest dose groups; the triglyceride concentrations were also significantly decreased in 1.25 and 2.5 mg/kg/day males compared to the vehicle control group. The mean cholesterol concentration was significantly decreased in 2.5 mg/kg females compared to the vehicle control group.

Significant dose-dependent decreases were observed in total protein and globulin concentrations in male rats compared to the vehicle control group (Table 30). The albumin concentrations were also significantly decreased in 1.25 and 2.5 mg/kg/day males compared to the vehicle control group; the overall effect of these changes resulted in an increase in the albumin/globulin ratio for all male dose groups. The globulin concentration was significantly decreased and the albumin/globulin ratio significantly increased in 0.312 mg/kg/day or greater females compared to the vehicle control group.

ALT, AST, and ALP activities were generally significantly increased in 0.312 mg/kg and greater males compared to the vehicle control group (Table 30). Total bilirubin and total bile acid concentrations were significantly elevated in 1.25 and 2.5 mg/kg/day males compared to the vehicle control group; the total bilirubin elevations were driven by significant increases in both direct and indirect bilirubin concentrations. ALP activity was significantly increased in 0.312 mg/kg or greater females compared to the vehicle control group. ALT and AST activities, as well as total bile acid and total bilirubin concentrations, were increased in 1.25 and 2.5 mg/kg/day females; SDH activity was significantly increased in the 2.5 mg/kg/day group. Similar to the males, the bilirubin elevations were driven by both the direct and indirect bilirubin concentrations. Creatinine kinase activity was significantly increased in 1.25 and 2.5 mg/kg/day females compared to the vehicle control group.

Free T4 concentrations were significantly decreased in 0.312 mg/kg/day and greater males and 1.25 and 2.5 mg/kg/day females compared to the respective vehicle control groups (Table 30).

Male and female rats administered PFDA exhibited a significant increase in gene expression of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2 compared to respective controls indicating a significant increase in PPARα and CAR activity (Table 31). Except for Cyp4a1 in females, genes of interest were significantly increased in males and females at all doses.

Table 31 Hepatic Parameters for Rats in the 28-day Gavage Study of Perfluorodecanoic Acid^a^

| Vehicle Control | 0.156 mg/kg/day | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
Male
n | 9 | 10 | 10 | 10 | 10 | 10
Enzyme Activity
Acetyl-CoA (nmol/min/mg) | 1.892 ± 0.051^b^ | 2.299 ± 0.055** | 4.580 ± 0.088** | 9.364 ± 0.367** | 11.856 ± 0.321** | 7.645 ± 0.335**
Gene Expression
Acox1 | 1.03 ± 0.10 | 1.70 ± 0.17** | 4.39 ± 0.39** | 6.39 ± 0.62** | 8.16 ± 0.47** | 9.34 ± 0.73**
Cyp4a1 | 1.04 ± 0.10 | 10.85 ± 1.11** | 33.46 ± 3.52** | 41.12 ± 4.19** | 62.69 ± 4.39** | 38.19 ± 3.64**
Cyp2b1 | 1.06 ± 0.21 | 3.33 ± 0.57** | 6.17 ± 0.85** | 8.24 ± 1.36** | 10.87 ± 1.50** | 4.07 ± 0.64**
Cyp2b2 | 1.00 ± 0.13 | 4.24 ± 0.52** | 5.94 ± 0.61** | 6.26 ± 0.75** | 10.91 ± 0.86** | 6.33 ± 0.96**
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Gene Expression
Acox1 | 1.06 ± 0.12 | 1.58 ± 0.12* | 2.30 ± 0.16** | 3.50 ± 0.35** | 5.46 ± 0.45** | 5.73 ± 0.67**
Cyp4a1 | 1.09 ± 0.14 | 1.42 ± 0.17 | 1.47 ± 0.18 | 3.71 ± 0.91** | 18.76 ± 1.91** | 10.17 ± 1.53**
Cyp2b1 | 1.44 ± 0.37 | 14.39 ± 4.01** | 45.16 ± 9.69** | 49.71 ± 7.67** | 128.63 ± 19.57** | 33.14 ± 5.68**
Cyp2b2 | 1.47 ± 0.42 | 12.28 ± 2.95** | 26.48 ± 3.15** | 32.89 ± 3.76** | 52.84 ± 5.30** | 16.79 ± 3.48**

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Gene expression data are presented as fold change values from the base-signal values.

^b^ n = 10.

Male rats assessed for reproductive toxicity were administered 0, 0.625, 1.25, or 2.5 mg PFDA/kg/day for 28 days, which is much less than the time needed to make a full assessment of the effect on spermatogenesis. Cauda epididymal sperm counts in rats administered 1.25 or 2.5 mg/kg/day were lower than vehicle controls (17% and 30% respectively; statistically significant at 2.5 mg/kg) and occurred in the presence of lower epididymal weights (10% and 23% respectively; statistically significant) (Table 32). Exfoliated germ cell in the duct of the epididymis was observed in four rats administered 2.5 mg/kg/day. Males administered 0.625, 1.25, or 2.5 mg/kg/day had lower serum testosterone levels (25%, 64%, and 75%; statistically significant at 1.25 and 2.5 mg/kg/day) (Table 30). Testis weight was lower in the 2.5 mg/kg/day group (11%; statistically significant). Spermatid and spermatid/g testis counts in this group were similar to the vehicle control group. Multiple histopathologic findings in the testis were noted in rats exposed to 2.5 mg/kg/day (degeneration, spermatid retention, interstitial cell atrophy; interstitial atrophy was also noted in eight rats in the 1.25 mg/kg/day group) (Table 34).

Table 32 Summary of Reproductive Tissue Evaluations for Male Rats in the 28-day Gavage Study of Perfluorodecanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy Body Wt. | 333 ± 6 | 322 ± 5 | 263 ± 4** | 207 ± 8**
L. Cauda Epididymis | 0.184 ± 0.005 | 0.178 ± 0.004 | 0.164 ± 0.006* | 0.138 ± 0.009**
L. Epididymis | 0.528 ± 0.015 | 0.508 ± 0.009 | 0.474 ± 0.013* | 0.407 ± 0.024**
L. Testis | 1.786 ± 0.060 | 1.777 ± 0.031 | 1.730 ± 0.031 | 1.594 ± 0.047**
Spermatid Measurements
Spermatid Heads (10^6^/testis) | 230.3 ± 12.5 | 208.2 ± 8.8 | 181.6 ± 10.7* | 217.0 ± 7.5
Spermatid Heads (10^6^/g testis) | 129.8 ± 7.8 | 117.0 ± 3.8 | 104.8 ± 5.6* | 137.3 ± 6.3
Epididymal Spermatozoal Measurements
Sperm Motility (%) | 85.7 ± 0.7 | 85.5 ± 1.0 | 84.1 ± 0.7 | 76.2 ± 7.8
Sperm (10^6^/cauda epididymis) | 136.3 ± 10.2 | 120.8 ± 5.5 | 112.9 ± 7.3 | 95.7 ± 11.5**
Sperm (10^6^/g cauda epididymis) | 735.9 ± 41.8 | 678.6 ± 30.6 | 687.1 ± 36.4 | 672.9 ± 78.2

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test (weights) or Shirley’s or Dunn’s test (spermatid and epididymal spermatozoal measurements).

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

Female rats administered 0, 0.625, 1.25, or 2.5 mg PFDA/kg/day were assessed for reproductive toxicity. Inspection of the daily vaginal cytology data indicated that none of the 2.5 mg/kg/day rats were cycling, (93.8% of the time in diestrus) (Table 33). Markov analyses demonstrated that rats administered 1.25 or 2.5 mg/kg/day had a higher probability than the control group of transitioning to extended diestrus from normal cycling (Table A-5; Figure A-4). Females administered 0.312 mg/kg/day or greater had significantly higher serum testosterone levels (32%, 74%, 145%, and 354%, respectively) relative to the vehicle control group (Table 30).

Table 33 Estrous Cycle Characterization for Female Rats in the 28-day Gavage Study of Perfluorodecanoic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
Number Weighed at Necropsy | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 227 ± 4 | 227 ± 5 | 199 ± 4** | 145 ± 4**
Proportion of Regular Cycling Females^b^ | 8/10 | 9/10 | 7/10 | 0/10
Estrous Cycle Length (days) | 5.3 ± 0.57 | 4.8 ± 0.14 | 5.6 ± 0.28 | 0^c^
Estrous Stages (% of cycle)
Diestrus | 57.5 | 63.1 | 73.1 | 93.8
Proestrus | 3.1 | 6.3 | 6.9 | 0.6
Estrus | 34.4 | 26.9 | 20.0 | 5.6
Metestrus | 3.1 | 3.8 | 0.0 | 0.0
Uncertain | 1.9 | 0.0 | 0.0 | 0.0

** Significantly different (p ≤ 0.01) from the vehicle control group by Dunnett’s test (body weight).

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated that 1.25 and 2.5 mg/kg/day females had extended diestrus.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ No cycles observed.

#### Pathology

The morphologic features of the lesions discussed in this section are presented in the Histopathologic Descriptions section following the Wyeth-14,643 results.

Liver: The incidences of hepatocyte cytoplasmic alteration were significantly increased in 0.625 mg/kg/day or greater males and females compared to the respective vehicle control groups (Table 34). The incidences of hepatocyte hypertrophy in 1.25 and 2.5 mg/kg/day males and females, cytoplasmic vacuolization in 1.25 and 2.5 mg/kg/day males and 2.5 mg/kg/day females, and hepatocyte, necrosis in 2.5 mg/kg/day females were significantly greater than those of the respective vehicle control groups. The severity of the hepatocellular lesions generally increased with increasing dose. Hepatocyte cytoplasmic alteration was mostly of marked severity in the 1.25 and 2.5 mg/kg/day males and minimal to mild severity in the females. Hepatocyte hypertrophy was generally of mild to marked severity in males and minimal to moderate in females. In general, hepatocyte cytoplasmic vacuolization was mostly of mild to moderate severity in males, and moderate to marked in females.

Table 34 Incidences of Selected Nonneoplastic Lesions in Rats in the 28-day Gavage Study of Perfluorodecanoic Acid

| Vehicle Control | 0.156 mg/kg/day | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
Male
Liver^a^ | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration^b^ | 0 | 0 | 0 | 10** (1.1)^c^ | 10** (4.0) | 10** (3.8)
Hepatocyte, Hypertrophy | 0 | 0 | 0 | 2 (1.5) | 10** (3.1) | 10** (4.0)
Hepatocyte, Vacuolization Cytoplasmic | 0 | 0 | 0 | 0 | 9** (1.9) | 10** (2.9)
Stomach, Forestomach | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Ulcer | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 2 (2.5)
Bone Marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hypocellularity | 0 | 0 | 0 | 0 | 0 | 10** (2.5)
Thymus | (10) | (10) | (10) | (10) | (10) | (10)
Lymphocyte, Apoptosis | 0 | 0 | 0 | 0 | 8** (1.3) | 0
Atrophy | 0 | 0 | 0 | 0 | 0 | 9** (2.8)
Testes | (10) | (10) | (10) | (10) | (10) | (10)
Interstitial Cell, Atrophy | 0 | 0 | 0 | 0 | 8** (1.6) | 10** (1.5)
Seminiferous Tubule, Spermatid Retention | 0 | 0 | 0 | 0 | 0 | 4* (2.0)
Germinal Epithelium, Degeneration | 1 (1.0) | 0 | 0 | 0 | 0 | 4 (1.8)
Epididymis | (10) | (0) | (0) | (10) | (10) | (10)
Duct, Exfoliated Germ Cell | 1 (1.0) | 0 | 0 | 0 | 0 | 4 (2.0)
Female
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration | 0 | 0 | 0 | 8** (1.0) | 10** (1.3) | 10** (1.6)
Hepatocyte, Hypertrophy | 0 | 0 | 0 | 0 | 8** (1.1) | 10** (2.9)
Hepatocyte, Vacuolization Cytoplasmic | 0 | 0 | 0 | 0 | 1 (1.0) | 10** (3.2)
Hepatocyte, Necrosis | 0 | 0 | 0 | 0 | 1 (1.0) | 4* (1.0)
Bone Marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hypocellularity | 0 | 0 | 0 | 0 | 0 | 10** (2.5)
Thymus | (10) | (10) | (10) | (10) | (10) | (10)
Atrophy | 0 | 0 | 0 | 0 | 0 | 8** (2.8)

* Significantly different (p ≤ 0.05) from the vehicle control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Bone Marrow: The incidences of bone marrow hypocellularity were significantly increased in 2.5 mg/kg/day males and females compared to the respective vehicle control groups (Table 34).

Thymus: The incidences of lymphocyte apoptosis in the thymus of 1.25 mg/kg/day males and atrophy of the thymus in 2.5 mg/kg/day males and females were significantly increased compared to the respective vehicle control groups (Table 34).

Testis and Epididymis: The incidences of interstitial cell atrophy of the testes were significantly increased in 1.25 and 2.5 mg/kg/day males compared to the vehicle control group (Table 34). The incidence of seminiferous tubule spermatid retention was significantly increased in 2.5 mg/kg/day males. The incidences of minimal germinal epithelium degeneration in the testes and epididymis, duct, exfoliated germ cells were increased in 2.5 mg/kg/day males; although these increases were not statistically significant, they may be an indication of toxicity in the testes. Germinal epithelium degeneration in the testes and in the epididymis, duct, exfoliated germ cells occurred in the same rats. The severities in three of the four rats with germinal epithelium degeneration or epididymis, duct, exfoliated germ cells were minimal or mild, and moderate or severe in the fourth rat, respectively.

Forestomach: Incidences of epithelial hyperplasia, ulcer, and inflammation in the forestomach were increased in the 2.5 mg/kg/day males compared to the vehicle control group; however, the incidences were not statistically significant (Table 34).

### Wyeth-14,643

Wyeth-14,643 (WY) was used as a positive control for PPARα agonists. In the WY study, all rats survived to scheduled euthanasia (Table 35). There were no significant treatment-related clinical observations in male or female rats. The mean body weights of dose groups of males and females were within 10% of the respective vehicle control groups throughout the study (Table 35; Figure 5).

Table 35 Mean Body Weights and Survival of Rats in the 28-day Gavage Study of Wyeth-14,643

Day | Vehicle Control | | 6.25 mg/kg/day | | | 12.5 mg/kg/day | | | 25 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 271 | 10 | 273 | 101 | 10 | 272 | 100 | 10 | 272 | 100 | 10
8 | 291 | 10 | 297 | 102 | 10 | 292 | 101 | 10 | 293 | 101 | 10
15 | 310 | 10 | 310 | 100 | 10 | 303 | 98 | 10 | 300 | 97 | 10
22 | 321 | 10 | 320 | 100 | 10 | 313 | 97 | 10 | 309 | 96 | 10
29 | 336 | 10 | 324 | 96 | 10 | 316 | 94 | 10 | 308 | 92 | 10
Female
1 | 197 | 10 | 198 | 100 | 10 | 198 | 100 | 10 | 198 | 100 | 10
8 | 204 | 10 | 208 | 102 | 10 | 208 | 102 | 10 | 209 | 102 | 10
15 | 215 | 10 | 218 | 102 | 10 | 216 | 101 | 10 | 216 | 101 | 10
22 | 220 | 10 | 224 | 102 | 10 | 225 | 103 | 10 | 224 | 102 | 10
29 | 224 | 10 | 230 | 103 | 10 | 229 | 102 | 10 | 229 | 103 | 10

Figure 5

Growth Curves for Rats Administered Wyeth-14,643 by Gavage for 28 Days

In all WY exposed male and female groups, compared to vehicle controls, there were dose-related significant increases in the absolute and relative liver and right kidney weights (Table 36). Changes in liver weights appear to correlate with histopathologic changes in the liver. Absolute heart weight in 25 mg/kg/day males and absolute spleen weight in 6.25 and 25 mg/kg/day males were significantly lower compared to those of the vehicle control group; biologic significance of these changes is not clear.

Table 36 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 10 | 10
Male
Necropsy Body Wt. | 337 ± 4 | 324 ± 5 | 316 ± 5** | 308 ± 5**
R. Kidney
Absolute | 1.00 ± 0.02 | 1.10 ± 0.04* | 1.13 ± 0.03** | 1.13 ± 0.02**
Relative | 2.98 ± 0.07 | 3.38 ± 0.08** | 3.59 ± 0.08** | 3.68 ± 0.05**
Liver
Absolute | 11.57 ± 0.21 | 15.35 ± 0.31** | 15.97 ± 0.49** | 16.56 ± 0.44**
Relative | 34.33 ± 0.49 | 47.35 ± 0.46** | 50.55 ± 1.22** | 53.90 ± 1.67**
Female
Necropsy Body Wt. | 224 ± 4 | 230 ± 4 | 229 ± 3 | 229 ± 5
R. Kidney
Absolute | 0.67 ± 0.01 | 0.74 ± 0.02** | 0.75 ± 0.02** | 0.76 ± 0.01**
Relative | 3.02 ± 0.05 | 3.22 ± 0.08* | 3.30 ± 0.09** | 3.31 ± 0.04**
Liver
Absolute | 7.32 ± 0.19 | 10.25 ± 0.27** | 11.07 ± 0.27** | 11.98 ± 0.40**
Relative | 32.78 ± 0.71 | 44.52 ± 0.90** | 48.45 ± 1.05** | 52.21 ± 1.14**

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

There were several statistically significant changes, when compared to the respective vehicle control groups, in the hematology parameters of male and female rats. These changes, however, were inconsistent across dose groups and not considered toxicologically relevant.

Blood urea nitrogen concentrations were significantly increased in all male dose groups compared to the vehicle control group (Table 37). Cholesterol concentrations were significantly decreased in all male dose groups compared to the vehicle control group. In all male dose groups, the total protein and globulin concentrations were significantly decreased, and the albumin concentrations were significantly increased compared to the vehicle control group; the combination of these changes resulted in significantly increased albumin/globulin ratios in male dose groups. In female rats, globulin concentrations were significantly decreased in all dose groups compared to the vehicle control group and total protein and albumin concentrations were significantly increased in most dose groups compared to the vehicle control group; the combination of these changes resulted in significantly increased albumin/globulin ratios in all dose groups compared to the vehicle control group. ALT, ALP, and SDH activities were significantly increased in all male dose groups compared to the vehicle control group; AST was significantly increased in 25 mg/kg/day males compared to the vehicle control group. In addition, direct bilirubin concentrations were significantly increased in 25 mg/kg/day males and total bile acid concentrations were significantly increased in all male dose groups compared to the vehicle control group. In females, ALP and SDH activities were significantly increased in all dose groups and ALT and AST activities were significantly increased in the 25 mg/kg/day group.

Table 37 Selected Clinical Chemistry Data for Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 10 | 10
Male
Urea Nitrogen (mg/dL) | 18.6 ± 0.7 | 20.2 ± 0.5* | 21.3 ± 0.5** | 23.1 ± 0.6**
Total Protein (g/dL) | 6.59 ± 0.05 | 6.24 ± 0.13* | 6.37 ± 0.05* | 6.25 ± 0.07**
Albumin (g/dL) | 4.30 ± 0.03 | 4.74 ± 0.06** | 4.78 ± 0.04** | 4.86 ± 0.09**
Globulin (g/dL) | 2.29 ± 0.03 | 1.50 ± 0.07** | 1.59 ± 0.04** | 1.39 ± 0.04**
Albumin/Globulin Ratio | 1.88 ± 0.02 | 3.22 ± 0.13** | 3.02 ± 0.08** | 3.53 ± 0.14**
Cholesterol (mg/dL) | 125.0 ± 2.7 | 106.6 ± 5.0** | 116.2 ± 4.0* | 101.8 ± 3.5**
Alanine Aminotransferase (IU/L) | 52.20 ± 1.32 | 62.80 ± 4.29* | 59.50 ± 2.36* | 62.70 ± 2.10**
Alkaline Phosphatase (IU/L) | 202.8 ± 7.5 | 286.2 ± 12.2** | 325.1 ± 14.7** | 386.5 ± 31.2**
Aspartate Aminotransferase (IU/L) | 60.00 ± 1.26 | 64.70 ± 3.45 | 62.50 ± 1.90 | 70.00 ± 3.35*
Sorbitol Dehydrogenase (IU/L) | 5.7 ± 0.4 | 9.9 ± 1.4** | 7.9 ± 0.5** | 8.4 ± 0.4**
Direct Bilirubin (mg/dL) | 0.024 ± 0.003 | 0.021 ± 0.002 | 0.025 ± 0.002 | 0.030 ± 0.002*
Total Bile Acids (µmol/L) | 11.8 ± 1.6 | 40.9 ± 6.5** | 73.1 ± 11.2** | 83.2 ± 9.5**
Total Triiodothyronine (ng/dL) | 106.350 ± 5.527 | 113.620 ± 4.208 | 102.400 ± 3.391 | 103.950 ± 4.949
Total Thyroxine (µg/dL) | 3.58 ± 0.13 | 2.90 ± 0.15** | 2.94 ± 0.20* | 2.78 ± 0.17**
Free Thyroxine (ng/dL) | 2.35 ± 0.09 | 1.43 ± 0.13** | 1.41 ± 0.14** | 1.31 ± 0.13**
Thyroid Stimulating Hormone (ng/mL) | 18.56 ± 1.16 | 21.46 ± 3.59 | 15.64 ± 2.13 | 13.07 ± 1.01*
Testosterone (ng/mL) | 4.03 ± 0.48 | 3.14 ± 0.91 | 4.37 ± 1.29 | 1.56 ± 0.39*
Female
Total Protein (g/dL) | 6.37 ± 0.08 | 6.54 ± 0.05 | 6.85 ± 0.12** | 6.85 ± 0.08**
Albumin (g/dL) | 4.46 ± 0.05 | 5.03 ± 0.05** | 5.20 ± 0.08** | 5.20 ± 0.05**
Globulin (g/dL) | 1.91 ± 0.05 | 1.51 ± 0.04** | 1.65 ± 0.05* | 1.65 ± 0.05*
Albumin/Globulin Ratio | 2.34 ± 0.05 | 3.35 ± 0.10** | 3.17 ± 0.08** | 3.17 ± 0.09**
Alanine Aminotransferase (IU/L) | 41.80 ± 1.24 | 49.50 ± 3.85 | 46.80 ± 1.85 | 54.80 ± 2.58**
Alkaline Phosphatase (IU/L) | 142.6 ± 6.9 | 181.7 ± 10.2** | 179.2 ± 5.4** | 217.3 ± 11.4**
Aspartate Aminotransferase (IU/L) | 55.30 ± 1.08 | 64.70 ± 8.15 | 56.50 ± 1.70 | 61.90 ± 1.55*
Sorbitol Dehydrogenase (IU/L) | 4.2 ± 0.5 | 9.9 ± 2.4** | 7.7 ± 0.7** | 8.3 ± 0.6**
Total Triiodothyronine (ng/dL) | 65.66 ± 2.47 | 71.86 ± 4.312 | 83.09 ± 4.79** | 83.57 ± 3.72**
Total Thyroxine (µg/dL) | 1.790 ± 0.126 | 1.990 ± 0.164 | 2.280 ± 0.146 | 1.700 ± 0.116
Free Thyroxine (ng/dL) | 1.134 ± 0.082 | 1.444 ± 0.102 | 1.671 ± 0.136** | 1.338 ± 0.093
Thyroid Stimulating Hormone (ng/mL) | 10.07 ± 0.51^b^ | 16.19 ± 2.03** | 14.96 ± 1.71** | 17.21 ± 1.25**
Testosterone (ng/mL) | 0.33 ± 0.03 | 0.52 ± 0.07* | 0.49 ± 0.06 | 0.57 ± 0.08*

* Significantly different (p ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ n = 9

Free T4 and total T4 concentrations were significantly decreased in all male dose groups compared to the vehicle control group, and TSH was significantly decreased in the 25 mg/kg/day group compared to the vehicle control group (Table 37). Additionally, testosterone concentrations were significantly decreased in 25 mg/kg/day males compared to the vehicle control group. In females, T3 and TSH concentrations were significantly increased in most dose groups compared to the vehicle control group, and testosterone concentrations were significantly increased at 6.25 and 25 mg/kg/day compared to the vehicle control group. Free T4 was significantly increased in the 12.5 mg/kg/day females; the relevance of this change was not certain and may have been due to biological variability.

There were significant increases in expression of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2 compared to controls indicating significantly increased PPARα and CAR activities in treated male and female rats. Males displayed a greater fold increase in Cyp4a1 expression compared to controls than did females compared to their controls, whereas CAR increases compared to controls were more prominent in females than in males (Table 38). Acyl-CoA oxidase activity was increased in male rats at all dose levels.

Table 38 Hepatic Parameters for Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 10 | 10
Male
Enzyme Activity
Acyl-CoA Oxidase (nmol/min/mg) | 2.028 ± 0.044 | 11.731 ± 0.692** | 14.560 ± 1.027** | 17.370 ± 0.592**
Gene Expression
Acox1 | 1.05 ± 0.10 | 3.54 ± 0.60** | 4.77 ± 0.55** | 6.86 ± 0.44**
Cyp4a1 | 1.06 ± 0.10 | 29.92 ± 4.63** | 33.96 ± 2.45** | 45.82 ± 3.31**
Cyp2b1 | 1.21 ± 0.21 | 3.77 ± 0.94** | 3.69 ± 0.67** | 4.45 ± 0.95**
Cyp2b2 | 1.27 ± 0.28 | 2.32 ± 0.23** | 1.93 ± 0.20* | 2.43 ± 0.19**
Female
Gene Expression
Acox1 | 1.01 ± 0.05 | 3.11 ± 0.26** | 4.08 ± 0.27** | 5.65 ± 0.49**
Cyp4a1 | 1.02 ± 0.07 | 2.90 ± 0.52** | 3.85 ± 1.12** | 7.26 ± 1.22**
Cyp2b1 | 1.18 ± 0.24 | 24.05 ± 4.59** | 28.82 ± 3.36** | 38.79 ± 4.74**
Cyp2b2 | 1.18 ± 0.21 | 19.59 ± 2.67** | 29.41 ± 1.48** | 30.41 ± 3.22**

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Gene expression data are presented as fold change values from the base-signal values.

Male rats administered 6.25, 12.5, or 25 mg/kg/day for 28 days displayed lower testicular spermatid counts (9%, 14%, and 13%, respectively) relative to vehicle controls (Table 39). When normalized to total testicular weight, counts were slightly lower in the dose groups, with the 12.5 and 25 mg/kg/day groups exhibiting lower (11% and 10%) counts relative to the vehicle control group. These differences did not attain statistical significance, but the trend was significant. WY administration did not affect motility or testis weight. Cauda epididymal sperm counts (both total and normalized to total weight) were generally lower (22% to 25%) in the dosed rats; however, none of these changes attained statistical significance. Epididymis weights in treated males were 10% to 12% lower than vehicle controls with the observed decrease in 25 mg/kg/day males attaining statistical significance. The trend test was also significant. One rat in the 25 mg/kg/day group displayed histopathologic findings in the testis (germinal epithelium degeneration) and epididymis (duct, exfoliated germ cell) (Table 41). Testosterone measured at time of necropsy was significantly lower (61%) in the 25 mg/kg/day group (positive trend test) (Table 37).

Table 39 Summary of Reproductive Tissue Evaluations for Male Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy Body Wt. | 337 ± 4 | 324 ± 5 | 316 ± 5 | 308 ± 5**
L. Cauda Epididymis | 0.230 ± 0.035** | 0.197 ± 0.007 | 0.188 ± 0.004 | 0.179 ± 0.006
L. Epididymis | 0.584 ± 0.037* | 0.519 ± 0.008 | 0.524 ± 0.012 | 0.512 ± 0.011*
L. Testis | 1.840 ± 0.029 | 1.786 ± 0.040 | 1.780 ± 0.043 | 1.774 ± 0.036
Spermatid Measurements
Spermatid Heads (10^6^/testis) | 294.3 ± 13.6 | 269.2 ± 13.7 | 253.9 ± 13.7 | 255.8 ± 11.5
Spermatid Heads (10^6^/g testis) | 159.8 ± 6.3* | 150.7 ± 6.9 | 141.9 ± 4.8 | 144.4 ± 6.4
Epididymal Spermatozoal Measurements
Sperm Motility (%) | 88.5 ± 0.5 | 87.9 ± 0.3 | 87.9 ± 0.3 | 88.2 ± 0.5
Sperm (10^6^/g cauda epididymis) | 148.4 ± 17.4 | 111.0 ± 8.2 | 115.3 ± 7.8 | 116.3 ± 8.4
Sperm (10^6^/cauda epididymis) | 671 ± 46 | 562 ± 31 | 616 ± 44 | 643 ± 33

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group were analyzed for significance by Williams’ or Dunnett’s test (cauda epididymis and testis weights) or Shirley’s or Dunn’s test (spermatid and epididymal spermatozoal measurements). A Jonckheere trend test was performed on each endpoint.

Dosed female rats displayed similar amounts of time in each respective estrous stage compared to control (Table 40, Figure A-5). However, Markov analyses demonstrated that females administered WY displayed alterations in the estrous cycle (extended diestrus was significantly higher in all dose groups) (Table 40 and Table A-6). Under the conditions of this study, these data indicate that WY via oral gavage exhibits the potential to be a reproductive toxicant in female Sprague Dawley rats on the basis of altered estrus cyclicity (extended diestrus).

Table 40 Estrous Cycle Characterization for Female Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 9 | 10
Necropsy Body Wt. (g) | 224 ± 4 | 230 ± 4 | 229 ± 3^b^ | 229 ± 5
Number of Estrus Cycles | 2.0 ± 0.15 | 2.0 ± 0.00 | 1.9 ± 0.11 | 1.8 ± 0.13
Estrous Cycle Length (days) | 5.0 ± 0.16 | 5.0 ± 0.09 | 4.8 ± 0.26 | 5.1 ± 0.16
Estrous Stages (% of cycle)
Diestrus | 55.6 | 61.9 | 58.1 | 61.9
Proestrus | 4.4 | 3.8 | 12.5 | 6.3
Estrus | 38.1 | 32.5 | 25.6 | 28.8
Metestrus | 1.9 | 1.9 | 3.1 | 3.1
Uncertain diagnosis | 0.0 | 0.0 | 0.6 | 0.0

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated that dosed females spent significantly more time in extended diestrus (p = 0.009 or less) than did the vehicle control group.

^b^ n = 10.

#### Pathology

The morphologic features of the lesions discussed in this section are presented in the Histopathologic Descriptions section following these results.

Liver: The incidences of hepatocyte hypertrophy were significantly increased in all dose groups of males and in 25 mg/kg/day females (Table 41). Hepatocyte hypertrophy was generally of minimal to mild severity in males and minimal in females. The average severity increased with increasing dose in males. The incidences of hepatocyte cytoplasmic alteration were significantly increased in all dose groups of males and females, and the lesion was generally of minimal to marked severity in males and minimal to mild in females. The average severity increased with increasing dose.

Table 41 Incidences of Nonneoplastic Lesions in Rats in the 28-day Gavage Study of Wyeth-14,643

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
Male
Liver^a^ | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration^b^ | 0 | 9** (1.7)^c^ | 10** (2.2) | 10** (4.0)
Hepatocyte, Hypertrophy | 0 | 5* (1.4) | 10** (1.5) | 10** (2.0)
Testes | (10) | (10) | (10) | (10)
Germinal Epithelium, Degeneration | 0 | 0 | 0 | 1 (2.0)
Epididymis | (10) | (0) | (10) | (10)
Duct, Exfoliated Germ Cell | 0 | 0 | 0 | 1 (1.0)
Female
Liver | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration | 0 | 7** (1.0) | 10** (1.2) | 10** (1.9)
Hepatocyte, Hypertrophy | 0 | 0 | 2 (1.0) | 8** (1.1)

* Significantly different (p ≤ 0.05) from the vehicle control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

### Histopathologic Descriptions for PFHxA, PFOA, PFNA, PFDA, and WY

The treatment-related lesions in the liver, nose, bone marrow, spleen, thymus, mandibular and mesenteric lymph nodes, testes and epididymis, thyroid gland, and forestomach were generally morphologically similar across the studies in which they occurred; however, the severities of the lesions varied among studies.

Liver: Figure 6 and Figure 7 show the normal histological morphology of the liver. Hepatocyte cytoplasmic alteration was generally of minimal to marked severity characterized by an accumulation of eosinophilic granules within the cytoplasm of centrilobular hepatocytes (Figure 8 and Figure 9). A grade of minimal (Grade 1) was used when eosinophilic granules were present within occasional centrilobular hepatocytes (up to 10% of the liver involved); mild (Grade 2) when 10% to 33% of the liver was involved with most or all centrilobular zones affected; moderate (Grade 3) when 33% to 67% of the liver was involved with widespread centrilobular and midzonal hepatocytes affected; and marked (Grade 4) when greater than 67% of the liver was involved.

Figure 6

Normal Liver of a Male Vehicle Control Rat in the 28-day Gavage Toxicity Study of Perfluorononanoic Acid (H&E)

Central veins (arrows).

Figure 7

Higher Magnification of Figure 6 (H&E)

Figure 8

Centrilobular Areas of Cytoplasmic Alteration (Arrows) in a Male Rat Administered Perfluorononanoic Acid 2.5 mg/kg/day by Gavage for 28 Days (H&E)

Figure 9

Higher Magnification of Figure 8 (H&E)

Hepatocyte Cytoplasmic alteration is characterized by enlarged centrilobular hepatocytes that contain granular eosinophilic cytoplasm (arrows).

Hepatocyte hypertrophy was generally of minimal to marked severity characterized by an increase in the size of primarily centrilobular hepatocytes due to an accumulation of cytoplasmic granules or an increase in homogenous eosinophilic cytoplasm in the absence of distinct eosinophilic cytoplasmic granules (Figure 10 and Figure 11). Hepatocyte hypertrophy was graded as minimal (Grade 1) when hepatocytes were enlarged in occasional lobules (up to 10% of the liver involved); mild (Grade 2) when 10% to 33% of the liver was involved; moderate (Grade 3) when 33% to 67% of the liver was involved; and marked (Grade 4) when greater than 67% of the liver was involved.

Figure 10

Hepatocyte Hypertrophy in a Male Rat Administered Perfluorobutane Sulfonic Acid 2.5 mg/kg/day by Gavage for 28 Days (H&E)

Figure 11

Higher Magnification of Figure 10 (H&E)

Centrilobular hepatocytes are enlarged (arrows) but lack cytoplasmic granules.

Hepatocyte cytoplasmic vacuolization was generally of mild to marked severity in males and moderate to marked in females; it was largely centrilobular in distribution and characterized by accumulation of microvacuoles within the cytoplasm (Figure 12). Hepatocyte cytoplasmic vacuolization was graded as minimal (Grade 1) when cytoplasmic vacuolization was present within occasional centrilobular hepatocytes (with up to 10% of the liver involved); mild (Grade 2) when 10% to 33% of the liver was involved with most or all centrilobular zones affected; moderate (Grade 3) when 33% to 67% of the liver was involved with widespread centrilobular and midzonal hepatocytes affected; and marked (Grade 4) when greater than 67% of the liver was involved.

Figure 12

Hepatocyte Cytoplasmic Vacuolation in a Male Rat Administered Perfluorononanoic Acid 2.5 mg/kg/day by Gavage for 28 Days (H&E)

Note clear vacuoles (arrows) within the hepatocytes.

In all cases, hepatocyte necrosis was of minimal severity and consisted of a few widely scattered, variably sized, randomly distributed foci of necrotic hepatocytes within the hepatic parenchyma, mixed with variable numbers of mononuclear inflammatory cells.

Nose: Compared to normal respiratory epithelium (Figure 13), respiratory epithelium hyperplasia was characterized by increased numbers of basal and nonciliated cuboidal to columnar epithelial cells of the mucosal respiratory epithelium primarily lining the nasal septum and terminates of Level I (Figure 14). The cell layers were frequently disorganized and often associated with chronic active inflammation. A grade of minimal (Grade 1) was assigned when respiratory epithelium hyperplasia was present as one to several foci on one or both sides of the nasal septum or a few small areas on the tips of the nasal turbinates and mild (Grade 2) when one entire side or both sides of the nasal septum were involved or, less commonly, the hyperplasia was primarily on the surface of multiple turbinates with little or no septum involvement. Moderate (Grade 3) hyperplasia was diagnosed when the hyperplasia involved the majority of the nasal septum epithelium and up to 50% of the surface of the turbinates.

Figure 13

Normal Respiratory Epithelium in the Nose of a Female Vehicle Control Rat in the 28-day Gavage Toxicity Study of Perfluorooctanoic Acid (H&E)

The epithelium lining the turbinates is composed of a single layer of tall columnar, ciliated epithelial cells (arrows). The epithelium lining the nasal septum is composed of a single layer of tall columnar epithelial cells (arrowheads), which contain clear goblet cells within the cytoplasm. NS = nasal septum.

Figure 14

Respiratory Epithelium Hyperplasia and Chronic Active Inflammation in the Nose of a Female Rat Administered Perfluorooctanoic Acid 100 mg/kg/day by Gavage for 28 Days (H&E)

Respiratory epithelium hyperplasia is characterized by disorganization of the epithelium and increased numbers of epithelial cells including basal epithelial cells (long arrows). There is also focal proliferation of goblet cells (short arrows). Chronic active inflammation consists of a mixture of mononuclear inflammatory cells and neutrophils in the submucosa (asterisks). NS = nasal septum.

Chronic active inflammation of the respiratory epithelium generally occurred concurrently with respiratory epithelium hyperplasia and consisted of a mixed population of primarily mononuclear inflammatory cells (mostly lymphocytes) and lesser numbers of neutrophils within the lamina propria beneath the mucosal respiratory epithelium of the nasal turbinates (Figure 14). Neutrophils were also noted migrating from the lamina propria into the overlying respiratory epithelium. A grade of minimal (Grade 1) was used when a few foci of inflammatory cells were noted in propria beneath the septum or a few areas in the tips of turbinates; mild (Grade 2) when inflammatory cells were noted along the majority of the nasal septum propria and migrating into the overlying respiratory epithelium; and moderate (Grade 3) when inflammatory cells were noted in the majority of the nasal septum and in multiple turbinates with migration into the overlying respiratory epithelium.

Compared to normal olfactory epithelium (Figure 15), olfactory epithelium, degeneration was characterized by segmental decreased nuclear density and decreased height of the olfactory epithelium due to loss of the olfactory epithelial cells (Figure 16). In the affected segments, the remaining epithelial cells had lost the surface cilia/microvillus border and contained cytoplasmic vacuoles, and there were scattered pyknotic cell nuclei within the epithelium. Olfactory epithelium, degeneration was diagnosed as minimal (Grade 1) when epithelium on up to 25% of the nasal turbinates was affected; mild (Grade 2) when epithelium on 25% to 50% of the nasal turbinates was affected; moderate (Grade 3) when epithelium on 50% to 75% of the nasal turbinates was affected; and marked (Grade 4) when epithelium on greater than 75% of the nasal turbinates was affected.

Figure 15

Normal Olfactory Epithelium in the Nose of a Female Vehicle Control Rat in the 28-day Gavage Toxicity Study of Perfluorooctanoic Acid (H&E)

The epithelium (arrows) lining the turbinates and nasal septum is pseudostratified and has a prominent brush border. Note prominent olfactory nerve bundles (asterisks) within the submucosa. NS = nasal septum.

Figure 16

Olfactory Epithelium, Degeneration, Hyperplasia, and Suppurative Inflammation in a Female Rat Administered Perfluorooctanoic Acid 100 mg/kg/day by Gavage for 28 Days (H&E)

Epithelial degeneration (arrows) is characterized by disorganization of the epithelium, decreased density of epithelial cells, degenerate cells within the epithelium, and loss of the surface microvilli. Epithelial hyperplasia (square) is characterized by disorganized proliferation of the olfactory epithelial cells. Suppurative inflammation consists of accumulations of neutrophils and a pale fibrinous exudate within the nasal passages (asterisks).

Olfactory epithelium, hyperplasia was of minimal to mild severity and was characterized by multifocal to linear areas of proliferation and piling up of the olfactory epithelial cells resulting in disorganization and increased thickness of the epithelium (Figure 16). In some affected segments, there were focal proliferations of basal epithelial cells extending into the underlying propria effacing the normally distinct border between olfactory epithelium and the underlying lamina propria. A grade of minimal (Grade 1) was used when less than 15% of the olfactory epithelium in Level III was involved and mild (Grade 2) when greater than or equal to 16% to 50% of the Level III olfactory epithelium was hyperplastic.

Olfactory epithelium, suppurative inflammation was of minimal to moderate severity and was characterized by aggregates of neutrophils and cellular debris within the nasal passages and within the epithelium and lamina propria of the ethmoid turbinates (Figure 16). A grade of minimal (Grade 1) was used when up to 25% of the nasal cavity lumen contained free neutrophils; mild (Grade 2) when 25% up to 50% of the nasal cavity lumen contained free neutrophils; moderate (Grade 3) when 50% up to 75% of the nasal cavity lumen contained free neutrophils; and marked (Grade 4) when 75% or greater of the nasal cavity contained free neutrophils.

Bone Marrow: Hypocellularity was minimal to marked in severity and was characterized by a decrease in both erythroid and myeloid cell lines and a corresponding increase in fat cells in the marrow. Minimal (Grade 1) hypocellularity was diagnosed when the bone marrow contained approximately 10% to 15% more adipocytes and a corresponding fewer number of hematopoietic cells than concurrent vehicle controls. Mild (Grade 2) hypocellularity was diagnosed when the bone marrow contained greater than 15% to 30% more adipocytes and a corresponding fewer number of hematopoietic cells than concurrent vehicle controls.

Spleen and Mandibular and Mesenteric Lymph Nodes: Compared to the normal spleen (Figure 17) and lymph node (Figure 19), atrophy was characterized by regional reduction in the number of lymphocytes within the splenic white pulp (Figure 18) and generalized decrease in the number of lymphocytes within the lymph nodes (Figure 20). The severity of atrophy was diagnosed as minimal (Grade 1) when there was up to a 25% reduction in mandibular lymph node lymphocyte number; mild (Grade 2) when there was a 26% to 50% reduction in mandibular lymph node lymphocyte number; moderate (Grade 3) when there was a 51% to 75% reduction in mandibular lymph node lymphocyte number; and marked (Grade 4) when there was over a 75% reduction in mandibular lymph node lymphocyte number.

Figure 17

Normal Spleen of a Male Vehicle Control Rat in the 28-day Gavage Toxicity Study of Perfluorononanoic Acid (H&E)

Figure 18

Atrophy in the Spleen of a Male Rat Administered Perfluorononanoic Acid 5 mg/kg/day (H&E)

Atrophy is characterized by a generalized decrease in the number of lymphocytes throughout the red and white pulp.

Figure 20

Atrophy in the Mesenteric Lymph Node of a Male Rat Administered Perfluorononanoic Acid 5 mg/kg/day (H&E)

Atrophy is characterized by a generalized decrease in the number of lymphocytes within the lymphoid follicles

Increased extramedullary hematopoiesis in the spleen was generally of minimal to mild severity and diagnosed when hematopoietic cells, largely of the erythroid lineage, were present within the splenic red pulp in excess of numbers normally present in the red pulp. The hematopoietic cells occurred as variably sized discrete clusters distributed diffusely throughout the red pulp. Extramedullary hematopoietic cell proliferation was graded as minimal (Grade 1) when approximately 25% of the splenic red pulp contained excess hematopoietic cells; mild (Grade 2) when 26% to 50% of the splenic red pulp contained excess hematopoietic cells; moderate (Grade 3) when 51% to 75% of the splenic red pulp contained excess hematopoietic cells; and marked (Grade 4) when greater than 75% of the splenic red pulp contained excess hematopoietic cells.

Thymus: Lymphocyte apoptosis was of mostly minimal severity characterized by an increased number of shrunken cells with dark nuclei and was diagnosed when ≤15% of the cortical lymphocytes were apoptotic.

Atrophy was of minimal to marked severity among dosed rats but was mostly marked in males and females. Compared to the normal thymus (Figure 21), atrophy was characterized by a decrease in the thickness of the thymic cortex considered to be due to a decrease in the number of cortical lymphocytes (Figure 22). Atrophy was diagnosed as minimal (Grade 1) when there was up to a 25% reduction in the cortex; mild (Grade 2) when there was a 26% to 50% reduction of the cortex; moderate (Grade 3) when there was a 51% to 75% reduction of the cortex; and marked (Grade 4) when there was over a 75% reduction in the cortex and loss of the corticomedullary junction. Increased tingible body macrophages that contained apoptotic bodies were scattered among the thymic lymphocytes.

Figure 21

Normal Thymus of a Male Vehicle Control Rat in the 28-day Gavage Toxicity Study of Perfluorononanoic Acid (H&E)

Cortex (arrows).

Figure 22

Atrophy in the Thymus of a Male Rat Administered Perfluorodecanoic Acid 2.5 mg/kg/day by Gavage for 28 Days (H&E)

Atrophy is characterized by a generalized decrease in the number of cortical lymphocytes (arrows).

Testes and Epididymis: Normal histology of a seminiferous tubule of the testis is shown in Figure 23. Interstitial cell atrophy of the testes was of minimal to marked severity characterized by decreased numbers of interstitial cells; affected cells also seemingly had decreased amounts of cytoplasm (Figure 24). A minimal severity grade (Grade 1) was assigned when less than 25% of the interstitial cells had decreased amounts of cytoplasm; mild (Grade 2) when there was a decrease in cytoplasm of 26% to 50%; moderate (Grade 3) when there was a 51% to 75% decrease in cytoplasm accompanied by an approximate decrease in cell numbers by up to 30%; and marked (Grade 4) when almost no cytoplasm could be visualized around interstitial cell nuclei and numbers of interstitial cells had decreased by approximately 31% to 60%.

Figure 23

Normal Testis of a Male Vehicle Control Rat in the 28-day Gavage Toxicity Study of Perfluorononanoic Acid (H&E)

Note normal germinal epithelium with typical residual bodies observed in this stage VIII seminiferous tubule (upper left). Also note plump cytoplasm of the interstitial (Leydig) cells (triangle).

Figure 24

Interstitial Cell Atrophy and Degeneration in the Testis of a Male Rat Administered Perfluorononanoic Acid 10 mg/kg/day (H&E)

Compared to Figure 23, atrophic interstitial cells are shrunken and have scant cytoplasm. Also note degeneration characterized by decreased tubular diameters, depletion of germ cells in all tubules, and the multinucleated giant cell. Magnification and triangle size are the same as in Figure 23.

Seminiferous tubule spermatid retention was of minimal to marked severity characterized by either retained spermatids at the surface of the germinal epithelium and/or retained spermatid heads at the basement membrane of the germinal epithelium of Stage IX through Stage XIV tubules (Figure 25). A severity grade of minimal (Grade 1) was assigned if greater than three retained spermatids (combined surface or heads at the basement membrane) were noted in over seven tubules; mild (Grade 2) when greater than 50% of the late stage tubules had greater than three retained spermatids; and moderate (Grade 3) when retention at the surface or basement membrane could be noted at low power and involved the majority of the late stage tubules (although not all spermatids being produced by the testes were retained).

Figure 25

Testis of a Male Rat Administered Perfluorononanoic Acid 10 mg/kg/day for 28 Days (H&E)

Note retained spermatid heads at the basement membrane (rectangles) and surface (square) of the germinal epithelium of a Stage 10 seminiferous tubule.

Germinal epithelium degeneration in the testes was of minimal to marked severity characterized by loss of elongating spermatids in late stage tubules; cell-to-cell disassociation; vacuolization of Sertoli cells; pyknotic pachytene, diplotene, and meiotic spermatocytes; focal areas of cell drop out; multinucleated giant cells; loss of spermatogonia; vacuolated nuclei of round spermatids; loss of round spermatids in early stages; and residual bodies in the tubular lumens (Figure 24, Figure 25, Figure 26, and Figure 27). Germinal epithelial degeneration was graded as minimal (Grade 1) when the primary finding was increased residual bodies in lumens of tubules; mild (Grade 2) was characterized by increased residual bodies in tubular lumens, decreased elongating spermatids in late stages, and necrotic pachytene spermatocytes; moderate (Grade 3) was used when many or all of the above findings listed for degeneration were noted and involved up to 67% of the tubules; and marked (Grade 4) was used when greater than 67% of tubules were affected.

Figure 26

Marked Degeneration in the Testis of a Male Rat Administered Perfluorononanoic Acid 2.5 mg/kg/day for 28 Days (H&E)

Note that all seminiferous tubules in the section are affected. The primary changes are disorganization of the germinal epithelium, significant exfoliation, and loss of germinal epithelial cells. Also, note Sertoli cell vacuolation and the presence of numerous atypical residual bodies, apoptotic cells, and multinucleate cells.

Figure 27

Degeneration in the Testis of a Male Rat Administered Perfluorononanoic Acid 2.5 mg/kg/day (H&E)

Note the atypical residual bodies (long arrow) and the apoptotic pachytene spermatocyte (short arrow) in a Stage VIII seminiferous tubule. The residual bodies are larger than the typical residual bodies in the Stage VIII tubule in the control testis shown in Figure 23.

Normal histology of the epididymis is shown in Figure 28. Epididymis, duct, exfoliated germ cells was of mild to marked severity characterized by sloughed germinal epithelial cells and cytoplasmic debris, including residual bodies, in some cases, in the lumen of the duct of the epididymis (Figure 29). A minimal severity grade (Grade 1) was used when the average of the five largest profiles in the cauda of the epididymis contained 5 to 12 exfoliated germ cells or bits of cellular debris, mild (Grade 2) was used when the average was 13 to 25, moderate (Grade 3) was used when the average was greater than 25 but less than marked (Grade 4), which was used when the lumen of the duct was almost completely filled with sloughed cells and cytoplasmic debris.

Figure 28

Normal Epididymis of a Male Vehicle Control Rat in the 28-day Gavage Toxicity Study of Perfluorononanoic Acid (H&E)

Epididymal duct is lined by a single row of columnar epithelial cells (arrows) and contain tangled masses of mature spermatozoa (asterisks).

Figure 29

Exfoliated Germ Cells and Hypospermia in the Epididymal Duct of a Male Rat Administered Perfluorononanoic Acid 10 mg/kg/day for 28 Days (H&E)

Note that the epididymal duct from cauda epididymis is filled mostly with exfoliated germinal epithelial and apoptotic cells mixed with low numbers of mature spermatozoa (hypospermia).

Epididymis hypospermia was of mild to marked severity characterized by decreased sperm within the duct of the epididymis (Figure 29 and Figure 30). An estimate of the decrease was made by a semiquantitative and qualitative assessment of the duct, particularly the cauda portion, for density of the sperm within the duct and the degree of distension of the duct lumen as the lumen tends to become decreased in diameter with less sperm. Degree of decrease in lumen diameter with hypospermia was not recorded separately. A minimal severity grade (Grade 1) was used when the duct only contained a slight decrease in sperm density and a slight decrease in duct diameter compared to concurrent vehicle controls.

Figure 30

Apoptosis in the Head of the Epididymis of a Male Rat Administered Perfluorononanoic Acid 10 mg/kg/day for 28 Days (H&E)

Note numerous apoptotic cells (arrows) in the epithelium of the seminiferous tubules.

Epididymis, epithelium apoptosis occurred primarily in the head of the epididymis with extension into the body where this change was most prominent (Figure 30). Apoptosis consisted of shrunken, hypereosinophilic cells with fragmented pyknotic nuclei within the epithelium of the ducts. Apoptosis was graded as minimal (Grade 1) if only scattered cells in the epithelium of the head were affected; mild (Grade 2) when up to 30% of the cells were affected; and moderate (Grade 3) when greater than 30% of the cells were affected with extension into the body of the epididymis.

Epididymis sperm granuloma was of mild severity characterized as a focal aggregated mass of spermatozoa in the interstitial tissue around the epididymal duct (Figure 31 and Figure 32). The mass of spermatozoa was mixed with neutrophils and necrotic cell debris and, in some areas, surrounded by fibrous tissue and inflammatory cells, primarily macrophages and neutrophils and with lesser numbers of lymphocytes.

Figure 31

Sperm Granuloma in a Male Rat Administered Perfluorononanoic Acid 10 mg/kg/day (H&E)

The granuloma occurs as a discrete mass within the interstitium of the epididymis (arrows).

Figure 32

Higher Magnification of Figure 31 (H&E)

Sperm granuloma consists of a mass of tangled spermatozoa mixed with necrotic cell debris, inflammatory cells (macrophages, neutrophils, and lymphocytes) bordered by fibrous tissue.

Thyroid Gland: Follicle cell hypertrophy was of minimal severity characterized by enlarged follicle cells approximately twice as tall as normal and frequently with a vacuolated pale amphophilic cytoplasm. Minimal (Grade 1) hypertrophy was used when the number of enlarged follicular cells was less than 15% of the total number of cells involved, and the affected cells were generally no taller than twice the height of follicular cells in concurrent vehicle controls.

Forestomach: Epithelial hyperplasia of the forestomach mucosa was characterized by a focal area of increased cell numbers resulting in an increased thickness and folding of the mucosa. The epithelial cells maintained normal orientation, and atypia was not noted.

Inflammation chronic was diagnosed as mild (Grade 2) when infiltrates of lymphocytes and plasma cells were randomly scattered in the submucosal lamina propria.

## Genetic Toxicology

The four perfluoroalkyl carboxylates were tested in assays that measure the potential for induction of mutations in bacteria (Salmonella typhimurium strains TA100 and TA98 and Escherichia coli strain WP2 uvrA pKM101) and chromosomal damage in erythrocyte precursor cells in the bone marrow of male and female Sprague Dawley rats. Although the damage is induced in the erythroblast population in the bone marrow, it is measured as micronuclei in immature red blood cells (reticulocytes, RET; polychromatic erythrocytes, PCEs) in peripheral blood.

PFHxA was negative in bacterial mutagenicity assays with and without 10% rat liver S9; it was tested at doses up to 750 µg/plate in TA100 and TA98 and up to 2,000 µg/plate in the E. coli strain in the absence of S9 (Table B-1). With S9, all strains were tested up to the assay limit of 10,000 µg/plate.

No increases in micronucleated reticulocytes were seen in peripheral blood of female rats administered PFHxA by two daily gavage treatments (31.3 to 500 mg/kg twice daily) for 28 days; however, the percentage of circulating immature erythrocytes (% PCEs) was markedly increased over the dose range in both sexes, suggesting a stimulation of erythropoiesis in the bone marrow of PFHxA-treated rats (Table B-5). An increase in micronucleated reticulocytes occurred at the top dose administered to male rats. Although this increase was not significant, it produced a significant trend test. The results for male rats were considered to be negative due to the very high stimulation of erythropoiesis at this dose.

PFOA was equivocal in bacterial mutagenicity assays using strain TA 98 without 10% rat liver S9 and negative in bacterial mutagenicity assays using TA 100 and E. coli with and without 10% rat liver S9, and in TA 98 with S9; it was tested at doses up to 1,000 µg/plate in all three strains in the absence of S9 (Table B-2). PFOA was tested at doses up to 5,000 µg/plate with S9 in TA100 and TA98 and 10,000 µg/plate in the E. coli strain.

No increases in micronucleated reticulocytes were seen in peripheral blood of female rats administered PFOA (6.25 to 100 mg/kg/day) by gavage once daily for 28 days (Table B-6). A statistically significant increase in micronucleated reticulocytes was observed over the administered dose range of 0.625 to 10 mg/kg/day in male rats. However, this increase was within the laboratory’s historical control range (95% confidence limits); therefore, the biologic significance of this small increase is questionable. No changes were noted in the percentage of immature erythrocytes in peripheral blood of male or female rats, suggesting that PFOA did not induce bone marrow toxicity.

PFNA was negative in bacterial mutagenicity assays with and without 10% rat liver S9; it was tested at doses up to 500 µg/plate in TA100 and TA98 and up to 5,000 µg/plate in the E. coli strain in the absence of S9 (Table B-3). With S9, PFNA was tested up to 1,000 µg/plate in TA100 and TA98 and up to the assay limit of 10,000 µg/plate in the E. coli strain.

No increases in micronucleated reticulocytes were seen in peripheral blood of male rats administered PFNA once daily by gavage for 28 days; only two treatment groups could be evaluated for this endpoint due to severe toxicity to the bone marrow in the high-dose male rats, evidenced by marked reduction in circulating reticulocytes (Table B-7). In female rats, no significant increases in micronucleated reticulocytes were seen over the dose range of 1.56 to 6.25 mg/kg/day, and no indication of bone marrow toxicity was seen due to the percentage of immature erythrocytes in circulation, which was unaffected by treatment.

PFDA was negative in bacterial mutagenicity assays with and without 10% rat liver S9; it was tested at doses up to 1,000 µg/plate in TA100 and TA98 and up to 5,000 µg/plate in the E. coli strain in the absence of S9 (Table B-4). With S9, all strains were tested up to the assay limit of 10,000 µg/plate.

No increases in micronucleated reticulocytes were seen in peripheral blood of female rats administered PFDA once daily by gavage for 28 days over a dose range of 0.156 to 1.25 mg/kg/day (Table B-8). However, in males, a significant increase in micronucleated reticulocytes was seen at the highest dose administered (2.5 mg/kg/day), although two of the five rats in this treatment group had a severe reduction in the number of reticulocytes, precluding accurate evaluation of the % PCEs in these two rats. Thus, in male rats, the increase in micronuclei was only seen at a dose level that induced severe toxicity to the bone marrow, and the % PCEs value was at the top end of the laboratory’s historical control range (95% confidence limits) for male Sprague Dawley rats.

No increases in the frequencies of micronucleated erythrocytes (either immature or mature [NCEs]) were observed in peripheral blood of rats administered WY (6.25 to 25 mg/kg/day) by gavage for 28 days (Table B-9). However, WY caused significant, dose-dependent decreases in % PCEs in the peripheral blood of female rats, suggesting that the bone marrow was a target for cytotoxicity.

Figure 19

Normal Mesenteric Lymph Node of a Male Vehicle Control Rat in the 28-day Gavage Toxicity Study of Perfluorononanoic Acid (H&E)

Lymphoid follicles (arrows).