# Materials and Methods

## Procurement and Characterization

### Perfluoroalkyl Carboxylates

Perfluorohexanoic acid (PFHxA) was obtained from Matrix Scientific (Columbia, SC) in one lot (Q02G); perfluorooctanoic acid (PFOA) was obtained from Sigma-Aldrich (St. Louis, MO) in one lot (03427TH); perfluorononanoic acid (PFNA) was obtained from Oakwood Products, Inc. (West Columbia, SC), in one lot (D11G); and perfluorodecanoic acid (PFDA) was obtained from Sigma-Aldrich in one lot (01820LE). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory and the study laboratory at Battelle (Columbus, OH) (Appendix C). Reports on analyses performed in support of the perfluoroalkyl carboxylate studies are on file at the National Institute of Environmental Health Sciences.

Lot Q02G (PFHxA), a clear, colorless liquid; lot 03427TH (PFOA), white crystals; lot D11G (PFNA), a white, crystalline powder; and lot 01820LE (PFDA), white, transparent wet crystals, were identified using Fourier transform infrared (FTIR) spectroscopy, mass spectrometry (MS), and carbon-13 and fluorine-19 nuclear magnetic resonance (NMR) spectroscopy.

The purity of each perfluoroalkyl carboxylate lot was determined by high-performance liquid chromatography (HPLC)/ion chromatography (IC) with suppressed conductivity (SC) detection (all lots except 01820LE), and gas chromatography (GC) with flame ionization detection (FID) and electron capture detection (ECD); in addition, GC/MS was used to confirm the identity of each perfluoroalkyl carboxylate test article and identify impurities within each lot. Additional GC/FID, GC/ECD, and GC/MS analyses were performed on lot D11G to screen it for selected volatile solvents. All GC analyses were performed on derivatized (methylated) aliquots of each perfluoroalkyl carboxylate. Differential scanning calorimetry (DSC) was used to determine the purities of lots 03427TH and D11G. In addition, Karl Fischer titration for lots Q02G and 03427TH was performed by Prevalere Life Sciences, Inc. (Whitesboro, NY), and similar analysis for lot D11G was performed by Galbraith Laboratories, Inc. (Knoxville, TN).

For lot Q02G (PFHxA), Karl Fischer titration indicated 0.47% water. HPLC/IC/SC analysis indicated one major peak that was 99.6% of the total peak area and two reportable (areas ≥0.1% of the total peak area) impurities with a combined area of 0.37% of the total peak area. GC/FID analysis indicated one major peak (99.1%) and five reportable impurities with a combined area of 0.95% of the total peak area. GC/ECD analysis showed that the impurities were likely fluorinated compounds. GC/MS analysis confirmed the identity of the test article and indicated that one of the impurities representing 0.33% of the total was an isomer of PFHxA. The overall purity of lot Q02G was determined to be greater than 99% (Table 2).

Table 2 Purity of Chemicals in the 28-day Gavage Studies of Perfluoroalkyl Carboxylates

Chemical Name | Lot Number | Percent Purity | Number of Impurities^a^ | Percent Impurity^a^
PFHxA | Q02G | >99 | ≤5 | ≤0.95
PFOA | 03427TH | >98 | ≤5 | ≤2.0
PFNA | D11G | >98 | ≤6 | ≤1.5
PFDA | 01820LE | >97 | 10 | ≤3.0

PFHxA = perfluorohexanoic acid; PFOA = perfluorooctanoic acid; PFNA = perfluorononanoic acid; PFDA = perfluorodecanoic acid.

^a^ Value depends on analytical method applied.

For lot 03427TH (PFOA), Karl Fischer titration indicated 0.24% water. DSC indicated an average purity of 98.96%. HPLC/IC/SC analysis indicated one major peak that was 98.8% of the total peak area and three reportable impurities with a combined area of 1.2% of the total peak area. GC/FID analysis indicated one major peak (98.3%) and four reportable impurities with a combined area of 1.66% of the total peak area. GC/ECD analysis showed that the impurities were likely fluorinated compounds. GC/MS analysis confirmed the identity of the test article and indicated that two of the impurities representing 1.04% of the total were isomers of PFOA. The overall purity of lot 03427TH was determined to be greater than 98% (Table 2).

For lot D11G (PFNA), Karl Fischer titration indicated 0.29% water. DSC indicated an average purity of 99.5%. HPLC/IC/SC analysis indicated one major peak that was 98.5% of the total peak area and two reportable impurities with a combined area of 1.5% of the total peak area. GC/FID analysis by one system indicated a purity of 100%. GC/ECD by one system analysis indicated a purity of 99.0% with six reportable impurities. GC/MS analysis confirmed the identity of the test article and indicated the presence of perfluoroheptanoic acid as an impurity. GC/FID analysis by a second system showed the presence of low concentrations of the nonhalogenated solvents (≤0.007%) hexane, diethyl ether, and acetone. GC/ECD analysis by a second system showed the presence of low concentrations of the halogenated solvents (≤0.0009%) chloroform and carbon tetrachloride. The overall purity of lot D11G was determined to be greater than 98% (Table 2).

For lot 01820LE (PFDA), GC/FID analysis indicated one major peak (97.2%) and 10 reportable impurities with a combined area of 2.8% of the total peak area. GC/ECD analysis showed that the impurities were likely fluorinated compounds. GC/MS analysis confirmed the identity of the test article and indicated that one of the impurities representing 0.59% of the total was an isomer of PFDA. The overall purity of lot 01820LE was determined to be greater than 97% (Table 2).

Stability studies of lots Q02G (PFHxA) and D11G (PFNA) of the bulk chemicals were performed using HPLC/IC/SC and GC/ECD, respectively. Stability was confirmed for bulk chemical samples stored in sealed amber glass bottles at temperatures up to 60°C for at least 14 days. To ensure stability, all the bulk chemicals were stored at room temperature in sealed opaque plastic containers (lots Q02G and D11G) or sealed amber glass bottles (lots 03427TH and 01820LE). Reanalyses of the bulk chemicals were performed by the study laboratory; no degradation was detected.

### Wyeth-14,643

Wyeth-14,643 (WY) was obtained from Chem Syn Laboratories (Lenexa, KS) in one lot (91-314-72-07/91-314-100-33A). Identity and purity analyses were conducted by the analytical chemistry laboratory and the study laboratory at Battelle (Columbus, OH) (Appendix C).

Lot 91-314-72-07/91-314-100-33A, a white powder, was identified using FTIR spectroscopy and proton and carbon-13 NMR spectroscopy. The purity of WY was determined by HPLC with ultraviolet light (UV) detection and DSC.

For lot 91-314-72-07/91-314-100-33A, HPLC/UV analysis indicated one major peak (99.4%) and two reportable impurities with a combined area of 0.64% of the total peak area. DSC indicated an average purity of 94.3%; this lower calculated purity compared to that shown by HPLC was considered an indication of thermal decomposition rather than impurity of the bulk chemical. The overall purity of lot 91-314-72-07/91-314-100-33A was determined to be greater than 99%.

To ensure stability, the bulk chemical was stored at room temperature in sealed amber glass bottles. Reanalyses of the bulk chemical were performed by the study laboratory, and no degradation was detected.

### Tween^®^ 80

Tween 80 (polysorbate 80) was obtained from Spectrum Laboratory Products, Inc. (Gardena, CA), and was used at a 2% concentration as the vehicle in the 28-day gavage studies. The vehicle was prepared by mixing the appropriate amount of Tween 80 with deionized water in a calibrated carboy and stirring with an overhead stirrer until all the Tween 80 was dissolved.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing PFHxA, PFOA, PFNA, PFDA, or WY with 2% Tween 80 in deionized water to give the required concentrations. Each formulation pH was adjusted to between 6 and 8. The dose formulations were stored at room (PFHxA, PFOA, PFNA, and PFDA) or refrigerated (WY) temperatures in amber glass bottles sealed with Teflon^®^-lined lids for no more than 43 days.

Homogeneity studies of the 6.26 and 100 mg/mL dose formulations of PFHxA and a stability study of the 6.26 mg/mL dose formulation were performed by the analytical chemistry laboratory using GC/ECD. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.05 mg/mL formulation and the 20 mg/mL dose formulation of PFOA and a stability study of a 0.05 mg/mL formulation were performed by the analytical chemistry laboratory using the same GC/ECD system. These studies were performed on lot 02702EE (Sigma-Aldrich) which was not used in the animal studies. In addition, homogeneity and stability of a 0.05 mg/mL formulation of lot 03427TH were assessed by the analytical chemistry laboratory using GC/ECD. Homogeneity was confirmed, and stability was confirmed for at least 42 days for formulations stored in amber glass bottles with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.12 mg/mL formulation and the 5 mg/mL dose formulation of PFNA and a stability study of a 0.12 mg/mL formulation were performed by the analytical chemistry laboratory using GC/ECD. Homogeneity was confirmed, and stability was confirmed for at least 43 days for formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.04 mg/mL formulation and the 0.5 mg/mL dose formulation of PFDA and a stability study of a 0.04 mg/mL formulation were performed by the analytical chemistry laboratory using GC/ECD. An additional stability study of the 0.0312 mg/mL dose formulation was performed by the study laboratory using the same GC/ECD system. Homogeneity was confirmed, and stability was confirmed for at least 42 (analytical chemistry laboratory) or 45 (study laboratory) days for formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of the 1.26 and 5 mg/mL dose formulations of WY and a stability study of the 1.26 mg/mL dose formulation were performed by the analytical chemistry laboratory using HPLC/UV. Homogeneity was confirmed, and stability was confirmed for at least 42 days for formulations stored in amber glass bottles sealed with Teflon^-^lined lids at refrigerated temperature and for at least 3 hours under simulated animal room conditions.

Analyses of the dose formulations for the 28-day studies of PFHxA, PFOA, PFNA, and PFDA were conducted once for each study by the study laboratory using GC/ECD. HPLC/UV was used to conduct similar analyses for the 28-day study of WY. All dose formulations for all five chemicals were within 10% of the target concentrations (Table C-4). Animal room samples of these dose formulations were also analyzed; with the exception of two of 10 samples for the PFOA study, all animal room samples for all five chemicals were within 10% of the target concentrations.

## Animal Source

Male and female Sprague Dawley (Hsd:Sprague Dawley SD) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Twenty-eight-day Studies

On receipt, rats were approximately 7 to 9 weeks old. Animals were quarantined for 12 (males) or 13 (females) days for PFHxA, 11 (males) or 12 (females) days for PFOA, 14 (males) or 15 (females) days for PFNA, 19 (males) or 20 (females) days for PFDA, and 21 (males) or 22 (females) days for WY. The rats were 10 to 11 weeks old on the first day of each study. Before the studies began, five male and five female rats were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the NTP Sentinel Animal Program (Appendix E). All results were negative.

All dose groups consisted of 10 male and 10 female rats. All test compounds were administered in deionized water with 2% Tween 80 by gavage, 7 days per week for 28 days; control animals received the vehicle only. Doses were selected based on a maximum tolerated daily dose and kinetic information obtained from toxicokinetics studies. PFHxA was administered twice daily at one-half the dose for total daily doses of 0, 62.6, 125, 250, 500, or 1,000 mg/kg body weight. PFOA was administered once daily at 0, 0.625, 1.25, 2.5, 5, or 10 mg/kg (males) or 0, 6.25, 12.5, 25, 50, or 100 mg/kg (females). PFNA was administered once daily at 0, 0.625, 1.25, 2.5, 5, or 10 mg/kg (males) or 0, 1.56, 3.12, 6.25, 12.5, or 25 mg/kg (females). PFDA was administered once daily at 0, 0.156, 0.312, 0.625, 1.25, or 2.5 mg/kg. WY was administered once daily at 0, 6.25, 12.5, or 25 mg/kg. All formulations were administered at a volume of 5 mL/kg. NTP-2000 feed and water were available ad libitum. Rats were housed five per cage and were observed twice daily. The animals were weighed, and clinical observations were recorded initially, weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 3. Information on feed composition and contaminants is provided in Appendix D.

Table 3 Experimental Design and Materials and Methods in the 28-day Gavage Studies of Perfluoroalkyl Carboxylates^a^

28-day Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley SD) rats
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN)
Time Held Before Studies
PFHxA: 12 (males) or 13 (females) days
PFOA: 11 (males) or 12 (females) days
PFNA: 14 (males) or 15 (females) days
PFDA: 19 (males) or 20 (females) days
WY: 21 (males) or 22 (females) days
Average Age When Studies Began
10 to 11 weeks
Date of First Dose
PFHxA: January 17 (males) or 18 (females), 2012
PFOA: January 31 (males) or February 1 (females), 2012
PFNA: February 2 (males) or 3 (females), 2012
PFDA: February 7 (males) or 8 (females), 2012
WY: January 26 (males) or 27 (females), 2012
Duration of Dosing
7 days/week for 28 days (gavage)
Date of Last Dose
PFHxA: February 13 (males) or 14 (females), 2012
PFOA: February 27 (males) or 28 (females), 2012
PFNA: February 29 (males) or March 1 (females), 2012
PFDA: March 5 (males) or 6 (females), 2012
WY: February 22 (males) or 23 (females), 2012
Necropsy Dates
PFHxA: February 14 (males) or 15 (females), 2012
PFOA: February 28 (males) or 29 (females), 2012
PFNA: March 1 (males) or 2 (females), 2012
PFDA: March 6 (males) or 7 (females), 2012
WY: February 23 (males) or 24 (females), 2012
Average Age at Necropsy
PFHxA: 13 to 15 weeks PFOA, PFNA, PFDA, WY: 14 to 15 weeks
Size of Study Groups
10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
5
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom, Inc., Waterford, WI), available ad libitum
Cages
Solid, polycarbonate (Lab Products, Inc., Seaford, DE), changed twice weekly
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed twice weekly with cages
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed at least every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F
Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day
Room air changes: at least 10/hour
Doses
PFHxA: 0, 62.6, 125, 250, 500, or 1,000 mg/kg per day; one-half the dose was administered twice daily approximately 6 hours apart (males and females)
PFOA: males: 0, 0.625, 1.25, 2.5, 5, or 10 mg/kg per day; females: 0, 6.25, 12.5, 25, 50, or 100 mg/kg per day
PFNA: males: 0, 0.625, 1.25, 2.5, 5, or 10 mg/kg per day; females: 0, 1.56, 3.12, 6.25, 12.5, or 25 mg/kg per day
PFDA: 0, 0.156, 0.312, 0.625, 1.25, or 2.5 mg/kg per day (males and females)
WY: 0, 6.25, 12.5, or 25 mg/kg per day
All doses were administered in deionized water with 2% Tween^®^ 80 by gavage (dosing volume 5 mL/kg).
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical findings were recorded on day 1, weekly thereafter, and at the end of the study.
Method of Euthanasia
Anesthetization with CO_2_:O_2_ (70%:30%) followed by exsanguination by severing the abdominal aorta
Necropsy
Necropsies were performed on all rats. Organs weighed were right adrenal gland, heart, right kidney, liver, lungs, spleen, right testis, thymus, thyroid gland, and uterus/cervix/vagina.
Clinical Pathology
Blood was collected from the abdominal aorta of all rats at the end of the studies for hematology and clinical chemistry.
Hematology: hematocrit; manual hematocrit, hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials, blood smear morphological evaluation
Clinical chemistry: urea nitrogen; creatinine; glucose; total protein; albumin; globulin; total, direct, and indirect bilirubin; aspartate aminotransferase; alanine aminotransferase; alkaline phosphatase; creatine kinase; sorbitol dehydrogenase; cholesterol; triglycerides; total bile acids; total triiodothyronine; thyroid stimulating hormone; total and free thyroxine; and testosterone.
Histopathology
PFHxA: Complete histopathology was performed on 0 and 1,000 mg/kg per day rats.
PFOA: Complete histopathology was performed on 0, 10 (males), and 100 (females) mg/kg per day rats.
PFNA: Complete histopathology was performed on 0, 2.5, 5, and 10 mg/kg per day (males) and 0, 6.25, 12.5, and 25 mg/kg per day (females) rats.
PFDA: Complete histopathology was performed on rats in the 0 and 2.5 mg/kg per day rats.
WY: Complete histopathology was performed on rats in the 0 and 25 mg/kg per day rats.
In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: adrenal gland, bone with marrow, brain, clitoral gland, epididymis esophagus, eyes, Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine, (duodenum, jejunum, ileum), lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), thymus, trachea, urinary bladder, and uterus. The kidney, liver, pancreas, ovary, testis, and thyroid gland were examined in all dose groups.
Reproductive Parameters
PFHxA: Blood was collected from the abdominal aorta of all rats at the end of the study and analyzed for testosterone levels. Sperm samples were collected from 0, 250, 500, and 1,000 mg/kg per day males at study termination. The following parameters were evaluated: spermatid heads per testis and per gram testis, spermatid counts, and epididymal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for 16 consecutive days prior to the end of the study from females in the 0, 125, 250, and 500 mg/kg per day groups for vaginal cytology evaluations. The percentage of time spent in the various estrus cycle stages and estrus cycle length were evaluated.
PFOA: Same as the PFHxA study except sperm samples were collected from 0, 2.5, 5, and 10 mg/kg per day males, and vaginal samples were collected from 0, 25, 50, and 100 mg/kg per day females.
PFNA: Same as the PFHxA study except sperm samples were collected from 0, 0.625, 1.25, and 2.5 mg/kg per day males, and vaginal samples were collected from 0, 1.56, 3.12, and 6.25 mg/kg per day females.
PFDA: Same as the PFHxA study except sperm samples were collected from 0, 0.625, 1.25, and 2.5 mg/kg per day males, and vaginal samples were collected from 0, 0.625, 1.25, and 2.5 mg/kg per day females.
WY: Same as the PFHxA study except sperm and vaginal samples were collected from rats in all dose groups.
Internal Dose Assessment
Approximately 24 hours after the last dose in the PFHxA, PFOA, PFNA, PFDA studies, parent compound concentrations were determined in plasma from blood collected from the abdominal aorta of all rats and in liver samples from the right anterior and posterior lobes of male rats.
Liver Enzyme Levels and Gene Expression
Samples were collected from the median liver lobe of surviving male rats at study termination for determination of acyl-CoA oxidase activity. Samples were collected from the left liver lobe of all surviving rats at study termination for determination of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2.

^a^ PFHxA = perfluorohexanoic acid; PFOA = perfluorooctanoic acid; PFNA = perfluorononanoic acid; PFDA = perfluorodecanoic acid; WY = Wyeth-14,643.

Animals were anesthetized with a 70%:30% CO_2_:O_2_ mixture and blood was collected from the abdominal aorta at the end of the studies for hematology, clinical chemistry, thyroid hormone and testosterone analyses, parent compound concentration, and micronucleus assays. For each animal, blood was collected into two tubes containing K_3_ EDTA and one tube devoid of an anticoagulant. An aliquot of whole blood was removed from one K_3_ EDTA tube and centrifuged, and the plasma was harvested and shipped to Battelle (Columbus, OH) for internal dose analyses^25,26^; the remaining whole blood was used for hematology analysis. The other K_3_ EDTA tube was shipped on wet ice to ILS, Inc. (Durham, NC), for micronuclei analysis the day it was collected. Any remaining plasma was frozen and shipped to NTP Frozen Tissue Bank (Durham, NC). Blood collected in tubes devoid of anticoagulant was allowed to clot, and the serum harvested for clinical chemistry and hormonal analysis, except aspartate aminotransferase activity and total and direct bilirubin concentrations, which were analyzed at a later date using an aliquot of the stored frozen plasma. The hematology analyses were conducted using an Advia 120 (Bayer Diagnostics Division, Tarrytown, NY) and reagents supplied by the manufacturer. A manual hematocrit was determined with the use of a microcentrifuge. Blood smears were stained with a Romanowsky-type stain and the morphology of the leukocytes, erythrocytes, and platelets reviewed. Clinical chemistry analyses (including total thyroxine) were completed using a Cobas c501 Chemistry Analyzer (Roche, Indianapolis, IN); aspartate aminotransferase activity and bilirubin concentrations were analyzed on an Olympus AU400 Analyzer (Irving, TX). The remaining thyroid hormones were determined by radioimmunoassay (free thyroxine and total triiodothyronine [MP Biomedicals, Irvine, CA]; thyroid stimulating hormone [Institute of Isotopes, Ltd., Budapest, Hungary]). Testosterone was determined by enzyme-linked immunosorbent assay (Calbiotech, Inc., Spring Valley, CA). The parameters measured are listed in Table 3.

Necropsies were performed on all rats. The right adrenal gland, heart, right kidney, liver, lung, spleen, right testis, thymus, thyroid gland, and uterus/cervix/vagina from each animal were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, testes, epididymides, and vaginal tunics were first fixed in Davidson’s solution or modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of approximately 5 µm, and stained with hematoxylin and eosin. Histopathologic examinations were performed on all rats. Table 3 lists the tissues and organs routinely examined.

At the end of the 28-day studies, samples were collected for sperm motility evaluations on male rats administered 0, 250, 500, or 1,000 mg/kg/day (PFHxA); 0, 2.5, 5, or 10 mg/kg/day (PFOA); 0, 0.625, 1.25, and 2.5 mg/kg/day (PFNA, PFDA); and 0, 6.25, 12.5, or 25 mg/kg/day (WY). It was recognized that the 28-day dosing duration would not cover the full spermatogenic cycle. The parameters evaluated are listed in Table 3. Male rats were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer. For vaginal cytology, samples were taken from females in the 0, 125, 250, and 500 mg/kg/day (PFHxA); 0, 25, 50, and 100 mg/kg/day (PFOA); 0, 1.56, 3.12, and 6.25 mg/kg/day (PFNA); 0, 0.625, 1.25, and 2.5 mg/kg/day (PFDA); and 0, 6.25, 12.5, and 25 mg/kg/day (WY) groups. For 16 consecutive days prior to scheduled terminal euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus).

At the end of the PFHxA, PFOA, PFNA, and PFDA studies, 500 mg liver samples from the right anterior and posterior lobes of male rats were collected for determination of parent compound concentrations, given that male rat liver responses to PFAS are generally greater compared to females. At the end of all studies, approximately 1 g of liver tissue was collected from the median lobe of male rats, homogenized, frozen, and stored until analyzed for acyl-CoA oxidase activity. From the left liver lobe, tissue samples were placed in RNAlater^®^ (Ambion, Inc., Austin, TX) and stored at 2° to 8°C overnight. The RNAlater supernatant was then removed from the samples, and the samples were frozen at −70°C ± 10°C. Samples weighing between 22.0 and 30.0 mg were added to lysis buffer, homogenized, and stored at −80°C ± 10°C until RNA was isolated. RNA was extracted from the supernatant, subjected to DNase digestion, and isolated using the Qiagen RNeasy Mini Kit (Qiagen, Valencia, CA). Each RNA sample was analyzed for quantity and purity by ultraviolet analysis using a NanoDrop ND-1000 Spectrophotometer (NanoDrop Technologies, Wilmington, DE). All samples were evaluated for RNA integrity using an RNA 6000 Nano Chip kit with an Agilent 2100 Bioanalyzer (Agilent, Santa Clara, CA) and then stored at −80°C ± 10°C until further processing. Total RNA (1 µg) isolated from rat tissue samples was reverse transcribed into cDNA using Qiagen RT HT First Strand Kits (Qiagen, Valencia, CA). The cDNA samples were analyzed using Qiagen RT^2^ Custom Arrays in a 96-well plate format. Relative fold change was calculated within the analysis software based on the ∆∆Ct method for relative quantitation. Twelve samples were run on each array plate with a single sample in each column of the plate. The eight wells in each column of the array plates contained the four genes of interest: PPARα-related genes acyl-CoA oxidase (Acox1) and cytochrome P450 4a1 (Cyp4a1), constitutive androstane receptor (CAR)-related genes cytochrome P450 2b1 (Cyp2b1) and cytochrome P450 2b2 (Cyp2b2), a housekeeping gene glyceraldehyde-3-phosphate dehydrogenase (GAPDH), and three array plate quality controls. The parameters measured are listed in Table 3.

Quality control measurements for each sample on each qPCR array plate were evaluated to determine if the data generated from the sample were of sufficient quality prior to analysis using the web-based RT Profiler PCR Array Data Analysis software (version 3.5, SABiosciences, Valencia, CA). The controls on the qPCR array were analyzed for each sample and included a PCR positive/array reproducibility control (PPC), a reverse transcription control (RTC), and a genomic DNA contamination (GDC) control. A sample successfully passed all of these control parameters when the cycle threshold (Ct) value for the PPC was 20 ± 2, the Ct value for the GDC was greater than or equal to 35, and the Ct value of the PPC subtracted from the Ct value of the RTC was less than or equal to 5. If a sample failed the acceptance criteria for the GDC and/or RTC controls, the sample was repeated starting with the reverse transcription (cDNA synthesis) process followed by analysis on a new qPCR array plate. If a sample failed the PPC control, the cDNA sample was used to repeat the sample on a new qPCR array plate. Once all the data from a single experiment were analyzed and collected (male or female, control animals, and all dosages), the quality control data were assessed a second time after the total experimental data were uploaded into the web-based RT Array Data Analysis software (version 3.5, SABiosciences). This provided additional assurance that the data for the entire experiment passed the quality control criteria.

The relative fold change for each gene of interest (Acox1, Cyp4a1, Cyp2b1, and Cyp2b2) was calculated within the analysis software for relative quantitation. All the samples were normalized using the housekeeping gene GAPDH, and the geometric mean of all samples in a particular group was used for normalization. The p values (based on the Student’s t-test of the replicate values for each gene in the vehicle control group and dose groups) and 95% confidence intervals for each fold change value were also calculated during analysis. The threshold for determining significant differential expression of each gene was a fold change of ≥2 or ≤−2 and a p value ≤0.05.

After a review of the laboratory reports, selected histopathology slides were submitted to quality assessment (QA) pathologists for review. After the review, diagnostic discrepancies/inconsistencies were discussed and resolved with the NTP pathologists. The QA pathologist also served as the Pathology Working Group (PWG) pathologist and coordinator. Any remaining discrepancies/inconsistencies were resolved by the PWG. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, and the QA/PWG pathologist. Details of these review procedures have been described, in part, by Maronpot and Boorman^106^ and Boorman et al.^107^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in this report and in the CEBS database (https://manticore.niehs.nih.gov/cebssearch) as the numbers of animals bearing such lesions at a specific anatomic site and as the numbers of animals with that site examined microscopically. The Fisher exact test,^108^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and vehicle control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^109^ and Williams.^110,111^ Hematology, clinical chemistry, hormones, parent compound, spermatid, epididymal spermatozoal, hepatic enzymes, and hepatic gene expression data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^112^ (as modified by Williams^113^) and Dunn.^114^ Jonckheere’s test^115^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^116^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the vehicle control group using the Dunn’s or Shirley’s test on the cycle length and number of cycles.^108^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^117^ The “Overall” test checks for any of the extended or skipped states. For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the vehicle control group and each dosed group was tested using chi-square statistics.

## Quality Assurance Methods

The 28-day studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^118^ In addition, as records from the 28-day studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at the National Institute of Environmental Health Sciences. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.

## Genetic Toxicology

### Bacterial Mutagenicity Test Protocol

The test articles were coded prior to testing. Testing was conducted as reported by Zeiger et al.,^119^ with some modifications. Compounds were incubated with the bacterial tester strains (Salmonella typhimurium strains TA98 and TA100 and Escherichia coli strain WP2uvrApKM101) either in buffer or S9 mix (metabolic activation enzymes and cofactors from livers of phenobarbital/benzoflavone-induced male Sprague Dawley rats) for 20 minutes at 37°C. Top agar supplemented with L-histidine or L-tryptophan (for the E. coli strain only) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted using an automatic colony counter following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of at least five doses of the test compound. The highest concentration tested was limited by toxicity in the absence of S9; with S9, concentrations were either limited by toxicity or achieved the limit concentration of 10,000 µg/plate. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, not reproducible, or not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. No minimum percentage or fold increase is required for a chemical to be judged positive or weakly positive.

### Rat Peripheral Blood Micronucleus Test Protocol

Blood samples (200 µL per animal) were collected at the end of the studies, stabilized in EDTA tubes, and packaged on ice packs for shipment later that same day by overnight courier to ILS, Inc. (Durham, NC). Samples were kept chilled upon arrival at the laboratory the following day and were fixed within 4 hours of receipt. For each sample, 50 µL of blood were dispensed into a microcentrifuge tube containing heparin and mixed by inverting several times. A fixation tube containing ultra-cold methanol was then removed from a −80°C freezer and 180 µL of the heparinized blood sample was forcefully dispensed into the tube, rapidly mixed, and quickly transferred back to the −80°C freezer. The fixed blood samples were stored in the −80°C freezer for at least 3 days prior to flow cytometry analysis of micronucleated red blood cells.

Flow cytometry analysis was performed using MicroFlow^PLUS^ Kit reagents (Litron Laboratories, Rochester, NY) and a Becton-Dickinson FACSCalibur™ dual-laser bench top system (BD Biosciences, San Jose, CA). The analysis was performed according to the kit’s instruction manual with minimal modification.^120,121^ For up to five peripheral blood samples per dose group, 20,000 (±2,000) immature CD71-positive erythrocytes (also referred to as polychromatic erythrocytes [PCE]) were analyzed by flow cytometry to determine the frequency of normal and micronucleated PCE (MN-PCE). Aggregates were excluded on the basis of forward and side scatter; platelets were excluded on the basis of staining with an anti-CD61 antibody; and nucleated leukocytes were excluded on the basis of intense propidium iodide staining. Normal and micronucleated mature erythrocytes (also referred to as normochromatic erythrocytes [NCE]) were enumerated concurrently during MN-PCE analysis, allowing for calculation of the percentage of PCE among total erythrocytes as a measure of bone marrow toxicity.

In rats, although both immature and mature erythrocytes are evaluated for presence of micronuclei concurrently, the appropriate cell population for determining the frequency of micronucleated cells is the youngest portion of the immature erythrocyte population, i.e., the fraction of immature erythrocytes that is newly emerged from the bone marrow, due to the efficiency with which the rat spleen removes micronucleated red blood cells from circulation.

Prior experience with the large number of cells scored using flow cytometric scoring techniques^122,123^ suggested it was reasonable to assume that the proportion of micronucleated reticulocytes was approximately normally distributed. Mean MN-PCE/1,000 PCE and MN-NCE/1,000 erythrocytes, as well as % PCE, were calculated for each animal. These data are summarized in the tables as mean ± standard error of the mean. Levene’s test was used to determine if variances among dose groups were equal at α = 0.05. When variances were equal, linear regression analysis was used to test for linear trend and Williams’ test was used to evaluate pairwise differences between each dosed group and the vehicle control group. When variances were unequal, nonparametric methods were used to analyze the data; Jonckheere’s test was used to evaluate linear trend; and Dunn’s test was used to assess the significance of pairwise differences between each dosed group and the vehicle control group. Trend tests and pairwise comparisons with the controls are considered statistically significant for PCEs and NCEs when the one-sided p value is less than 0.025 and for percent PCEs when the two-sided p value is less than 0.05. A result was considered positive if the trend test was significant and if at least one dose group was significantly elevated over the vehicle control group or if two or more dose groups were significantly increased over the corresponding vehicle control group. A response was considered equivocal if only the trend test was significant or if only a single dosed group was significantly increased over the vehicle control group.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this toxicity study report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.