# Introduction

## Chemical and Physical Properties

The per/polyfluorinated alkyl substances (PFAS) are a class of chemicals that consist of alkyl chains in which hydrogen is substituted with fluorines. This Toxicity Study Report focuses on straight-chain PFAS with a carboxylic acid end group, including perfluorohexanoic acid (PFHxA), perfluorooctanoic acid (PFOA), perfluorononanoic acid (PFNA), and perfluorodecanoic acid (PFDA) (Table 1). The hydrophobic and lipophilic qualities of these chemicals make them useful in surfactants and polymers.^1^

Table 1 Perfluoroalkyl Carboxylates

Chemical Formula | CAS Number | Chemical Structure | Molecular Weight
Perfluorohexanoic Acid C_6_HF_11_O_2_ | 307-24-4 | | 314.054
Perfluorooctanoic Acid C_8_HF_15_O_2_ | 335-67-1 | | 414.07
Perfluorononanoic Acid C_9_HF_17_O_2_ | 375-95-1 | | 464.078
Perfluorodecanoic Acid C_10_HF_19_O_2_ | 335-76-2 | | 514.086

PFHxA is a colorless liquid with a boiling point of 157°C and a vapor pressure of 1.98 mm Hg at 25°C.^2^ PFOA is a white, pungent powder with a boiling point of 192°C and a vapor pressure of 0.525 mm Hg (25°C).^3^ PFNA is a white, crystalline powder with a boiling point of 218°C at 740 mm Hg and a vapor pressure of 0.083 mm Hg (25°C).^4^ PFDA is a liquid with a boiling point of 189°C and a vapor pressure of 10 mm Hg (0°C).^5^

## Production, Use, and Human Exposure

PFAS are widely used in the manufacturing of a variety of consumer products and are used in food-contact substances such as nonstick coatings for cookware.^6^ Indirect human exposure to perfluoroalkyl carboxylates, such as PFOA, can also occur as a degradation by-product or from internal metabolism of other PFAS, such as polyfluoroalkyl phosphate surfactants, which are often applied to food-contact paper products.^7^

Levels of PFAS can persist in the human population for a prolonged period, contributing to a lifetime of exposure to a variety of PFAS species. The four carboxylates evaluated in this report display a wide range of human internal exposure.

In the U.S. National Health and Nutrition Examination Survey (NHANES), the national geometric means measured in human plasma for one year from 2013 to 2014 were 1.94 ng/mL PFOA, 0.68 ng/mL PFNA, and 0.19 ng/mL PFDA.^8^ All children, ages 3 to 11, surveyed in that year had detectable levels of PFOA (1.92 ng/mL) and PFNA (0.794 ng/mL) but not PFDA.^9^ A more recent survey year (2015 to 2016) reported decreases in the geometric means measured in the total population for each PFAS: 1.56 ng/mL PFOA, 0.58 ng/mL PFNA, and 0.15 ng/mL PFDA.^8^ In a different 2015 survey, 13 PFAS were analyzed in human plasma collected from American Red Cross donors.^10^ PFOA (1.09 ng/mL), PFNA (0.43 ng/mL), and PFDA (0.15 ng/mL) were all detected. PFHxA was below the lower limit of quantitation (0.04 ng/mL) for this analysis.^10^ These values were compared to the concentrations in 2001 samples, which indicated a 77% decline in PFOA, a 33% decline in PFNA, and a 50% decline in PFDA between 2001 and 2015.^10^ Nevertheless, PFAS persist in surface soil, water, and wildlife providing a continuous source of exposure and environmental concern.^11,12^

Areas near sites of PFAS manufacturing or use are often associated with higher plasma levels due to contamination of water supplies. A 2015 survey of a New Hampshire community close to a former military base was conducted when the drinking water supply was found to be contaminated with PFAS. The survey revealed that more than 94% of individuals were found to have PFOA detectable in serum, with a geometric mean of 3.1 ng/mL.^13^ A 20-year survey of PFAS exposure in the mid-Ohio River Valley from 1991 to 2012 revealed that PFOA was detected in 99.9% of sera collected from test subjects, 47% of which were in the 95th percentile of PFOA sera levels in the United States, with a peak median concentration of 7.6 ng/mL.^14^

## Regulatory Status

The PFOA Stewardship Program, started in 2006, is an agreement with industry manufacturers to enact a decade-long plan to phase out the use of PFOA, PFOA precursors, and higher homologues, the goals of which have been met (PFOA Stewardship Program, 2014 https://www.epa.gov/assessing-and-managing-chemicals-under-tsca/20102015-pfoa-stewardship-program-2014-annual-progress). Although PFOA is no longer used in the United States, some fluoropolymers containing PFOA may be imported in other consumer products, and it can be produced by the breakdown of some fluorinated telomers. The U.S. Environmental Protection Agency (USEPA) established a drinking water level of 70 ppt in 2016.^15^

PFNA and PFOA, as with several other PFAS chemicals, are currently listed under USEPA’s UCMR3 (Third Unregulated Contaminant Monitoring Rule), which considers suspected contaminants. PFHxA and PFDA are not covered under this monitoring rule. As of November 2018, the Agency for Toxic Substances and Disease Registry set minimal risk levels for PFOA and PFNA to be 78 parts per trillion (ppt) for adults, and 21 ppt for children.^16^ Recently, the European Food Safety Authority (EFSA) developed tolerable weekly intakes of 6 ng/kg/week for PFOA based on human endpoints.^17^

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

Several studies have evaluated the absorption, distribution, metabolism, excretion, and toxicokinetics of these PFAS; results of these studies indicate large differences in excretion rates and are summarized in this section. Generally, PFAS are water soluble and most of their elimination occurs via urine. The kinetics across the class is variable depending on species and sex in some cases. Reuptake via renal absorption has been proposed to explain the differential elimination across species and sexes. Sex differences in PFOA elimination in rats is mediated by sex hormone-dependent regulation of organic anion transporters (OATs) OAT2 and OAT3.^18^ This mechanism is generally assumed to apply to the other PFAS displaying similar sex differences. Physiologically based pharmacokinetic (PBPK) modeling of PFAS has included a saturable renal resorption function.^19-24^ The pharmacokinetic properties were evaluated for several PFAS in the Hsd:Sprague Dawley rat, the animal model used in these 28-day toxicity studies.^25,26^

PFHxA: PFHxA was evaluated in Sprague Dawley rats administered either a bolus intravenous dose of 10 mg/kg or repeated oral gavage doses of 50, 150, or 300 mg/kg/day for 26 days.^27^ In the repeated administration gavage study, serum half-lives were reported to be 2 to 3 hours, with no apparent difference observed between males and females. In the single-dose intravenous studies, the terminal half-life was estimated to be 1 hour in males and 0.42 hours in females. Similar half-lives were observed in male and female Wistar rats administered 15 mg/kg intravenously.^28^ Terminal half-lives of 5 to 13 hours were observed in male and female Sprague Dawley rats administered 40, 80, or 160 mg PFHxA/kg orally; half-lives increased with dose.^25^

PFOA: The half-life of PFOA in male and female Sprague Dawley rats administered a single intraperitoneal dose of 4 mg/kg was found to be from four hours (females) to 15 days (males).^29^ This is longer than the results of a study done in Wistar rats administered PFOA intravenously (20 mg/kg), where male rats exhibited a half-life of 5 days. A full toxicokinetic evaluation of PFOA in males (6, 12, or 48 mg/kg/day) and females (40, 80, or 320 mg/kg/day) exhibited a k_10_ half-life in females of 3 to 14 hours, but in males it ranged from 8 to 12 days, decreasing with dose.^25^ An observational study of PFAS in retired fluorochemical production workers estimated the half-life of PFOA to be approximately 3.5 years.^30^ A small study of ski waxers (n = 6) estimated a half-life average of 2.4 years.^31^ A half-life average of 2.7 years was estimated from a community (n = 106) exposed to drinking water contaminated with PFOA.^32^

PFNA: Sprague Dawley rats were administered a single gavage dose of 1, 3, or 10 mg/kg PFNA, and blood samples were collected over the course of 50 days.^33^ Serum half-lives ranged from 24 to 42 days with no sex differences. Male and female Wistar rats administered PFNA intravenously (22 mg/kg) exhibited half-lives of 30 days (males) and 2 days (females).

PFDA: In male and female Wistar rats, evaluation of distribution, metabolism, and excretion after a single 20 mg/kg intraperitoneal dose showed PFDA was eliminated slowly over the course of 14 days with little to no urinary excretion.^34^ This is consistent with a report of male and female Wistar rats administered PFDA intravenously (24 mg/kg) exhibiting half-lives of 40 days (males) and 60 days (females). An evaluation of PFDA toxicokinetics in male and female rats (2, 10, or 20 mg/kg) also exhibited half-lives greater than 50 days.^25^

## Toxicity

### Experimental Animals

The literature on potential PFAS toxicity is extensive, and the following summaries focus mainly on guideline studies in rats for comparison to the results within this report. Liver toxicity is a common finding across this class, ranging from liver hypertrophy or necrosis to alterations in liver gene expression and clinical chemistry changes. Peroxisome proliferator-activated receptor alpha (PPARα) activation—leading to increased related gene expression and enzyme activity (e.g., cytochrome P450 4a1 and acyl-CoA oxidase 1 [Acox1] along with related enzyme activity of acyl-CoA oxidase) by PFAS in rodents—is a mechanistic pathway with varying potency across the class, depending on chain length.^35-39^ Generally, longer-chain PFAS display a greater toxicity than shorter-chain PFAS; and rodent species display a greater PPARα sensitivity than humans.^38-40^ Gene expression profiling of the liver suggests that constitutive androstane receptor (CAR) induction is another factor in liver toxicity and enzyme alterations.^41,42^

PFHxA: Several evaluations of PFHxA toxicity have been performed in rodents. A subchronic evaluation of PFHxA toxicity revealed nasal lesions and induction of hepatic peroxisomal β-oxidation in SD rats.^43^ In reproductive and developmental studies, no effects on reproductive parameters were observed; however, PFHxA-treated rats had lower fetal body weights compared to controls.^43^ In a separate subchronic study, PFHxA induced centrilobular hepatocellular hypertrophy that correlated with higher liver weights.^44^ In a perinatal study in CD-1 mice, PFHxA exposure at levels as low as 7 mg/kg/day led to lower F_1_ body weights at birth.^45^

PFOA: Subchronic exposure to PFOA in BR rats caused increased liver weights and induced hepatocyte hypertrophy.^46^ A two-generation study on ammonium perfluorooctanoate in Sprague Dawley rats revealed no changes in mating, fertility, or delivery endpoints in the parent or F_1_ generations.^47^ Parent and F_1_ generation male rats had decreased body weight and increased liver and kidney weights, and F_1_ generation pups had a lower birth weight and decreased viability at 30 mg/kg. PFOA significantly decreased fetal weight, live birth, and postnatal growth and survival and caused delays in eye opening in the offspring of dosed pregnant CD-1 mice.^48^

PFNA: In a subchronic study, Sprague Dawley rats were administered S-111-S-WB, a mixture of PFAS, once daily for 90 days; the predominant species in the mixture was PFNA.^49^ All rats survived to the end of the study, but recorded toxicities included lethargy, decreased body weight, lower serum protein concentrations, higher bilirubin, increased liver weights, and hepatocellular hypertrophy, degeneration, and necrosis. The no-observed-effect levels (NOELs) were 0.025 mg/kg/day for males and 0.125 mg/kg/day for females.

A two-generation reproductive toxicity study of S-111-S-WB was also conducted in Crl:CD(SD) rats.^50^ There were no test article-related reproductive effects at the doses tested; however, there were significant increases in liver and kidney weights in the top doses (0.125 and 0.6 mg/kg/day). In the liver, hepatocellular hypertrophy, centrilobular vacuolation, and clear cell foci were also observed and deemed to be related to dose, with male rats being more sensitive than female rats. Hypertrophy of renal tubule cells was also observed at the top dose in males and females.

PFNA was evaluated in a perinatal study in CD-1 mice.^51^ There were no differences observed in pregnancy parameters, but neonates exhibited dose-dependent delays in eye opening and onset of puberty, as well as increased liver weight that persisted into adulthood.

PFDA: In a teratology study in C57BL/6N mice, PFDA led to significantly reduced maternal body weights but no fetal toxicity in the absence of maternal toxicity.^52^

### Humans

A systematic review identified several human health categories of concern in children with respect to exposure to PFAS, including immunity, cardiometabolic, neurodevelopment, thyroid, renal, and puberty onset.^53,54^ Additionally, PFOA and PFOS levels in serum of women are correlated with thyroid disease.^55^ PFOA exposure in an occupational population has been associated with cerebrovascular disease, ischemic heart disease, ulcerative colitis, and diabetes.^56-58^ Dyslipidemia in adolescents has also been associated with exposure to PFOA and PFOS.^59^

PFAS exposure in women has been linked to irregular and long menstrual cycles and to delayed onset of menarche.^60,61^ A meta-analysis of several human studies revealed an association between serum or plasma PFOA and a difference in birth weight.^62^ Levels of PFOA in cord serum was not found to be associated with low birth weight or gestational age at birth in a Baltimore cohort.^63^ Modest associations between PFOA and preeclampsia and birth defects were found in a PFOA-exposed population in mid-Ohio.^64^ Elevated serum PFOA levels during development has been associated with a reduced antibody response (postvaccination) as observed in the Norwegian and Faroe Island birth cohort studies^65-67^ and a cross-sectional study of adolescents using NHANES data.^68^ NTP^69^ conducted a systematic review of immune effects and concluded that PFOA is presumed to be an immune hazard due to evidence from human and animal studies. ATSDR^70^ and the C8 panel reports^71-74^ found associations between exposure and reproductive parameters.

## Carcinogenicity

### Experimental Animals

Chronic exposure to PFHxA in SD rats did not reveal carcinogenic activity but did lead to a dose-dependent decrease in survival.^75^ A study was conducted with male and female Sprague Dawley rats exposed to 0, 30, or 300 ppm of ammonium perfluorooctonoate (APFO).^76^ An increase in Leydig cell adenomas of the testis was observed, as were increased female mammary fibroadenomas in the 300 ppm group. Further review of the mammary glands from this study found that they were not in fact increased, as more were observed in the control group than initially reported.^77^ Review of the pancreas found increased incidence of acinar cell hyperplasia and a single incidence of an acinar cell carcinoma.^78^ In a follow-up study with male Sprague Dawley rats exposed to 300 ppm, increased hepatocellular adenomas, Leydig cell adenomas, and pancreatic acinar cell tumors were observed.^79^

### Humans

Serum concentrations of various PFAS were measured in the blood of patients with hereditary prostate cancer in Sweden.^80^ PFDA, but not PFOA or PFNA, was found to have a positive correlation between concentration and prostate cancer incidence. A cohort mortality study in workers exposed to PFOA found an association between exposure and malignant and nonmalignant renal disease.^81^ In another occupational exposure study, PFOA was found to be associated with prostate cancer but not with liver, pancreatic, or testicular cancers.^56^ However, in a population of adults living near a chemical plant in Ohio, an association was found between PFOA exposure and kidney and testicular cancers.^82^ These cancers were also implicated in a similar association study conducted in West Virginia.^83^ In this analysis, PFOA serum levels were associated with not only kidney and testicular cancers but also prostate and ovarian cancers and non-Hodgkin’s lymphoma. A general population study in Denmark concluded that plasma levels of PFOA and PFOS were not linked to prostate, bladder, pancreatic, or liver cancer.^84^ Finally, PFAS were found, along with polychlorinated biphenyls, to be related to breast cancer risk in a Greenlandic Inuit population.^85^

The carcinogenic activity of PFOA in humans was recently reviewed by the International Agency for Research on Cancer (IARC).^86^ Approximately a dozen epidemiological studies have evaluated the possible cancer effects of PFOA in different exposure scenarios (e.g., occupational, community). IARC’s evaluation of these studies led to its conclusion that PFOA was possibly carcinogenic to humans (Group 2B) on the basis of limited evidence found in humans of associations with cancer of the testis and kidney and limited evidence in animals.^86^

## Genetic Toxicity

The genetic toxicity of PFHxA, PFOA, PFNA, and PFDA has been evaluated in bacterial mutagenicity assays and in vitro tests using human and rodent cells. PFOA and PFDA have also been evaluated in a limited number of in vivo genotoxicity tests. All four chemicals were negative in tests for bacterial mutagenicity. PFOA, PFNA, and PFDA showed mixed, primarily positive or primarily negative results, respectively, when tested in vitro using mammalian cell assays. Little is known about the genetic toxicity of PFHxA in mammalian cells. With regard to in vivo studies, a weak response was observed for PFOA and negative responses were observed for PFDA.

PFHxA, PFOA, PFNA, and PFDA have been shown to be negative in bacterial mutagenicity assays. PFHxA, PFOA, PFNA, and PFDA were not mutagenic when tested in Salmonella typhimurium strains TA98, TA100, TA1535, TA1537, and TA1538 in the absence or presence of rat liver metabolic enzymes (S9 mix) at concentrations up to 20 µmol/plate (PFHxA) or 5 µmol/plate (PFOA, PFNA, and PFDA).^87^ Sodium perfluorohexanoate, at concentrations ranging from 333 to 5,000 µg/plate, was negative when tested in S. typhimurium strains TA98, TA100, TA1535, and TA1537 and Escherichia coli WP2 uvrA in the absence or presence of S9 mix.^43^ PFOA tested at concentrations up to 500 µM/plate was negative in S. typhimurium strains TA98, TA100, TA102, and TA104 in the absence or presence of S9 mix.^88^ PFDA was negative when tested in S. typhimurium strains TA98, TA100, TA1537, and TA1538 at concentrations ranging from 333 to 10,000 µg/plate (without S9 mix) or 33.3 to 10,000 µg/plate (with S9 mix).^89^ PFDA was also negative when tested in S. typhimurium strains TA98 and TA1537 in the presence of S9 mix at notably high concentrations of 1, 10, or 100 g/plate.^90^

In comet assay experiments using human hepatocellular carcinoma (HepG2) cells, PFOA and PFNA, but not PFDA, induced significant increases in DNA damage at concentrations ranging from 0.2 to 20 µM for 24 hours,^91^ and PFOA induced significant, dose-dependent increases in DNA damage at concentrations ranging from 50 to 400 µM.^92^ In contrast, negative results were reported with PFOA (5 to 400 µM for 1 or 24 hours) in a comet assay in HepG2 cells^93^; however, these authors reported using a relatively high final concentration of dimethyl sulfoxide (DMSO) (2.5%) for their experiments, which may have been a factor in the lack of observed response. DMSO is a known scavenger of free radicals and can protect DNA from oxidative damage.^94^ In human lymphoblastoid TK6 cells, exposure to 0.25 or 0.5 mg/mL PFOA for 2 hours produced small but significant increases in DNA damage in the comet assay and in 8-hydroxy-2ʹ-deoxyguanosine DNA adducts (per 10^5^ dG) as detected using high-performance liquid chromatography (HPLC)-mass spectrometry (MS).^95^ Similar results were obtained for PFNA when tested at 0.125 or 0.25 mg/mL.^95^ Exposure to PFOA at concentrations up to 300 µM for 5 or 24 hours did not induce DNA damage in Syrian hamster embryo cells as measured using the comet assay.^96^ Negative results were also reported for the comet assay when freshly isolated Wistar rat testicular cells were exposed to 100 or 300 µM PFOA for 24 hours; however, a significant increase in DNA damage was observed when testicular cells were exposed to 300 µM PFNA for 24 hours.^97^ PFHxA has not been tested in the in vitro comet assay.

Significant, dose-dependent increases in micronuclei were observed in HepG2 cells exposed to PFOA for 24 hours at concentrations ranging from 50 to 400 µM.^92^ Micronuclei were not significantly increased in HepG2 cells exposed to PFOA for 24 hours at concentrations ranging from 5 to 400 µM^93^; however, Florentin et al.^93^ reported a high baseline for micronuclei and use of a relatively high final concentration of DMSO (2.5%) for their experiments. PFHxA, PFOA, PFNA, and PFDA did not significantly increase micronuclei in Chinese hamster lung fibroblast V79 cells when exposed to concentrations of 100 µM (PFHxA) or 10 µM (PFOA, PFNA, and PFDA) for 3 hours in the absence or presence of S9 mix.^87^

Several additional studies assessed PFDA for mutagenicity and chromosomal damage in rodent cells. PFDA was not mutagenic in the Chinese hamster ovary (CHO)/HGPRT forward mutation assay when cells were exposed to concentrations ranging from 0.01 to 0.16 mg/mL in the absence of S9 mix or from 0.005 to 0.1 mg/mL in the presence of S9 mix.^89^ PFDA was also negative in the mouse lymphoma L5178Y/tk^+/-^ forward mutation assay after 24 hours of exposure at concentrations ranging from 0.01 to 100 µg/mL in the absence of S9 mix.^98^ Sister chromatid exchanges were not induced in CHO-WBL cells exposed to PFDA for 2.5 hours at concentrations ranging from 1.67 to 50 µg/mL in the absence of S9 mix or when exposed to PFDA for 2 hours at concentrations ranging from 5 to 167 µg/mL with S9 mix.^89^ No significant increases in chromosomal aberrations were observed in CHO-WBL cells after 7.25 hours of exposure to concentrations of PFDA ranging from 75 to 200 μg/mL in the absence of S9 mix. Chromosomal aberrations were also not induced in CHO-WBL cells after 2 hours of exposure to concentrations of PFDA ranging from 10 to 100 μg/mL in the presence of S9 mix and harvested approximately 8 hours after exposure; however, chromosomal aberrations were induced after 2 hours of exposure to 151 or 201 μg/mL PFDA in the presence of S9 mix when harvested approximately 18 hours after exposure.^89^

In a review of unpublished genetic toxicity test data generated in industry-sponsored studies, PFOA, tested as either an ammonium or sodium salt, was found to be negative in bacterial mutagenicity assays, in the CHO/HGPRT forward mutation assay, in the chromosomal aberration assay when performed using CHO cells or primary human lymphocytes, and in the mouse bone marrow micronucleus assay.^99^

One study in the published literature examined the genotoxicity of PFOA in vivo. Using HPLC and an electrochemical detector system, small increases in 8-hydroxy-2ʹ-deoxyguanosine DNA adducts (per 10^5^ dG) were detected in DNA obtained from the livers, but not the kidneys, of male F344 rats exposed to 0.02% PFOA in feed for 2 weeks or at 3, 5, or 8 days after a single intraperitoneal injection of 100 mg/kg.^100^ Increases in 8-hydroxy-2ʹ-deoxyguanosine (per 10^5^ dG) in DNA obtained from liver or kidney were not observed at one day after injection. Considering that oxidative damage to DNA typically undergoes rapid repair, the small increases in 8-hydroxy-2ʹ-deoxyguanosine that were detected by Takagi et al.^100^ several days after injection may not necessarily have been due to exposure to PFOA.

Two studies examined the genotoxicity of PFDA in vivo. Female Sprague Dawley rats were given single intraperitoneal injections of 10 mg/kg PFDA once a week for 2 or 8 weeks and liver tissue was analyzed for fatty acyl-CoA oxidase (FAO) activity, catalase activity, and 8-oxo-7,8-dihydroguanine DNA adducts (per 10^5^ dG).^90^ FAO activity was significantly increased at both time points; catalase activity was significantly increased at the 8-week time point, and liver weights were increased at both time points; however, 8-oxo-7,8-dihydroguanine DNA adducts were not increased at either time point. Unscheduled DNA synthesis was not induced in hepatocytes isolated from male Fischer 344 rats 16 hours after administration of a single dose of 5.5, 11, 22, or 44 mg/kg PFDA by oral gavage; however, S-phase replicative DNA synthesis was induced by PFDA in hepatocytes isolated at 16 and 48 hours.^89^

## Study Rationale

USEPA nominated the PFAS class for comparative toxicity evaluation to understand the relative toxicity of individual members of the class. Chemicals were selected by comparing newer replacement chemicals (PFHxA and perfluorobutane sulfonic acid) that are shorter in chain length to the older longer-chained PFAS (PFOA and PFOS) in addition to other environmental PFAS of varying exposure levels (perfluorohexane sulfonate, PFNA, and PFDA). The 28-day toxicity study design was used to evaluate multiple endpoints for each of these chemicals for comparison. Plasma concentrations of each PFAS were measured due to the wide range in kinetics of the individual chemicals across species and sexes. A PPARα positive control, Wyeth-14,643 (WY), was included to understand which PFAS toxicological findings were consistent with this mechanism of toxicity and which appear to be independent of this mechanism.

This study is part of a larger NTP program to evaluate PFAS chemicals, which has included an assessment of the contribution of perinatal exposure to PFOA chronic toxicity and carcinogenicity in rats^101^; evaluation of the toxicokinetics of seven PFAS chemicals after a single dose in rats^25^; and in vitro class evaluations of potential neurotoxicity, mitochondrial toxicity,^102^ and immunotoxicity^103,104^ with a follow-up in vivo immune toxicity study on perfluorodecanoic acid.^105^