# Appendix F Revision Listing

## F.1 2020 Erratum

An error was identified in the NTP Toxicity Report on Perfluoroalkyl Carboxylates (Perfluorohexanoic Acid, Perfluorooctanoic Acid, Perfluorononanoic Acid, and Perfluorodecanoic Acid) Administered by Gavage to Sprague Dawley (Hsd:Sprague Dawley SD) Rats (Toxicity Report 97). The conclusion for bacterial mutagenicity for perfluorooctanoic acid (PFOA) was equivocal and not negative for TA 98, as stated originally in the report. This error has been corrected in the abstract, summary table, results, and discussion of this report. [May 20, 2020]

The corrections made as part of the 2020 erratum, including the page numbers, are specified below.

Page xvi

PFOA was changed from negative in bacterial mutagenicity tests to equivocal in the Abstract, as follows:

Summary Table, page xxii

PFOA was changed from negative in bacterial mutagenicity tests to equivocal as follows:

Page 92

PFOA was changed from negative in bacterial mutagenicity tests to equivocal in the Results, as follows:

Page 113

PFOA was changed from negative in bacterial mutagenicity tests to equivocal in the Discussion, as follows:

Table B-2 , page B-3

PFOA was changed from negative in bacterial mutagenicity tests to equivocal in Table B-2, as follows:

## F.2 2022 Revisions

Errors were identified in the NTP Technical Report on the Toxicity Studies of Perfluoroalkyl Carboxylates (Perfluorohexanoic Acid, Perfluorooctanoic Acid, Perfluorononanoic Acid, and Perfluorodecanoic Acid) Administered by Gavage to Sprague Dawley (Hsd:Sprague Dawley SD) Rats (Toxicity Report 97). Revisions were made throughout the report to address transcription errors; corrections made in the report are specified below. [June 30, 2022]

### F.2.1 Abstract

Page xvi

The concentration of Tween^®^ 80 in water was corrected to read as follows:

Page xvi

Administered doses for PFOA and perfluorononanoic acid (PFNA) were corrected to read as follows:

Page xvi

Terminology related to bile acids and salts was changed to read “total bile acids” consistently throughout the report. Edits were made on pages xvi, 30, 40, 56, 70, 83, 110, and 111; in the Summary Tables; and in Tables 3, 7, 15, 22, 30, and 37.

Summary Table, page xviii

Administered doses for PFOA, PFNA, and perfluorodecanoic acid (PFDA) were corrected as follows:

Summary Table, page xix

Additional footnotes were added in the hematology section to better clarify findings that were dose-related but not toxicologically relevant. The table was adjusted as follows to improve readability and interpretation:

Summary Table, page xix

The direction of effect for sorbitol dehydrogenase (for PFDA) was corrected as follows:

Summary Table, page xx

The direction of effect for testosterone (for PFDA) was corrected as follows:

Summary Table, page xx

The terminology and direction of effect for nonneoplastic lesions of the liver (for PFNA) were corrected as follows:

Summary Table, page xxiv

The direction of effect for testosterone and total bile acids (for Wyeth-14,643) was corrected as follows:

### F.2.2 Materials and Methods

Page 12

The number of days that animals were quarantined was corrected as follows:

Table 3 , page 16

The number of days that animals were quarantined was corrected as follows:

Table 3 , page 17

The average age at necropsy was corrected as follows:

Table 3 , page 17

The number of room air changes for the animal room environment was corrected as follows:

Table 3 , page 18

The list of tissues examined at necropsy was corrected as follows:

### F.2.3 Results

Table 5 , page 26

Internal dose analysis tables for perfluorohexanoic acid (PFHxA) were rerun on January 17, 2019, using updated rules for rounding. The number of reported decimal places was changed from the tenths place to the ones place for plasma concentration and liver concentration to be consistent with the precision of actual data values. Additionally, the units for normalized plasma and liver concentrations were corrected. These changes to improve readability and interpretation are as follows:

Table 7 , page 28

Standard error values for total bile acids for the animals administered 250 mg/kg/day PFHxA were corrected as follows:

Page 35

The results text for relative kidney weight (for PFOA) was corrected as follows:

Table 13 , page 38

Internal dose analysis tables for PFOA were rerun on January 17, 2019, using updated rules for rounding. The number of reported decimal places was changed from the tenths place to the ones place for plasma concentration and liver concentration to be in line with the precision of actual data values. Additionally, the units for normalized plasma and liver concentrations were corrected. Footnotes were added to account for statistical findings reported in the table and edited to reflect the dosing regimen for the animals administered PFOA. These changes to improve readability and interpretation are as follows:

Page 40

The results text for creatine kinase (for PFOA) was revised to clarify toxicological relevance and to improve readability and interpretation as follows:

Page 45

The results text for bone marrow hypocellularity severity (for PFOA) was corrected as follows:

Table 18 , pages 46-47

Statistical results for lesions in the nose (for PFOA) in A) male and B) female rats were corrected as follows:

Table 20 , page 52

Internal dose analysis tables for PFNA were rerun on January 17, 2019, using updated rules for rounding. The number of reported decimal places was changed from reporting out to the tenth place to the one place for plasma concentration and liver concentration to be in line with the precision of actual data values. Additionally, the units for normalized plasma and liver concentrations were corrected and an abbreviation for below detection was removed from the footnotes. Footnotes were edited to reflect the dosing regimen for the animals administered PFNA. These changes to improve readability and interpretation were as follows:

Page 54

The results text for total protein and globulin concentrations (for PFNA) was corrected as follows:

Table 22 , pages 55-56

Terminology related to bile salts and acids was changed to read “Total Bile Acids” and statistical results for triiodothyronine (for PFNA) were corrected in the main table (A). An inapplicable footnote was removed from the table and footnotes were reordered as follows (B):

Page 58

The results text for epididymal weight (for PFNA) was corrected as follows:

Table 24 , page 58

The statistical results indicating p ≤ 0.01 for necropsy body weight (for PFNA) were added as follows:

Table 28 , page 66

Internal dose analysis tables for PFDA were rerun on January 17, 2019, using updated rules for rounding. The number of reported decimal places was changed from the tenths place to the ones place for plasma concentration and liver concentration to be in line with the precision of actual data values. Additionally, the units for normalized plasma and liver concentrations were corrected and a result below detection was corrected. Footnotes were edited to reflect the dosing regimen for the animals administered PFDA. These changes to improve readability and interpretation are as follows:

Page 67

The results text for adrenal gland weight (for PFDA) was corrected as follows:

Page 70

Terminology related to bile salts and acids was changed to read “total bile acid” and the results text for sorbitol dehydrogenase (for PFDA) was added as follows:

Table 30 , page 72

The values for female rat platelets (for PFDA) were added as follows:

Table 30 , page 73

The values for sorbitol dehydrogenase (for PFDA) were added and footnote f placement was adjusted as follows:

Page 74

The results text for testosterone (for PFDA) in male rats was corrected as follows:

Page 75

The results text for testosterone (for PFDA) in female rats was corrected as follows:

Table 34 , page 77

A duplicate double asterisk was removed to correctly reflect statistical results as follows:

Table 37 , page 83

Terminology related to bile salts and acids was changed to read “Total Bile Acids” and values for total triiodothyronine in A) male rats and total thyroxine and free thyroxine in B) female rats (for Wyeth-14,643) were added. A footnote was added to indicate the number of animals. Edits were made as follows:

Page 84

The results text for free thyroxine (for Wyeth-14,643) in female rats was added as follows:

Table 39 , page 85

The statistical results and associated footnotes for left cauda epididymis weight, left epididymis weight, and the relative number of spermatid heads (for Wyeth-14,643) were adjusted as follows:

Table 40 , page 86

The number of female rats weighed at study termination (for Wyeth-14,463) was corrected as follows:

Page 92

The results text for the micronucleus assay (for PFHxA) was adjusted as follows:

### F.2.4 Discussion

Page 111

The discussion text for total bile acids and bilirubin concentration was adjusted as follows:

Page 111

The concentration of PFOA was corrected as follows:

Figures 33 , 34 , 39 , 40 , pages 115–122

The x-axis labels for Figure 33a, c, e, and g (page 115); Figure 34a, c, e, and g (page 116); Figure 39a, c, e, and g (page 121); and Figure 40a, c, e, and g (page 122) were corrected from “Dose (mol/kg/day)” to “Dose (mmol/kg/day).” The change is shown as follows in Figure 33a:

### F.2.5 Appendix B

Table B-5 , page B-8

The statistical results for micronuclei data (for PFHxA) were corrected as follows:

Table B-6 , page B-9

The micronuclei data (for PFOA) were corrected as follows:

Table B-7 , page B-10

The statistical results for micronuclei data (for PFNA) were corrected as follows:

Table B-8 , page B-11

The statistical results for the micronuclei data (for PFDA) were corrected as follows:

Table B-9 , page B-12

The micronuclei data and statistical results (for Wyeth-14,643) were corrected as follows:

### F.2.6 Appendix E

Table E-1 , page E-2

The results for KRV testing in sentinel animals were added as follows:

### F.2.7 Reference Updates

Minor updates or corrections were made to the references listed below:

Reference 26: A correction was made to the authors to read “Huang MC, Dzierlenga AL, Robinson VG, Waidyanatha S, DeVito MJ, Eifrid MA, Granville CA, Gibbs ST, Blystone CR.”

Reference 62: A correction was made to the title to read “The navigation guide - evidence-based medicine meets environmental health: Systematic review of human evidence for PFOA effects on fetal growth.”

Reference 70: A correction was made to the publication date to read “updated March 2020, released 2021.”

Reference 96: A correction was made to the publication year and volume to read “2012; 19:2537-2549.”

Reference 111: A correction was made to add the volume number 28.

Reference 134: A correction was made to the DOI link to read https://dx.doi.org/10.1016/j.tox.2017.05.013

Reference 149: A correction was made to the volume and page numbers to read “volume III. London, UK: Elsevier; 2013. p. 2392-2492.”

Reference 158: A correction was made to the volume to read “volume III.”

References 9, 37, 119, 123, 125, and 145 were corrected to spell out each journal name.