# Appendix E Sentinel Animal Program

## E.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of chemical compounds. Under this program, the disease state of the rodents is monitored via serology on sera from extra (sentinel) animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For the toxicity studies of four perfluoroalkyl carboxylates, blood samples from the sentinel animals were collected, allowed to clot, and the serum was separated. All samples were processed appropriately with serology performed by the Research Animal Diagnostic Laboratory (RADIL, currently IDEXX BioResearch), University of Missouri, Columbia, MO, for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five rats per sex.

Table E-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Multiplex Fluorescent Immunoassay
KRV (Kilham Rat Virus) | End of quarantine
Mycoplasma pulmonis | End of quarantine
PVM (Pneumonia Virus of Mice) | End of quarantine
RCV/SDA (Rat Coronavirus/Sialodacryoadenitis Virus) | End of quarantine
RMV (Rat Minute Virus) | End of quarantine
RPV (Rat Parvovirus) | End of quarantine
RTV (Rat Theilovirus) | End of quarantine
Sendai | End of quarantine
TMEV (Theiler’s Murine Encephalomyelitis Virus) | End of quarantine
Toolan’s H-1 | End of quarantine

## E.2 Results

All test results were negative.