# Appendix D Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table D-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 22.26
Ground #2 Yellow Shelled Corn | 22.18
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 5.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table D-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table D-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 15.47 ± 1.05 | 14.1–16.5 | 3
Crude fat (% by weight) | 8.7 ± 0.10 | 8.6–8.8 | 3
Crude fiber (% by weight) | 9.73 ± 0.44 | 9.25–10.1 | 3
Ash (% by weight) | 4.96 ± 0.14 | 4.80–5.04 | 3
Amino Acids (% of total diet)
Arginine | 0.802 ± 0.075 | 0.67–0.97 | 28
Cystine | 0.220 ± 0.022 | 0.15–0.25 | 28
Glycine | 0.703 ± 0.038 | 0.62–0.80 | 28
Histidine | 0.342 ± 0.071 | 0.27–0.68 | 28
Isoleucine | 0.549 ± 0.041 | 0.43–0.66 | 28
Leucine | 1.097 ± 0.064 | 0.96–1.24 | 28
Lysine | 0.700 ± 0.106 | 0.31–0.86 | 28
Methionine | 0.410 ± 0.042 | 0.26–0.49 | 28
Phenylalanine | 0.623 ± 0.047 | 0.47–0.72 | 28
Threonine | 0.512 ± 0.042 | 0.43–0.61 | 28
Tryptophan | 0.155 ± 0.027 | 0.11–0.20 | 28
Tyrosine | 0.420 ± 0.066 | 0.28–0.54 | 28
Valine | 0.666 ± 0.040 | 0.55–0.73 | 28
Essential Fatty Acids (% of total diet)
Linoleic | 3.88 ± 0.455 | 1.89–4.55 | 28
Linolenic | 0.30 ± 0.065 | 0.007–0.368 | 28
Vitamins
Vitamin A (IU/kg) | 3,073 ± 49 | 2,520–3,450 | 3
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 2,543 ± 13,044 | 27.0–69,100 | 28
Thiamine (ppm)^b^ | 7.53 ± 0.51 | 7.1–8.1 | 3
Riboflavin (ppm) | 8.06 ± 2.83 | 4.20–17.50 | 28
Niacin (ppm) | 78.6 ± 8.26 | 66.4–98.2 | 28
Pantothenic acid (ppm) | 26.6 ± 11.22 | 17.4–81.0 | 28
Pyridoxine (ppm)^b^ | 9.78 ± 2.08 | 6.44–14.3 | 28
Folic acid (ppm) | 1.58 ± 0.44 | 1.15–3.27 | 28
Biotin (ppm) | 0.32 ± 0.09 | 0.20–0.704 | 28
Vitamin B_12_ (ppb) | 50.6 ± 35.5 | 18.3–174.0 | 28
Choline (ppm)^b^ | 2,615 ± 635 | 1,160–3,790 | 28
Minerals
Calcium (%) | 0.921 ± 0.021 | 0.906–0.945 | 3
Phosphorus (%) | 0.564 ± 0.017 | 0.549–0.582 | 3
Potassium (%) | 0.667 ± 0.030 | 0.626–0.733 | 28
Chloride (%) | 0.393 ± 0.045 | 0.300–0.517 | 28
Sodium (%) | 0.197 ± 0.026 | 0.160–0.283 | 28
Magnesium (%) | 0.217 ± 0.055 | 0.185–0.490 | 28
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 191.6 ± 36.8 | 135–311 | 28
Manganese (ppm) | 50.1 ± 9.59 | 21.0–73.1 | 28
Zinc (ppm) | 57.4 ± 26.0 | 43.3–184.0 | 28
Copper (ppm) | 7.53 ± 2.53 | 3.21–16.3 | 28
Iodine (ppm) | 0.531 ± 0.201 | 0.158–0.972 | 28
Chromium (ppm) | 0.684 ± 0.258 | 0.330–1.380 | 27
Cobalt (ppm) | 0.225 ± 0.154 | 0.086–0.864 | 26

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table D-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.1993 ± 0.047 | 0.16–0.25 | 3
Cadmium (ppm) | 0.0507 ± 0.006 | 0.050–0.051 | 3
Lead (ppm) | 0.072 ± 0.012 | 0.06–0.08 | 3
Mercury (ppm) | <0.02 | – | 3
Selenium (ppm) | 0.122 ± 0.081 | 0.029–0.177 | 3
Aflatoxins (ppb) | <5.00 | – | 3
Nitrate Nitrogen (ppm)^c^ | 12.27 ± 3.4 | 10.0–16.2 | 3
Nitrite Nitrogen (ppm)^c^ | 0.61 | – | 3
BHA (ppm)^d^ | <1.0 | – | 3
BHT (ppm)^d^ | <1.0 | – | 3
Aerobic Plate Count (CFU/g) | <10.0 | – | 3
Coliform (MPN/g) | 3.0 | – | 3
Escherichia coli (MPN/g) | <10.0 | – | 3
Salmonella (MPN/g) | Negative | – | 3
Total Nitrosoamines (ppb)^e^ | 10.7 ± 6.8 | 5.0–18.2 | 3
N-Nitrosodimethylamine (ppb)^e^ | 0.8 ± 0.7 | 0–1.3 | 3
N-Nitrosopyrrolidine (ppb)^e^ | 10 ± 6.2 | 5.0–17.0 | 3
Pesticides (ppm)
α-BHC | <0.01 | – | 3
β-BHC | <0.02 | – | 3
γ-BHC | <0.01 | – | 3
δ-BHC | <0.01 | – | 3
Heptachlor | <0.01 | – | 3
Aldrin | <0.01 | – | 3
Heptachlor Epoxide | <0.01 | – | 3
DDE | <0.01 | – | 3
DDD | <0.01 | – | 3
DDT | <0.01 | – | 3
HCB | <0.01 | – | 3
Mirex | <0.01 | – | 3
Methoxychlor | <0.05 | – | 3
Dieldrin | <0.01 | – | 3
Endrin | <0.01 | – | 3
Telodrin | <0.01 | – | 3
Chlordane | <0.05 | – | 3
Toxaphene | <0.10 | – | 3
Estimated PCBs | <0.20 | – | 3
Ronnel | <0.01 | – | 3
Ethion | <0.02 | – | 3
Trithion | <0.05 | – | 3
Diazinon | <0.10 | – | 3
Methyl Chlorpyrifos | 0.06 ± 0.033 | 0.02–0.08 | 3
Methyl Parathion | <0.02 | – | 3
Ethyl Parathion | <0.02 | – | 3
Malathion | 0.034 ± 0.016 | 0.02–0.051 | 3
Endosulfan I | <0.01 | – | 3
Endosulfan II | <0.01 | – | 3
Endosulfan Sulfate | <0.03 | – | 3

^a^ All samples were irradiated. CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.