# Appendix C Chemical Characterization and Dose Formulation Studies

## C.1 Procurement and Characterization

### C.1.1 Perfluoroalkyl Carboxylates and Wyeth-14,643

Perfluorohexanoic acid (PFHxA) was obtained from Matrix Scientific (Columbia, SC) in one lot (Q02G); perfluorooctanoic acid (PFOA) was obtained from Sigma-Aldrich (St. Louis, MO) in one lot (03427TH); perfluorononanoic acid (PFNA) was obtained from Oakwood Products, Inc. (West Columbia, SC) in one lot (D11G); perfluorodecanoic acid (PFDA) was obtained from Sigma-Aldrich in one lot (01820LE); and Wyeth-14,643 (WY) was obtained from Chem Syn Laboratories (Lenexa, KS) in one lot (91-314-72-07/91-314-100-33A); all lots were used in the 28-day gavage studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory and the study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the perfluoroalkyl carboxylate and WY studies are on file at the National Institute of Environmental Health Sciences.

Lot Q02G (PFHxA), a clear, colorless liquid; lot 03427TH (PFOA), white crystals; lot D11G (PFNA), a white, crystalline powder; lot 01820LE (PFDA), white, transparent wet crystals; and lot 91-314-72-07/91-314-100-33A (WY), a white powder, were identified using Fourier transform infrared (FTIR) spectroscopy, mass spectrometry (MS) (perfluoroalkyl carboxylates only), and proton (WY), carbon-13, and fluorine-19 (perfluoroalkyl carboxylates only) nuclear magnetic resonance (NMR) spectroscopy. The Advanced Chemistry Development (ACD) spectral prediction program was used to predict carbon-13 NMR spectra for each test article and proton NMR spectra for WY. Annotated fluorine-fluorine correlated spectroscopy (COSY) two-dimensional data were used to identify the fluorine-fluorine coupling within the perfluoroalkyl carboxylates by the observation of cross-peaks in each fluorine-19 NMR spectrum. For the WY molecule, COSY was used to identify proton-proton coupling, a distortionless enhancement by polarization transfer carbon-13 spectrum series was constructed to determine the types of carbon (methine, methylene, and methyl), and a proton-carbon-13 heteronuclear multiple quantum coherence two-dimensional spectrum was acquired to identify directly bonded protons and carbons. Spectra were in good agreement with the proposed structure of each test chemical, with ACD computer-predicted spectra, and with expected COSY-identified proton-proton and fluorine-fluorine coupling. Observed chemical shifts were in good agreement with those expected and reported for each test article. Representative IR spectra of lots Q02G (PFHxA), 03427TH (PFOA), D11G (PFNA), 01820LE (PFDA), and 91-314-72-07/91-314-100-33A (WY) are presented in Figure C-1, Figure C-2, Figure C-3, Figure C-4, and Figure C-5, respectively.

For the perfluoroalkyl carboxylates, the purities of lots Q02G, 03427TH, D11G, and 01820LE were determined by high-performance liquid chromatography (HPLC)/ion chromatography (IC) with suppressed conductivity (SC) detection (all lots except 01820LE), and gas chromatography (GC) with flame ionization detection (FID) and electron capture detection (ECD); in addition, GC/MS was used to confirm the identity of each perfluoroalkyl carboxylate test article and identify impurities within each lot. Additional GC/FID, GC/ECD, and GC/MS analyses were performed on lot D11G to screen it for selected volatile solvents. All GC analyses were performed on derivatized (methylated) aliquots of each perfluoroalkyl carboxylate. Differential scanning calorimetry (DSC) was used to determine the purities of lots 03427TH and D11G using a Perkin-Elmer (Shelton, CT) Diamond differential scanning calorimeter scanning 1°C per minute over the ranges of 25° to 65°C, and 50° to 85°C, respectively. In addition, Karl Fischer titration for lots Q02G and 03427TH was performed by Prevalere Life Sciences, Inc. (Whitesboro, NY) and similar analysis for lot D11G was performed by Galbraith Laboratories, Inc. (Knoxville, TN).

For WY, the purity of lot 91-314-72-07/91-314-100-33A was determined by HPLC with ultraviolet light (UV) detection and DSC as described for the perfluoroalkyl carboxylates over a range of 135° to 175°C.

For lot Q02G (PFHxA), Karl Fischer titration indicated 0.47% water. HPLC/IC/SC analysis using System A (Table C-1) indicated one major peak that was 99.6% of the total peak area and two reportable (areas ≥0.1% of the total peak area) impurities with a combined area of 0.37% of the total peak area. GC/FID analysis using System A (Table C-2) indicated one major peak (99.1%) and five reportable impurities with a combined area of 0.95% of the total peak area. GC/ECD analysis using System A showed that the impurities were likely fluorinated compounds. GC/MS analysis using System A confirmed the identity of the test article and indicated that one of the impurities representing 0.33% of the total was an isomer of PFHxA. The overall purity of lot Q02G was determined to be greater than 99%.

For lot 03427TH (PFOA), Karl Fischer titration indicated 0.24% water. DSC indicated an average purity of 98.96%. HPLC/IC/SC analysis using System B (Table C-1) indicated one major peak that was 98.8% of the total peak area and three reportable impurities with a combined area of 1.2% of the total peak area. GC/FID analysis using System A (Table C-2) indicated one major peak (98.3%) and four reportable impurities with a combined area of 1.66% of the total peak area. GC/ECD analysis using System A showed that the impurities were likely fluorinated compounds. GC/MS analysis using System A confirmed the identity of the test article and indicated that two of the impurities representing 1.04% of the total were isomers of PFOA. The overall purity of lot 03427TH was determined to be greater than 98%.

For lot D11G (PFNA), Karl Fischer titration indicated 0.29% water. DSC indicated an average purity of 99.5%. HPLC/IC/SC analysis using system B (Table C-1) indicated one major peak that was 98.5% of the total peak area and two reportable impurities with a combined area of 1.5% of the total peak area. GC/FID analysis using System A (Table C-2) indicated a purity of 100%. GC/ECD analysis using System A indicated a purity of 99.0% with six reportable impurities. GC/MS analysis using System A confirmed the identity of the test article and indicated the presence of perfluoroheptanoic acid as an impurity. GC/FID analysis using System B showed the presence of low concentrations of the nonhalogenated solvents (≤0.007%) hexane, diethyl ether, and acetone. GC/ECD analysis using System B showed the presence of low concentrations of the halogenated solvents (≤0.0009%) chloroform and carbon tetrachloride. The overall purity of lot D11G was determined to be greater than 98%.

For lot 01820LE (PFDA), GC/FID analysis using System A (Table C-2) indicated one major peak (97.2%) and 10 reportable impurities with a combined area of 2.8% of the total peak area. GC/ECD analysis using System A showed that the impurities were likely fluorinated compounds. GC/MS analysis using System A confirmed the identity of the test article and indicated that one of the impurities representing 0.59% of the total was an isomer of PFDA. The overall purity of lot 01820LE was determined to be greater than 97%.

For lot 91-314-72-07/91-314-100-33A (WY), HPLC/UV analysis using System C (Table C-1) indicated one major peak (99.4%) and two reportable impurities with a combined area of 0.64% of the total peak area. DSC indicated an average purity of 94.3%; this lower calculated purity compared to that shown by HPLC was considered an indication of thermal decomposition rather than impurity of the bulk chemical. The overall purity of lot 91-314-72-07/91-314-100-33A was determined to be greater than 99%.

Stability studies of lots Q02G (PFHxA) and D11G (PFNA) of the bulk chemicals were performed by the analytical chemistry laboratory using HPLC/IC/SC System A (Table C-1) and GC/ECD System A (Table C-2), respectively. Stability was confirmed for bulk chemical samples stored in sealed amber glass bottles at temperatures up to 60°C for at least 14 days. To ensure stability, all of the bulk chemicals were stored at room temperature in sealed opaque plastic containers (lots Q02G and D11G) or sealed amber glass bottles (lots 03427TH, 01820LE, and 91-314-72-07/91-314-100-33A. Reanalyses of the bulk chemicals were performed by the study laboratory on January 5, 2012 (lot Q02G), January 12, 2012 (lot 03427TH), January 10, 2012 (lot D11G), January 16, 2012 (lot 01820LE), and January 10, 2012 (lot 91-314-72-07/91-314-100-33A) (prior to the gavage studies) using GC/ECD System D (Table C-2) for PFHxA, GC/ECD System A for PFOA, PFNA, and PFDA, and HPLC/UV System C (Table C-1) for WY. No degradation of the bulk chemicals was detected.

### C.1.2 Tween^®^ 80

Tween 80 (polysorbate 80) was obtained from Spectrum Laboratory Products, Inc. (Gardena, CA), and was used at a 2% concentration as the vehicle in the 28-day gavage studies. The vehicle was prepared by mixing the appropriate amount of Tween 80 with deionized water in a calibrated carboy and stirring with an overhead stirrer until all the Tween 80 was dissolved.

## C.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing PFHxA, PFOA, PFNA, PFDA, or WY with 2% Tween 80 in deionized water to give the required concentrations (Table C-3). Each formulation pH was adjusted to between 6 and 8. The dose formulations were stored at room (PFHxA, PFOA, PFNA, and PFDA) or refrigerated (WY) temperatures in amber glass bottles sealed with Teflon^®^-lined lids for no more than 43 days.

Homogeneity studies of the 6.26 and 100 mg/mL dose formulations of PFHxA and a stability study of the 6.26 mg/mL dose formulation were performed by the analytical chemistry laboratory using GC/ECD System D (Table C-2). Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.05 mg/mL formulation and the 20 mg/mL dose formulation of PFOA and a stability study of a 0.05 mg/mL formulation were performed by the analytical chemistry laboratory using GC/ECD System D (Table C-2). These studies were performed on lot 02702EE (Sigma-Aldrich) which was not used in the animal studies. In addition, homogeneity and stability of a 0.05 mg/mL formulation of lot 03427TH were assessed by the analytical chemistry laboratory using the same GC/ECD system. Homogeneity was confirmed, and stability was confirmed for at least 42 days for formulations stored in amber glass bottles with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.12 mg/mL formulation and the 5 mg/mL dose formulation of PFNA and a stability study of a 0.12 mg/mL formulation were performed by the analytical chemistry laboratory using GC/ECD System A (Table C-2). Homogeneity was confirmed, and stability was confirmed for at least 43 days for formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.04 mg/mL formulation and the 0.5 mg/mL dose formulation of PFDA and a stability study of a 0.04 mg/mL formulation were performed by the analytical chemistry laboratory using GC/ECD System A (Table C-2). An additional stability study of the 0.0312 mg/mL dose formulation was performed by the study laboratory using the same GC/ECD system. Homogeneity was confirmed, and stability was confirmed for at least 42 (analytical chemistry laboratory) or 45 (study laboratory) days for formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of the 1.26 and 5 mg/mL dose formulations of WY and a stability study of the 1.26 mg/mL dose formulation were performed by the analytical chemistry laboratory using HPLC/UV System C (Table C-1). Homogeneity was confirmed, and stability was confirmed for at least 42 days for formulations stored in amber glass bottles sealed with Teflon^-^lined lids at refrigerated temperature and for at least 3 hours under simulated animal room conditions.

Analyses of the dose formulations for the 28-day studies of PFHxA, PFOA, PFNA, and PFDA were conducted once for each study by the study laboratory using GC/ECD Systems D, D, A, and A, respectively (Table C-2). HPLC/UV System C (Table C-1) was used to conduct similar analyses for the 28-day study of WY. All dose formulations for all five chemicals were within 10% of the target concentrations (Table C-4). Animal room samples of these dose formulations were also analyzed; with the exceptions of two of 10 samples for the PFOA study, all animal room samples for all five chemicals were within 10% of the target concentrations.

Table C-1 High-Performance Liquid Chromatography Systems Used in the 28-day Gavage Studies of Perfluoroalkyl Carboxylates and Wyeth-14,643^a^

Detection System | Column | Solvent System
System A
Suppressed Conductivity | IonPac™ NS1, 150 mm × 4 mm, 5 µm particle size (Dionex Corporation, Sunnyvale, CA) | A) 0.1 M NaOH in water, B) 70% isopropanol in water, and C) water (4% A:28% B:68% C), isocratic; flow rate 0.6 mL/minute
System B
Suppressed Conductivity | IonPac™ NS1, 150 mm × 4 mm, 5 µm particle size (Dionex Corporation) | A) 0.1 M NaOH in water, B) 70% isopropanol in water, and C) water; linear gradients from 1% A: 30% B: 69% C for 3 minutes, to 1% A: 43% B: 56% C in 14 minutes, held for 3 minutes, then to 1% A: 30% B: 69% C in 1 minute, held for 14 minutes; flow rate 0.6 mL/minute
System C
Ultraviolet (254 nm) Light | Inertsil^®^ ODS-2, 150 mm × 4.6 mm, 5 µm particle size (Phenomenex, Torrance, CA) | A) 7.5 mM heptanesulfonic acid (pH 3.4) in water:methanol (32:68), isocratic; flow rate 1 mL/minute

^a^ The high-performance liquid chromatographs were manufactured by Hitachi High-Technologies Science America, Inc. (Tokyo, Japan) (Systems A and B) or Agilent Technologies, Inc. (Santa Clara, CA) or Waters Corporation (Milford, MA) (System C).

Table C-2 Gas Chromatography Systems Used in the 28-day Gavage Studies of Perfluoroalkyl Carboxylates and Wyeth-14,643^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame Ionization, Electron Capture, or Mass Spectrometry with Electron Ionization | Rtx^®^-5, 30 m × 0.32 mm, 1.0 or 0.5 µm film (Restek, Bellefonte, PA) | Helium at ~1 mL/minute | 70°C for 2 minutes, then 7°C/minute to 240°C, held for 4 minutes
System B
Flame Ionization or Electron Capture | Rtx^®^-624, 30 m × 0.53 mm, 3.0 µm film (Restek) | Helium at ~5 mL/minute | 35°C for 14 minutes, then 15°C/minute to 40°C, held for 3 minutes, then 15°C/minute to 240°C, held for 2 minutes
System C
Mass Spectrometry with Electron Ionization | Rtx^®^ 624, 30 m × 0.32 mm, 1.8 µm film (Restek) | Helium at ~2 mL/minute | 35°C for 14 minutes, then 15°C/minute to 40°C, held for 3 minutes, then 15°C/minute to 240°C, held for 2 minutes
System D
Electron Capture | Rtx^®^-5, 30 m × 0.32 mm, 1.0 or 0.5 µm film (Restek) | Helium at ~1 mL/minute | 70°C for 3 minutes, then 5°C/minute to 120°C, then 15°C/minute to 240°C, held for 4 minutes

^a^ The gas chromatographs and mass spectrometer were manufactured by Agilent Technologies, Inc. (Palo Alto, CA).

Table C-3 Preparation and Storage of Dose Formulations in the 28-day Gavage Studies of Perfluoroalkyl Carboxylates and Wyeth-14,643

Perfluorohexanoic Acid | Perfluorooctanoic Acid | Perfluorononanoic Acid | Perfluorodecanoic Acid | Wyeth-14,643
Preparation
The appropriate amount of test article was weighed and quantitatively transferred into a calibrated mixing container containing a stir bar, and approximately 80% of the final total vehicle volume of 2% Tween^®^ 80 in deionized water was added to the mixing container; the formulation was stirred on a stir plate to wet the test article and then sonicated for 15 minutes. After sonication, the formulation was stirred on a stir plate for approximately 15 minutes. The pH was measured, and if necessary, it was adjusted to between 6 and 8 with 10 N, and/or 1 N, and/or 0.1 N NaOH; the formulation was then diluted to final volume with vehicle and stirred for an additional 15 minutes. | Same as perfluorohexanoic acid except the mixture was not stirred for 15 minutes following the 15-minute sonication. | Same as PFHxA | Same as PFHxA | The appropriate amount of Wyeth-14,643 was weighed and quantitatively transferred into a calibrated mixing container containing a stir bar, approximately 90% of the final total vehicle volume of 2% Tween 80 in deionized water was added to the mixing container, and the formulation was stirred on a stir plate and/or sonicated for approximately 15 minutes. If necessary, the pH was adjusted to between 6 and 8 with 10 N, and/or 1 N and/or 0.1 N NaOH; the formulation was then diluted to final volume with vehicle and stirred and/or sonicated for an additional 15 minutes.
Chemical Lot Number
Q02G | 03427TH | D11G | 01820LE | 91-314-72-07/91-314-100-33A
Maximum Storage Time
38 days | 43 days | 43 days | 42 days | 39 days
Storage Conditions
Stored in amber glass bottles sealed with Teflon^®^-lined lids at 25°C | Stored in amber glass bottles sealed with Teflon-lined lids at 25°C | Stored in amber glass bottles sealed with Teflon-lined lids at 25°C | Stored in amber glass bottles sealed with Teflon-lined lids at 25°C | Stored in amber glass bottles sealed with Teflon-lined lids at 5°C
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)

Table C-4 Results of Analyses of Dose Formulations Administered to Rats in the 28-day Gavage Studies of Perfluoroalkyl Carboxylates and Wyeth-14,643

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Perfluorohexanoic Acid
January 9, 2012 | January 11, 2012 | 6.26 | 6.36 | +2
| | 12.5 | 13.2 | +6
| | 25 | 25.8 | +3
| | 50 | 50.6 | +1
| | 100 | 103 | +3
| February 17, 2012^b^ | 6.26 | 6.29 | +1
| | 12.5 | 13.0 | +4
| | 25 | 25.4 | +2
| | 50 | 49.6 | −1
| | 100 | 99.0 | −1
Perfluorooctanoic Acid
January 17, 2012 | January 20, 2012 | 0.125 | 0.122 | −2
| | 0.25 | 0.269 | +8
| | 0.5 | 0.547 | +9
| | 1 | 1.03 | +3
| | 1.25 | 1.37 | +10
| | 2 | 2.19 | +10
| | 2.5 | 2.62 | +5
| | 5 | 5.48 | +10
| | 10 | 10.4 | +4
| | 20 | 19.6 | −2
| February 29, 2012^b^ | 0.125 | 0.137 | +10
| | 0.25 | 0.293 | +17
| | 0.5 | 0.578 | +16
| | 1 | 1.06 | +6
| | 1.25 | 1.30 | +4
| | 2 | 2.06 | +3
| | 2.5 | 2.53 | +1
| | 5 | 5.47 | +9
| | 10 | 10.6 | +6
| | 20 | 20.6 | +3
Perfluorononanoic Acid
January 19, 2012 | January 23, 2012 | 0.125 | 0.120 | ˗4
| | 0.25 | 0.260 | +4
| | 0.312 | 0.309 | −1
| | 0.5 | 0.501 | 0
| | 0.624 | 0.635 | +2
| | 1 | 1.06 | +6
| | 1.25 | 1.28 | +2
| | 2 | 2.04 | +2
| | 2.5 | 2.56 | +2
| | 5 | 5.08 | +2
| March 2, 2012^b^ | 0.125 | 0.123 | ˗2
| | 0.25 | 0.264 | +6
| | 0.312 | 0.320 | +3
| | 0.5 | 0.505 | +1
| | 0.624 | 0.625 | 0
| | 1 | 1.00 | 0
| | 1.25 | 1.30 | +4
| | 2 | 2.07 | +4
| | 2.5 | 2.57 | +3
| | 5 | 5.01 | 0
Perfluorodecanoic Acid
January 25, 2012 | January 26, 2012 | 0.0312 | 0.0317 | +2
| | 0.0624 | 0.0630 | +1
| | 0.125 | 0.127 | +2
| | 0.25 | 0.261 | +4
| | 0.5 | 0.486 | −3
| March 10, 2012^b^ | 0.0312 | 0.0306 | −2
| | 0.0624 | 0.0608 | −3
| | 0.125 | 0.124 | −1
| | 0.25 | 0.253 | +1
| | 0.5 | 0.502 | 0
Wyeth-14,643
January 16, 2012 | January 18, 2012 | 1.25 | 1.24 | −1
| | 2.5 | 2.48 | −1
| | 5 | 4.95 | −1
| March 1, 2012^b^ | 1.25 | 1.25 | 0
| | 2.5 | 2.49 | 0
| | 5 | 4.94 | −1

^a^ Results of duplicate analyses. Dosing volume for all studies = 5 mL/kg/day. One-half the perfluorohexanoic acid formulations were administered twice per day; perfluorooctanoic acid, perfluorononanoic acid, perfluorodecanoic acid, and Wyeth-14,643 formulations were administered once per day. For the perfluorohexanoic study, 6.26 mg/mL = 62.6 mg/kg/day, 12.5 mg/mL = 125 mg/kg/day, 25 mg/mL = 250 mg/kg/day, 50 mg/mL = 500 mg/kg/day, and 100 mg/mL = 1,000 mg/kg/day. For males in the perfluorooctanoic study, 0.125 mg/mL = 0.625 mg/kg/day, 0.25 mg/mL = 1.25 mg/kg/day, 0.5 mg/mL = 2.5 mg/kg/day, 1 mg/mL = 5 mg/kg/day and 2 mg/mL = 10 mg/kg/day. For females in the perfluorooctanoic study, 1.25 mg/mL = 6.25 mg/kg/day, 2.5 mg/mL = 12.5 mg/kg/day, 5 mg/mL = 25 mg/kg/day, 10 mg/mL = 50 mg/kg/day, and 20 mg/mL = 100 mg/kg/day. For males in the perfluorononanoic study, 0.125 mg/mL = 0.625 mg/kg/day, 0.25 mg/mL = 1.25 mg/kg/day, 0.5 mg/L = 2.5 mg/kg/day, 1 mg/mL = 5 mg/kg/day, and 2 mg/mL = 10 mg/kg/day. For females in the perfluorononanoic study, 0.312 mg/mL = 1.56 mg/kg/day, 0.624 mg/mL = 3.12 mg/kg/day, 1.25 mg/mL = 6.25 mg/kg/day, 2.5 mg/mL = 12.5 mg/kg/day, and 5 mg/mL = 25 mg/kg/day. For the perfluorodecanoic study, 0.0312 mg/mL = 0.156 mg/kg/day, 0.0624 mg/mL = 0.312 mg/kg/day, 0.125 mg/mL = 0.625 mg/kg/day, 0.25 mg/mL = 1.25 mg/kg/day, and 0.5 mg/mL = 2.5 mg/kg/day. For the Wyeth-14,643 study, 1.25 mg/mL = 6.25 mg/kg/day, 2.5 mg/mL = 12.5 mg/kg/day, and 5 mg/mL = 25 mg/kg/day.

^b^ Animal room samples.

Figure C-1

Fourier Transform Infrared Absorption Spectrum of Perfluorohexanoic Acid

Figure C-2

Fourier Transform Infrared Absorption Spectrum of Perfluorooctanoic Acid

Figure C-3

Fourier Transform Infrared Absorption Spectrum of Perfluorononanoic Acid

Figure C-4

Fourier Transform Infrared Absorption Spectrum of Perfluorodecanoic Acid

Figure C-5

Fourier Transform Infrared Absorption Spectrum of Wyeth-14,643