# Appendix B Genetic Toxicology

Table B-1 Mutagenicity of Perfluorohexanoic Acid in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 44 ± 0 | 50 ± 3 | 41 ± 3 | 54 ± 2
| 10 | 45 ± 5 | 44 ± 4
| 50 | 39 ± 3 | 35 ± 4
| 100 | 51 ± 3 | 59 ± 1 | 34 ± 3 | 57 ± 1
| 500 | 50 ± 7 | 30 ± 4 | 40 ± 8 | 46 ± 7
| 750 | 1 ± 0 | 19 ± 4
| 1,000 | | | 29 ± 3 | 54 ± 6
| 5,000 | | | 33 ± 4 | 61 ± 4
| 10,000 | | | 41 ± 3 | 56 ± 8
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control^b^ | | 691 ± 52 | 616 ± 33 | 674 ± 23 | 885 ± 34
TA98
| 0 | 15 ± 2 | 15 ± 2 | 19 ± 3 | 17 ± 3
| 10 | 12 ± 2 | 7 ± 0
| 50 | 9 ± 1 | 7 ± 2
| 100 | 15 ± 3 | 14 ± 2 | 15 ± 3 | 13 ± 1
| 500 | 15 ± 2 | 12 ± 1 | 15 ± 1 | 15 ± 3
| 750 | 10 ± 2 | 24 ± 15
| 1,000 | | | 21 ± 3 | 20 ± 2
| 5,000 | | | 18 ± 2 | 17 ± 1
| 10,000 | | | 13 ± 2 | 18 ± 2
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 626 ± 8 | 449 ± 53 | 937 ± 50 | 910 ± 127
Escherichia coli WP2 uvrA/pKM101
| 0 | 190 ± 6 | 188 ± 10 | 230 ± 13 | 125 ± 5
| 100 | 209 ± 8 | 198 ± 2 | 240 ± 14 | 138 ± 1
| 500 | 173 ± 16 | 144 ± 9 | 245 ± 6 | 134 ± 5
| 1,000 | 135 ± 4 | 98 ± 7 | 256 ± 7 | 125 ± 6.3
| 2,000 | 46 ± 11 | 61 ± 6
| 3,000 | 0 ± 0
| 5,000 | | | 246 ± 6 | 121 ± 11
| 10,000 | | | 255 ± 22 | 131 ± 4
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 736 ± 15 | 833 ± 54 | 786 ± 29 | 726 ± 14

^a^ Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table B-2 Mutagenicity of Perfluorooctanoic Acid in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 44 ± 7 | 51 ± 5 | | 49 ± 3 | 47 ± 3 | 54 ± 6
| 100 | 44 ± 3 | 62 ± 2 | | | | 60 ± 2
| 250 | 50 ± 4 | 52 ± 5 | | | | 64 ± 4
| 500 | 50 ± 7 | 56 ± 2 | | 53 ± 3 | 34 ± 5 | 68 ± 5
| 750 | 26 ± 2 | 50 ± 6
| 1,000 | 27 ± 5 | 34 ± 5 | | 54 ± 1 | 36 ± 4 | 53 ± 4
| 2,000 | | | | 54 ± 2 | 34 ± 5 | 32 ± 4
| 3,500 | | | | 45 ± 4 | 41 ± 5
| 5,000 | | | | 36 ± 7 | 38 ± 1
Trial Summary | | Negative | Negative | – | Negative | Negative | Negative
Positive Control^b^ | | 385 ± 4 | 377 ± 22 | – | 985 ± 39 | 648 ± 21 | 831 ± 93
TA98
| 0 | 14 ± 1 | 12 ± 1 | 21 ± 1 | 13 ± 1 | 26 ± 1 | 30 ± 2
| 100 | 28 ± 0 | 17 ± 4
| 250 | 30 ± 5 | 25 ± 3
| 500 | 34 ± 2 | 18 ± 2 | 20 ± 4 | 48 ± 6 | 30 ± 3 | 33 ± 1
| 750 | 34 ± 2 | 28 ± 8
| 1,000 | 24 ± 4 | 18 ± 0 | 20 ± 2 | 39 ± 3 | 24 ± 1 | 18 ± 1
| 2,000 | | | Toxic | 42 ± 2 | 24 ± 6 | 20 ± 3
| 3,500 | | | Toxic | 42 ± 4 | 22 ± 2 | 19 ± 1
| 5,000 | | | Toxic | 41 ± 6 | 21 ± 2 | 17 ± 0
Trial Summary | | Positive | Equivocal | Negative | Positive | Negative | Negative
Positive Control | | 170 ± 6 | 427 ± 4 | 874 ± 29 | 500 ± 28 | 826 ± 50 | 1,533 ± 29
Escherichia coli WP2 uvrA/pKM101
| 0 | 178 ± 17 | 200 ± 13 | 164 ± 20 | 242 ± 9 | 246 ± 17
| 10 | | | 146 ± 9
| 25 | | | 131 ± 9
| 50 | | | 143 ± 5
| 100 | 206 ± 14 | 234 ± 4 | 148 ± 2
| 250 | 197 ± 9 | 208 ± 10 | 147 ± 10
| 500 | 183 ± 7 | 194 ± 7
| 750 | 149 ± 17 | 176 ± 9
| 1,000 | 101 ± 16 | 183 ± 4 | | 242 ± 4 | 243 ± 9
| 2,500 | | | | 252 ± 11 | 265 ± 7
| 5,000 | | | | 234 ± 8 | 262 ± 8
| 7,500 | | | | 246 ± 18 | 241 ± 14
| 10,000 | | | | 214 ± 8 | 265 ± 6
Trial Summary | | Negative | Negative | Negative | Negative | Negative | –
Positive Control | | 768 ± 5 | 663 ± 46 | 2,139 ± 53 | 752 ± 7 | 713 ± 18 | –

^a^ Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table B-3 Mutagenicity of Perfluorononanoic Acid in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | Without S9 | With 10% Rat S9 | | | With 10% Rat S9
TA100
| 0 | 61 ± 3 | 50 ± 4 | | 73 ± 5 | | | 53 ± 3
| 50 | 59 ± 6 | 55 ± 6
| 100 | 58 ± 7 | 52 ± 3 | | 53 ± 3 | | | 50 ± 3
| 200 | 62 ± 6 | 53 ± 1 | | 52 ± 4 | | | 44 ± 1
| 350 | 61 ± 6 | 53 ± 6
| 500 | 55 ± 6 | 47 ± 7 | | 53 ± 4 | | | 51 ± 2
| 750 | | | | 68 ± 4 | | | 39 ± 1
| 1,000 | | | | 60 ± 10 | | | 55 ± 5
Trial Summary | | Negative | Negative | – | Negative | | | Negative
Positive Control^b^ | | 269 ± 3 | 211 ± 11 | – | 915 ± 29 | | | 719 ± 49
TA98
| 0 | 17 ± 3 | 18 ± 4 | | 18 ± 3 | | | 28 ± 4
| 50 | 10 ± 2 | 13 ± 1
| 100 | 13 ± 1 | 14 ± 2 | | 18 ± 1 | | | 23 ± 5
| 200 | 9 ± 1 | 12 ± 2 | | 10 ± 1 | | | 22 ± 3
| 350 | 10 ± 1 | 16 ± 2
| 500 | 2 ± 1 | 11 ± 1 | | 9 ± 2 | | | 24 ± 2
| 750 | | | | 7 ± 1 | | | 22 ± 2
| 1,000 | | | | 8 ± 1 | | | 22 ± 1
Trial Summary | | Negative | Negative | – | Negative | | | Negative
Positive Control | | 218 ± 23 | 516 ± 14 | – | 992 ± 27 | | | 790 ± 13
Escherichia coli WP2 uvrA/pKM101
| 0 | 226 ± 9 | 233 ± 11 | 204 ± 6 | | 248 ± 8 | 257 ± 5
| 10 | | | 209 ± 7
| 50 | | | 153 ± 16
| 100 | | | 184 ± 4
| 500 | 235 ± 10 | 213 ± 11 | 175 ± 10
| 1,000 | 196 ± 13 | 188 ± 14 | 194 ± 9 | | 285 ± 3 | 238 ± 10
| 2,000 | 137 ± 3 | 143 ± 7
| 2,500 | | | | | 277 ± 4 | 256 ± 13
| 3,500 | 73 ± 4 | 190 ± 84
| 5,000 | 5 ± 4 | 121 ± 51 | | | 276 ± 8 | 233 ± 24
| 7,500 | | | | | 294 ± 16 | 218 ± 3
| 10,000 | | | | | 296 ± 11 | 230 ± 34
Trial Summary | | Negative | Negative | Negative | | Negative | Negative
Positive Control | | 624 ± 8 | 554 ± 111 | 1,237 ± 37 | | 765 ± 37 | 728 ± 92

^a^ Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table B-4 Mutagenicity of Perfluorodecanoic Acid in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 61 ± 3 | 50 ± 4 | | 73 ± 5 | 53 ± 3
| 100 | 53 ± 2 | 49 ± 6
| 250 | 34 ± 5 | 43 ± 4
| 500 | 41 ± 3 | 41 ± 4
| 750 | 40 ± 2 | 42 ± 3
| 1,000 | 38 ± 6 | 41 ± 6 | | 45 ± 3 | 34 ± 2
| 2,500 | | | | 47 ± 3 | 34 ± 6
| 5,000 | | | | 50 ± 9 | 38 ± 7
| 7,500 | | | | 46 ± 4 | 38 ± 4
| 10,000 | | | | 51 ± 10 | 35 ± 6
Trial Summary | | Negative | Negative | – | Negative | Negative
Positive Control^b^ | | 269 ± 3 | 211 ± 11 | – | 915 ± 29 | 719 ± 49
TA98
| 0 | 17 ± 3 | 18 ± 4 | 15 ± 1 | 18 ± 3 | 28 ± 4
| 100 | 14 ± 2 | 18 ± 2 | 19 ± 1
| 250 | 11 ± 1 | 15 ± 2 | 13 ± 1
| 500 | 8 ± 2 | 17 ± 2 | 16 ± 1
| 750 | 15 ± 2 | 13 ± 3 | 13 ± 3
| 1,000 | 13 ± 1 | 16 ± 3 | 16 ± 1 | 19 ± 3 | 18 ± 2
| 2,500 | | | | 15 ± 3 | 17 ± 1
| 5,000 | | | | 14 ± 2 | 23 ± 1
| 7,500 | | | | 14 ± 2 | 13 ± 2
| 10,000 | | | | 13 ± 1 | 17 ± 2
Trial Summary | | Negative | Negative | Negative | Negative | Negative
Positive Control | | 218 ± 23 | 516 ± 14 | 529 ± 57 | 992 ± 27 | 790 ± 13
Escherichia coli WP2 uvrA/pKM101
| 0 | 226 ± 9 | 233 ± 11 | | 248 ± 8 | 257 ± 5
| 500 | 209 ± 22 | 190 ± 13
| 1,000 | 221 ± 11 | 166 ± 17 | | 262 ± 9 | 249 ± 13
| 2,000 | 149 ± 10 | 98 ± 14
| 2,500 | | | | 270 ± 13 | 250 ± 14
| 3,500 | 90 ± 15 | 61 ± 6
| 5,000 | 201 ± 66 | 137 ± 19 | | 277 ± 16 | 209 ± 13
| 7,500 | | | | 264 ± 10 | 209 ± 11
| 10,000 | | | | 272 ± 8 | 233 ± 11
Trial Summary | | Negative | Negative | – | Negative | Negative
Positive Control | | 624 ± 8 | 687 ± 34 | – | 765 ± 37 | 728 ± 92

^a^ Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table B-5 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Exposure to Perfluorohexanoic Acid by Gavage for 28 Days^a^

| Dose (mg/kg/day)^b^ | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^c^ | P Value^d^ | Micronucleated NCEs/1,000 NCEs^c^ | P Value^d^ | PCEs^c^ (%) | P Value^d^
Male
Vehicle Control^e^ | 0 | 5 | 0.57 ± 0.08 | | 0.13 ± 0.02 | | 1.06 ± 0.01
PFHxA | 62.6 | 5 | 0.51 ± 0.06 | 1.000 | 0.11 ± 0.01 | 1.000 | 1.02 ± 0.04 | 1.000
| 125 | 5 | 0.80 ± 0.10 | 0.280 | 0.09 ± 0.02 | 1.000 | 0.74 ± 0.08 | 1.000
| 250 | 5 | 0.45 ± 0.05 | 1.000 | 0.07 ± 0.02 | 1.000 | 1.19 ± 0.10 | 0.819
| 500 | 5 | 0.58 ± 0.04 | 1.000 | 0.10 ± 0.03 | 1.000 | 3.79 ± 1.33 | < 0.001
| 1,000 | 5 | 1.04 ± 0.18 | 0.066 | 0.18 ± 0.04 | 1.000 | 15.12 ± 3.17 | < 0.001
| | | p = 0.025^f^ | | p = 0.782 | | p < 0.001
Female
Vehicle Control | 0 | 5 | 0.68 ± 0.03 | | 0.06 ± 0.01 | | 0.76 ± 0.12
PFHxA | 62.6 | 5 | 0.75 ± 0.08 | 0.785 | 0.07 ± 0.01 | 1.000 | 0.70 ± 0.09 | 1.000
| 125 | 5 | 0.56 ± 0.08 | 0.861 | 0.06 ± 0.02 | 1.000 | 0.91 ± 0.13 | 0.465
| 250 | 5 | 0.48 ± 0.09 | 0.887 | 0.08 ± 0.03 | 1.000 | 1.30 ± 0.16 | 0.017
| 500 | 5 | 0.40 ± 0.07 | 0.899 | 0.04 ± 0.00 | 1.000 | 2.57 ± 0.58 | < 0.001
| 1,000 | 5 | 0.86 ± 0.16 | 0.117 | 0.18 ± 0.06 | 0.377 | 5.36 ± 0.65 | < 0.001
| | | p = 0.163 | | p = 0.450 | | p < 0.001

NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte; PFHxA = perfluorohexanoic acid.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^121^

^b^ One-half the dose was administered twice daily.

^c^ Mean ± standard error.

^d^ Pairwise comparison with the vehicle control group; dosed group values are significant at p ≤ 0.025 by Williams’ or Dunn’s test.

^e^ The vehicle control was 2% Tween^®^ 80 in deionized water.

^f^ Dose-related trend; significant at p ≤ 0.025 by linear regression or Jonckheere’s test.

Table B-6 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Exposure to Perfluorooctanoic Acid by Gavage for 28 Days^a^

| Dose (mg/kg/day) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Vehicle Control^d^ | 0 | 5 | 0.42 ± 0.05 | | 0.12 ± 0.01 | | 1.02 ± 0.05
PFOA | 0.625 | 5 | 0.73 ± 0.05 | 0.046 | 0.07 ± 0.01 | 0.994 | 0.79 ± 0.04 | 0.147
| 1.25 | 5 | 0.80 ± 0.15 | 0.043 | 0.09 ± 0.01 | 0.999 | 0.83 ± 0.04 | 0.175
| 2.5 | 5 | 0.81 ± 0.10 | 0.014 | 0.07 ± 0.01 | 0.999 | 0.80 ± 0.06 | 0.186
| 5 | 5 | 0.87 ± 0.06 | 0.001 | 0.07 ± 0.00 | 1.000 | 0.94 ± 0.15 | 0.190
| 10 | 5 | 0.64 ± 0.09 | 0.282 | 0.06 ± 0.01 | 1.000 | 0.95 ± 0.08 | 0.192
| | | p = 0.025^e^ | | p = 0.998 | | p = 0.530
Female
Vehicle Control | 0 | 5 | 0.65 ± 0.16 | | 0.05 ± 0.01 | | 0.97 ± 0.15
PFOA | 6.25 | 5 | 0.52 ± 0.05 | 0.708 | 0.04 ± 0.01 | 1.000 | 1.11 ± 0.07 | 1.000
| 12.5 | 5 | 0.68 ± 0.06 | 0.792 | 0.03 ± 0.00 | 1.000 | 0.88 ± 0.09 | 1.000
| 25 | 5 | 0.52 ± 0.12 | 0.824 | 0.02 ± 0.00 | 1.000 | 1.13 ± 0.14 | 1.000
| 50 | 5 | 0.53 ± 0.08 | 0.839 | 0.03 ± 0.00 | 1.000 | 1.15 ± 0.24 | 1.000
| 100 | 5 | 0.55 ± 0.07 | 0.851 | 0.04 ± 0.01 | 1.000 | 1.62 ± 0.17 | 0.089
| | | p = 0.740 | | p = 0.961 | | p = 0.048

NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte; PFOA = perfluorooctanoic acid.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^121^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at p ≤ 0.025 by Williams’ or Dunn’s test.

^d^ The vehicle control was 2% Tween^®^ 80 in deionized water.

^e^ Dose-related trend; significant at p ≤ 0.025 by linear regression or Jonckheere’s test.

Table B-7 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Exposure to Perfluorononanoic Acid by Gavage for 28 Days^a^

| Dose (mg/kg/day) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Vehicle Control^d^ | 0 | 5 | 0.99 ± 0.07 | | 0.29 ± 0.05 | | 1.08 ± 0.03
PFNA | 0.625 | 5 | 0.87 ± 0.10 | 0.614 | 0.26 ± 0.06 | 0.580 | 0.56 ± 0.03 | < 0.001
| 1.25 | 5 | 0.91 ± 0.24 | 0.703 | 0.27 ± 0.09 | 0.668 | 0.44 ± 0.05 | < 0.001
| 2.5 | 1 | 0.00 ± 0.00 | – | 0.00 ± 0.00 | – | 0.00 ± 0.00 | –
| | | p = 0.642^e^ | | p = 0.624 | | p < 0.001
Female
Vehicle Control | 0 | 5 | 0.84 ± 0.17 | | 0.14 ± 0.01 | | 1.44 ± 0.24
PFNA | 1.56 | 5 | 0.42 ± 0.05 | 1.000 | 0.05 ± 0.01 | 1.000 | 1.38 ± 0.08 | 1.000
| 3.12 | 5 | 0.46 ± 0.04 | 1.000 | 0.07 ± 0.01 | 1.000 | 1.11 ± 0.10 | 0.375
| 6.25 | 5 | 0.72 ± 0.06 | 1.000 | 0.06 ± 0.01 | 1.000 | 1.26 ± 0.08 | 0.400
| | | p = 0.318 | | p = 0.991 | | p = 0.425

NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte; PFNA=perfluorononanoic acid.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^121^ No data available for 5 or 10 mg/kg/day males or 12.5 or 25 mg/kg/day females due to high mortality.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group when there were at least two samples; dosed group values are significant at p ≤ 0.025 by Williams’ or Dunn’s test.

^d^ The vehicle control was 2% Tween^®^ 80 in deionized water.

^e^ Dose-related trend; significant at p ≤ 0.025 by linear regression or Jonckheere’s test.

Table B-8 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Exposure to Perfluorodecanoic Acid by Gavage for 28 Days^a^

| Dose (mg/kg/day) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Vehicle Control^d^ | 0 | 5 | 0.67 ± 0.11 | | 0.09 ± 0.02 | | 0.82 ± 0.13
PFDA | 0.156 | 5 | 0.65 ± 0.05 | 0.563 | 0.07 ± 0.02 | 0.641 | 0.79 ± 0.06 | 1.000
| 0.312 | 5 | 0.64 ± 0.15 | 0.651 | 0.10 ± 0.03 | 0.714 | 0.83 ± 0.03 | 1.000
| 0.625 | 5 | 0.62 ± 0.05 | 0.687 | 0.09 ± 0.02 | 0.749 | 0.72 ± 0.07 | 0.829
| 1.25 | 5 | 0.78 ± 0.09 | 0.331 | 0.06 ± 0.01 | 0.768 | 0.28 ± 0.06 | < 0.001
| 2.5 | 3 | 1.17 ± 0.22 | 0.004 | 0.08 ± 0.01 | 0.798 | 0.13 ± 0.04 | < 0.001
| | | p = 0.001^e^ | | p = 0.738 | | p < 0.001
Female
Vehicle Control | 0 | 5 | 0.50 ± 0.03 | | 0.06 ± 0.01 | | 1.06 ± 0.18
PFDA | 0.156 | 5 | 0.38 ± 0.05 | 0.689 | 0.05 ± 0.01 | 0.967 | 1.00 ± 0.09 | 1.000
| 0.312 | 5 | 0.49 ± 0.11 | 0.618 | 0.04 ± 0.00 | 0.987 | 1.12 ± 0.10 | 1.000
| 0.625 | 5 | 0.62 ± 0.04 | 0.292 | 0.03 ± 0.00 | 0.991 | 1.10 ± 0.05 | 1.000
| 1.25 | 5 | 0.56 ± 0.14 | 0.303 | 0.04 ± 0.01 | 0.994 | 0.36 ± 0.03 | 0.000
| | | p = 0.106 | | p = 0.965 | | p ≤ 0.001

NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte; PFDA = perfluorodecanoic acid.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^121^ No data are available for 2.5 mg/kg/day females because no samples were received by ILS, Inc. from the study laboratory.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at p ≤ 0.025 by Williams’ or Dunn’s test.

^d^ The vehicle control was 2% Tween^®^ 80 in deionized water.

^e^ Dose-related trend; significant at p ≤ 0.025 by linear regression or Jonckheere’s test.

Table B-9 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Exposure to Wyeth-14,643 by Gavage for 28 Days^a^

| Dose (mg/kg/day) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Vehicle Control^d^ | | 5 | 0.51 ± 0.09 | | 0.08 ± 0.01 | | 0.97 ± 0.05
WY | 6.25 | 5 | 0.80 ± 0.06 | 0.055 | 0.16 ± 0.04 | 0.131 | 0.76 ± 0.02 | 1.000
| 12.5 | 5 | 0.86 ± 0.20 | 0.050 | 0.29 ± 0.13 | 0.032 | 1.18 ± 0.15 | 0.236
| 25 | 5 | 0.79 ± 0.08 | 0.053 | 0.12 ± 0.03 | 0.465 | 1.08 ± 0.07 | 0.249
| | | p = 0.096^e^ | | p = 0.126 | | p = 0.110
Female
Vehicle Control | | 5 | 0.47 ± 0.09 | | 0.04 ± 0.00 | | 1.10 ± 0.09
WY | 6.25 | 5 | 0.73 ± 0.13 | 0.105 | 0.06 ± 0.01 | 0.056 | 0.95 ± 0.09 | 1.000
| 12.5 | 5 | 0.58 ± 0.07 | 0.127 | 0.04 ± 0.01 | 0.890 | 1.29 ± 0.07 | 0.187
| 25 | 5 | 0.62 ± 0.06 | 0.135 | 0.04 ± 0.01 | 0.946 | 1.40 ± 0.11 | 0.053
| | | p = 0.292 | | p = 0.447 | | p = 0.013

NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte; WY = Wyeth-14,643.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^121^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at p ≤ 0.025 by Williams’ or Dunn’s test.

^d^ The vehicle control was 2% Tween^®^ 80 in deionized water.

^e^ Dose-related trend; significant at p ≤ 0.025 by linear regression or Jonckheere’s test.