# Appendix A Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table A-1 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Perfluorohexanoic Acid by Gavage for 28 Days

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 125 mg/kg/day vs. vehicle controls | <0.001 | –
Overall Tests | 250 mg/kg/day vs. vehicle controls | <0.001 | –
Overall Tests | 500 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Estrus | Overall | <0.001
Extended Estrus | 125 mg/kg/day vs. vehicle controls | 0.006 | –
Extended Estrus | 250 mg/kg/day vs. vehicle controls | 0.002 | –
Extended Estrus | 500 mg/kg/day vs. vehicle controls | 0.022 | –
Extended Diestrus | Overall | <0.001
Extended Diestrus | 125 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Diestrus | 250 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Diestrus | 500 mg/kg/day vs. vehicle controls | 0.003 | N
Extended Metestrus | Overall | 1
Extended Metestrus | 125 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 250 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 500 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 125 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 250 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 500 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | Overall | 0.998
Skipped Estrus | 125 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | 250 mg/kg/day vs. vehicle controls | 0.869 | –
Skipped Estrus | 500 mg/kg/day vs. vehicle controls | 0.935 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | 125 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 250 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 500 mg/kg/day vs. vehicle controls | 1 | –
Summary of Significant Groups
Overall Tests | 125 mg/kg/day vs. vehicle controls | <0.001 | –
Overall Tests | 250 mg/kg/day vs. vehicle controls | <0.001 | –
Overall Tests | 500 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Estrus | 125 mg/kg/day vs. vehicle controls | 0.006 | –
Extended Estrus | 250 mg/kg/day vs. vehicle controls | 0.002 | –
Extended Estrus | 500 mg/kg/day vs. vehicle controls | 0.022 | –
Extended Diestrus | 125 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Diestrus | 250 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Diestrus | 500 mg/kg/day vs. vehicle controls | 0.003 | N

^a^ N indicates that the dosed group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dosed group had more departures from normal cycling than did the vehicle control group. One-half the dose was administered twice daily. The overall tests consider all six types of departures from normal cycling. The overall comparison tests for equal transitional probabilities across all dose groups.

Table A-2 Estrous Cycle Characterization for Female Rats in the 28-day Gavage Study of Perfluorooctanoic Acid^a^

| Vehicle Control | 25 mg/kg/day | 50 mg/kg/day | 100 mg/kg/day
Number Weighed at Necropsy | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 227 ± 5 | 219 ± 2 | 221 ± 3 | 215 ± 4
Proportion of Regular Cycling Females^b^ | 10/10 | 10/10 | 10/10 | 7/9
Estrous Cycle Length (days) | 5.0 ± 0.09 | 4.9 ± 0.18 | 4.7 ± 0.15 | 4.8 ± 0.15
Estrous Stages (% of cycle)
Diestrus | 51.9 | 55.6 | 51.9 | 62.5
Proestrus | 9.4 | 10.6 | 10.0 | 4.2
Estrus | 36.9 | 29.4 | 33.8 | 32.6
Metestrus | 1.3 | 4.4 | 4.4 | 0.7
Uncertain | 0.6 | 0.0 | 0.0 | 0.0

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated that 100 mg/kg/day females had extended diestrus.

^b^ Number of females with a regular cycle/number of females cycling.

Table A-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Perfluorooctanoic Acid by Gavage for 28 Days

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 25 mg/kg/day vs. vehicle controls | 0.086 | N
Overall Tests | 50 mg/kg/day vs. vehicle controls | 0.806 | N
Overall Tests | 100 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Estrus | Overall | 0.086
Extended Estrus | 25 mg/kg/day vs. vehicle controls | 0.007 | N
Extended Estrus | 50 mg/kg/day vs. vehicle controls | 0.767 | N
Extended Estrus | 100 mg/kg/day vs. vehicle controls | 0.733 | N
Extended Diestrus | Overall | <0.001
Extended Diestrus | 25 mg/kg/day vs. vehicle controls | 0.191 | –
Extended Diestrus | 50 mg/kg/day vs. vehicle controls | 0.943 | –
Extended Diestrus | 100 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 50 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 100 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 50 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 100 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | 50 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | 100 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 50 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 100 mg/kg/day vs. vehicle controls | 1 | –
Summary of Significant Groups
Overall Tests | 100 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Estrus | 25 mg/kg/day vs. vehicle controls | 0.007 | N
Extended Diestrus | 100 mg/kg/day vs. vehicle controls | <0.001 | –

^a^ N indicates that the dosed group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dosed group had more departures from normal cycling than did the vehicle control group. The Overall Tests consider all six types of departures from normal cycling. The overall comparison tests for equal transitional probabilities across all dose groups.

Table A-4 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Perfluorononanoic Acid by Gavage for 28 Days

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 1.56 mg/kg/day vs. vehicle controls | 0.001 | N
Overall Tests | 3.12 mg/kg/day vs. vehicle controls | 0.001 | N
Overall Tests | 6.25 mg/kg/day vs. vehicle controls | 0.026 | N
Extended Estrus | Overall | 0.312
Extended Estrus | 1.56 mg/kg/day vs. vehicle controls | 0.624 | N
Extended Estrus | 3.12 mg/kg/day vs. vehicle controls | 0.469 | N
Extended Estrus | 6.25 mg/kg/day vs. vehicle controls | 0.098 | N
Extended Diestrus | Overall | <0.001
Extended Diestrus | 1.56 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Diestrus | 3.12 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Diestrus | 6.25 mg/kg/day vs. vehicle controls | 0.192 | –
Extended Metestrus | Overall | 0.985
Extended Metestrus | 1.56 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 3.12 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 6.25 mg/kg/day vs. vehicle controls | 0.604 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 1.56 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 3.12 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 6.25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | 1.56 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | 3.12 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | 6.25 mg/kg/day vs. vehicle controls | 0.935 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | 1.56 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 3.12 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 6.25 mg/kg/day vs. vehicle controls | 1 | –
Summary of Significant Groups
Overall Tests | 1.56 mg/kg/day vs. vehicle controls | 0.001 | N
Overall Tests | 3.12 mg/kg/day vs. vehicle controls | 0.001 | N
Overall Tests | 6.25 mg/kg/day vs. vehicle controls | 0.026 | N
Extended Diestrus | 1.56 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Diestrus | 3.12 mg/kg/day vs. vehicle controls | <0.001 | –

^a^ N indicates that the dosed group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dosed group had more departures from normal cycling than did the vehicle control group. The Overall Tests consider all six types of departures from normal cycling. The overall comparison tests for equal transitional probabilities across all dose groups.

Table A-5 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Perfluorodecanoic Acid by Gavage for 28 Days

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 0.625 mg/kg/day vs. vehicle controls | 0.054 | N
Overall Tests | 1.25 mg/kg/day vs. vehicle controls | <0.001 | N
Overall Tests | 2.5 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Estrus | Overall | <0.001
Extended Estrus | 0.625 mg/kg/day vs. vehicle controls | 0.21 | N
Extended Estrus | 1.25 mg/kg/day vs. vehicle controls | 0.003 | N
Extended Estrus | 2.5 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Diestrus | Overall | <0.001
Extended Diestrus | 0.625 mg/kg/day vs. vehicle controls | 0.065 | –
Extended Diestrus | 1.25 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Diestrus | 2.5 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 0.625 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 1.25 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 2.5 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 0.625 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 1.25 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 2.5 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | Overall | 0.555
Skipped Estrus | 0.625 mg/kg/day vs. vehicle controls | 0.973 | N
Skipped Estrus | 1.25 mg/kg/day vs. vehicle controls | 0.307 | N
Skipped Estrus | 2.5 mg/kg/day vs. vehicle controls | 0.307 | N
Skipped Diestrus | Overall | 1
Skipped Diestrus | 0.625 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 1.25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 2.5 mg/kg/day vs. vehicle controls | 1 | –
Summary of Significant Groups
Overall Tests | 1.25 mg/kg/day vs. vehicle controls | <0.001 | N
Overall Tests | 2.5 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Estrus | 1.25 mg/kg/day vs. vehicle controls | 0.003 | N
Extended Estrus | 2.5 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Diestrus | 1.25 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Diestrus | 2.5 mg/kg/day vs. vehicle controls | <0.001 | –

^a^ N indicates that the dosed group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dosed group had more departures from normal cycling than did the vehicle control group. The Overall Tests consider all six types of departures from normal cycling. The overall comparison tests for equal transitional probabilities across all dose groups.

Table A-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Wyeth-14,643 by Gavage for 28 Days

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | 0.002
Overall Tests | 6.25 mg/kg/day vs. vehicle controls | 0.085 | –
Overall Tests | 12.5 mg/kg/day vs. vehicle controls | <0.001 | N
Overall Tests | 25 mg/kg/day vs. vehicle controls | 0.983 | –
Extended Estrus | Overall | <0.001
Extended Estrus | 6.25 mg/kg/day vs. vehicle controls | 0.032 | N
Extended Estrus | 12.5 mg/kg/day vs. vehicle controls | 0.001 | N
Extended Estrus | 25 mg/kg/day vs. vehicle controls | 0.017 | N
Extended Diestrus | Overall | <0.001
Extended Diestrus | 6.25 mg/kg/day vs. vehicle controls | 0.005 | –
Extended Diestrus | 12.5 mg/kg/day vs. vehicle controls | 0.001 | –
Extended Diestrus | 25 mg/kg/day vs. vehicle controls | 0.009 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 6.25 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 12.5 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 6.25 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 12.5 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | Overall | 0.572
Skipped Estrus | 6.25 mg/kg/day vs. vehicle controls | 0.316 | N
Skipped Estrus | 12.5 mg/kg/day vs. vehicle controls | 0.319 | N
Skipped Estrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | 6.25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 12.5 mg/kg/day vs. vehicle controls | 0.934 | –
Skipped Diestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Summary of Significant Groups
Overall Tests | 12.5 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Estrus | 6.25 mg/kg/day vs. vehicle controls | 0.032 | N
Extended Estrus | 12.5 mg/kg/day vs. vehicle controls | 0.001 | N
Extended Estrus | 25 mg/kg/day vs. vehicle controls | 0.017 | N
Extended Diestrus | 6.25 mg/kg/day vs. vehicle controls | 0.005 | –
Extended Diestrus | 12.5 mg/kg/day vs. vehicle controls | 0.001 | –
Extended Diestrus | 25 mg/kg/day vs. vehicle controls | 0.009 | –

^a^ N indicates that the dosed group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dosed group had more departures from normal cycling than did the vehicle control group. The Overall Tests consider all six types of departures from normal cycling. The overall comparison tests for equal transitional probabilities across all dose groups.

Figure A-1

Vaginal Cytology Plots for Female Rats in the 28-day Gavage Study of Perfluorohexanoic Acid

I = insufficient number of cells to determine stage; D = diestrus; P = proestrus; E = estrus; M = metestrus.

One-half the dose was administered twice daily.

Figure A-2

Vaginal Cytology Plots for Female Rats in the 28-day Gavage Study of Perfluorooctanoic Acid

I = insufficient number of cells to determine stage; D = diestrus; P = proestrus; E = estrus; M = metestrus.

Figure A-3

Vaginal Cytology Plots for Female Rats in the 28-day Gavage Study of Perfluorononanoic Acid

I = insufficient number of cells to determine stage; D = diestrus; P = proestrus; E = estrus; M = metestrus.

Figure A-4

Vaginal Cytology Plots for Female Rats in the 28-day Gavage Study of Perfluorodecanoic Acid

I = insufficient number of cells to determine stage; D = diestrus; P = proestrus; E = estrus; M = metestrus.

Figure A-5

Vaginal Cytology Plots for Female Rats in the 28-day Gavage Study of Wyeth-14,643

I = insufficient number of cells to determine stage; D = diestrus; P = proestrus; E = estrus; M = metestrus.