# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-96

Report Series: NTP Toxicity Report Series

Report Series Number: 96

Official citation: National Toxicology Program (NTP). 2022. NTP technical report on the toxicity studies of perfluoroalkyl sulfonates (perfluorobutane sulfonic acid, perfluorohexane sulfonate potassium salt, and perfluorooctane sulfonic acid) administered by gavage to Sprague Dawley (Hsd:Sprague Dawley SD) rats (revised). Research Triangle Park, NC: National Toxicology Program. Toxicity Report 96.