# Revision Notice

Errors were identified in the NTP Technical Report on the Toxicity Studies of Perfluoroalkyl Sulfonates (Perfluorobutane Sulfonic Acid, Perfluorohexane Sulfonate Potassium Salt, and Perfluorooctane Sulfonic Acid) Administered by Gavage to Sprague Dawley (Hsd:Sprague Dawley SD) Rats (Toxicity Report 96). Revisions were made throughout the report, and these corrections are described in detail in Appendix F. [June 30, 2022].