# Peer Review

The draft NTP Technical Report on the Toxicity Studies of Perfluoroalkyl Sulfonates (Perfluorobutane Sulfonic Acid, Perfluorohexane Sulfonate Potassium Salt, and Perfluorooctane Sulfonic Acid) Administered by Gavage to Sprague Dawley (Hsd:Sprague Dawley SD) Rats was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Toxicity Study Report presented the experimental results and conclusions fully and clearly.

The revised report was evaluated by one of the original peer reviewers listed below. This reviewer served as an independent scientist, not as a representative of any institution, company, or governmental agency. In this capacity, the reviewer agreed that the revisions to the report did not materially affect NTP’s original conclusions and were appropriately documented in Appendix F.

- Richard Miller, D.V.M., Ph.D.
  Vice President and Global Head of Integrated Biological Platform Sciences
  GlaxoSmithKline, Inc.
  Collegeville, Pennsylvania, USA
- Anne Marie Vinggaard, Ph.D.
  Professor, National Food Institute
  Technical University of Denmark
  Kongens Lyngby, Denmark