# References

1 Buck RC, Franklin J, Berger U, Conder JM, Cousins IT, de Voogt P, Jensen AA, Kannan K, Mabury SA, van Leeuwen SP. Perfluoroalkyl and polyfluoroalkyl substances in the environment: Terminology, classification, and origins. Integr Environ Assess Manag. 2011; 7(4):513–541. 10.1002/ieam.258 21793199
2 PubChem. 1-Perfluorobutanesulfonic acid. Bethesda, MD: National Library of Medicine, National Center for Biotechnology Information; 2018. https://pubchem.ncbi.nlm.nih.gov/compound/67815#Section=Chemical-and-Physical-Properties [Accessed: October 23, 2018]
3 PubChem. Potassium perfluorohexanesulfonate. Bethesda, MD: National Library of Medicine, National Institute of Biotechnology Information; 2018. https://pubchem.ncbi.nlm.nih.gov/compound/23678874#Section=Chemical-and-Physical-Properties [Accessed: October 23, 2018]
4 PubChem. Perfluorooctane sulfonic acid. Bethesda, MD: National Library of Medicine, National Center for Biotechnology Information; 2018. https://pubchem.ncbi.nlm.nih.gov/compound/74483#Section=Chemical-and-Physical-Properties [Accessed: October 23, 2018]
5 U.S. Environmental Proctection Agency (USEPA). Fact sheet: PFOA and PFOS drinking water health advisories. Washington, DC: U.S. Environmental Protection Agency, Office of Water; 2016. EPA Document No. EPA/800/F-16/003.
6 Olsen GW, Lange CC, Ellefson ME, Mair DC, Church TR, Goldberg CL, Herron RM, Medhdizadehkashi Z, Nobiletti JB, Rios JA, et al. Temporal trends of perfluoroalkyl concentrations in American Red Cross adult blood donors, 2000-2010. Environ Sci Technol. 2012; 46(11):6330–6338. 10.1021/es300604p 22554481
7 Bao J, Lee YL, Chen P-C, Jin Y-H, Dong G-H. Perfluoroalkyl acids in blood serum samples from children in Taiwan. Environ Sci Pollut Res Int. 2014; 21(12):7650–7655. 10.1007/s11356-014-2594-4 24622984
8 National Health and Nutrition Examination Survey (NHANES). Fourth national report on human exposure to environmental chemicals, updated tables, Vol 1, March 2018. Washington, DC: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; 2018. https://www.cdc.gov/exposurereport/index.html
9 National Health and Nutrition Examination Survey (NHANES). Fourth national report on human exposure to environmental chemicals, updated tables, Vol 2, March 2018. Washington, DC: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; 2018. https://www.cdc.gov/exposurereport/index.html
10 Zhang T, Wu Q, Sun HW, Zhang XZ, Yun SH, Kannan K. Perfluorinated compounds in whole blood samples from infants, children, and adults in China. Environ Sci Technol. 2010; 44(11):4341–4347. 10.1021/es1002132 20441147
11 Wang M, Park JS, Petreas M. Temporal changes in the levels of perfluorinated compounds in California women’s serum over the past 50 years. Environ Sci Technol. 2011; 45(17):7510–7516. 10.1021/es2012275 21732675
12 Spliethoff HM, Lin T, Shaver SM, Aldous KM, Pass KA, Kannan K, Eadon GA. Use of newborn screening program blood spots for exposure assessment: Declining levels of perfluorinated compounds in New York state infants. Environ Sci Technol. 2008; 42(14):5361–5367. 10.1021/es8006244 18754394
13 U.S. Environmental Proctection Agency (USEPA). Fact sheet: Draft toxicity assessments for GenX chemicals and PFBS. Washington, DC: U.S. Environmental Protection Agency, Office of Water; 2018.
14 Feng X, Cao X, Zhao S, Wang X, Hua X, Chen L, Chen L. Exposure of pregnant mice to perfluorobutanesulfonate causes hypothyroxinemia and developmental abnormalities in female offspring. Toxicol Sci. 2017; 155(2):409–419. 10.1093/toxsci/kfw219 27803384
15 Minnesota Department of Health (MDH). PFBS and drinking water. Saint Paul, MN: Minnesota Department of Health, Health Risk Assessment Unit; 2017.
16 Butenhoff JL, Ehresman DJ, Chang S-C, Parker GA, Stump DG. Gestational and lactational exposure to potassium perfluorooctanesulfonate (K+ PFOS) in rats: Developmental neurotoxicity. Reprod Toxicol. 2009; 27(3-4):319–330. 10.1016/j.reprotox.2008.12.010 19162172
17 No. 47. Vol. 67. Washington, DC: U.S. Environmental Protection Agency; 2002. (Federal Register. Perfluoroalkyl sulfonates: Significant new use rule.).
18 No. 236. Vol. 67. Washington, DC: U.S. Environmental Protection Agency; 2002. (Federal Register. Perfluoroalkyl sulfonates: Significant new use rule.).
19 No. 194. Vol. 72. Washington, DC: U.S. Environmental Protection Agency; 2007. (Federal Register. Perfluoroalkyl sulfonates: Significant new use rule.).
20 Seacat AM, Thomford PJ, Hansen KJ, Olsen GW, Case MT, Butenhoff JL. Subchronic toxicity studies on perfluorooctanesulfonate potassium salt in cynomolgus monkeys. Toxicol Sci. 2002; 68(1):249–264. 10.1093/toxsci/68.1.249 12075127
21 U.S. Environmental Proctection Agency (USEPA). Drinking water health advisory for perfluorooctanoic Acid (PFOA). Washington, DC: U.S. Environmental Protection Agency, Office of Water, Health and Ecological Criteria Division; 2016. EPA Document Number: EPA/822/R-16/005.
22 European Food Safety Authority (EFSA). Risk to human health related to the presence of perfluorooctane sulfonic acid and perfluorooctanoic acid in food. EFSA J. 2018; 16(12):5194. 32625773
23 Kudo N, Katakura M, Sato Y, Kawashima Y. Sex hormone-regulated renal transport of perfluorooctanoic acid. Chem Biol Interact. 2002; 139(3):301–316. 10.1016/S0009-2797(02)00006-6 11879818
24 Andersen ME, Clewell HJ, Tan Y-M, Butenhoff JL, Olsen GW. Pharmacokinetic modeling of saturable, renal resorption of perfluoroalkylacids in monkeys—Probing the determinants of long plasma half-lives. Toxicology. 2006; 227(1-2):156–164. 10.1016/j.tox.2006.08.004 16978759
25 Lou I, Wambaugh JF, Lau C, Hanson RG, Lindstrom AB, Strynar MJ, Zehr RD, Setzer RW, Barton HA. Modeling single and repeated dose pharmacokinetics of PFOA in mice. Toxicol Sci. 2009; 107(2):331–341. 10.1093/toxsci/kfn234 19005225
26 Loccisano AE, Campbell JL Jr, Andersen ME, Clewell HJ 3rd. Evaluation and prediction of pharmacokinetics of PFOA and PFOS in the monkey and human using a PBPK model. Regul Toxicol Pharmacol. 2011; 59(1):157–175. 10.1016/j.yrtph.2010.12.004 21168463
27 Loccisano AE, Campbell JL Jr, Butenhoff JL, Andersen ME, Clewell HJ 3rd. Comparison and evaluation of pharmacokinetics of PFOA and PFOS in the adult rat using a physiologically based pharmacokinetic model. Reprod Toxicol. 2012; 33(4):452–467. 10.1016/j.reprotox.2011.04.006 21565266
28 Loccisano AE, Campbell JL Jr, Butenhoff JL, Andersen ME, Clewell HJ 3rd. Evaluation of placental and lactational pharmacokinetics of PFOA and PFOS in the pregnant, lactating, fetal and neonatal rat using a physiologically based pharmacokinetic model. Reprod Toxicol. 2012; 33(4):468–490. 10.1016/j.reprotox.2011.07.003 21872655
29 Loccisano AE, Longnecker MP, Campbell JL Jr, Andersen ME, Clewell HJ 3rd. Development of PBPK models for PFOA and PFOS for human pregnancy and lactation life stages. J Toxicol Environ Health A. 2013; 76(1):25–57. 10.1080/15287394.2012.722523 23151209
30 Huang MC, Robinson VG, Waidyanatha S, Dzierlenga AL, DeVito MJ, Eifrid MA, Hong SP, Gibbs ST, Blystone CR. Toxicokinetics of 8:2 fluorotelomer alcohol (8:2-FTOH) in male and female Hsd:Sprague Dawley SD rats after intravenous and gavage administration. Toxicol Rep. 2019; 6:924–932. 10.1016/j.toxrep.2019.08.009 31516843
31 Huang MC, Dzierlenga AL, Robinson VG, Waidyanatha S, DeVito MJ, Eifrid MA, Granville CA, Gibbs ST, Hong SP, Pirone JR, et al. Toxicokinetics of perfluorobutane sulfonate (PFBS), perfluorohexane-1-sulphonic acid (PFHxS), and perfluorooctane sulfonic acid (PFOS) in male and female Hsd:Sprague Dawley SD rats after intravenous and gavage administration. Toxicol Rep. 2019; 6:645–655. 10.1016/j.toxrep.2019.06.016 31334035
32 Dzierlenga AL, Robinson VG, Waidyanatha S, DeVito MJ, Eifrid MA, Gibbs ST, Granville CA, Blystone CR. Toxicokinetics of perfluorohexanoic acid (PFHxA), perfluorooctanoic acid (PFOA), and perfluorodecanoic acid (PFDA) in male and female Hsd:Sprague Dawley SD rats following intravenous or gavage administration. Xenobiotica. 2020; 50(6):722–732. 10.1080/00498254.2019.1683776 31680603
33 Olsen GW, Chang SC, Noker PE, Gorman GS, Ehresman DJ, Lieder PH, Butenhoff JL. A comparison of the pharmacokinetics of perfluorobutanesulfonate (PFBS) in rats, monkeys, and humans. Toxicology. 2009; 256(1-2):65–74. 10.1016/j.tox.2008.11.008 19059455
34 Sundstrom M, Chang SC, Noker PE, Gorman GS, Hart JA, Ehresman DJ, Bergman A, Butenhoff JL. Comparative pharmacokinetics of perfluorohexanesulfonate (PFHxS) in rats, mice, and monkeys. Reprod Toxicol. 2012; 33(4):441–451. 10.1016/j.reprotox.2011.07.004 21856411
35 Olsen GW, Burris JM, Ehresman DJ, Froehlich JW, Seacat AM, Butenhoff JL, Zobel LR. Half-life of serum elimination of perfluorooctanesulfonate, perfluorohexanesulfonate, and perfluorooctanoate in retired fluorochemical production workers. Environ Health Perspect. 2007; 115(9):1298–1305. 10.1289/ehp.10009 17805419
36 Li Y, Fletcher T, Mucs D, Scott K, Lindh CH, Tallving P, Jakobsson K. Half-lives of PFOS, PFHxS and PFOA after end of exposure to contaminated drinking water. Occup Environ Med. 2018; 75(1):46–51. 10.1136/oemed-2017-104651 29133598
37 Chang S-C, Noker PE, Gorman GS, Gibson SJ, Hart JA, Ehresman DJ, Butenhoff JL. Comparative pharmacokinetics of perfluorooctanesulfonate (PFOS) in rats, mice, and monkeys. Reprod Toxicol. 2012; 33(4):428–440. 10.1016/j.reprotox.2011.07.002 21889587
38 Permadi H, Lundgren B, Andersson K, DePierre JW. Effects of perfluoro fatty acids on xenobiotic-metabolizing enzymes, enzymes which detoxify reactive forms of oxygen and lipid peroxidation in mouse liver. Biochem Pharmacol. 1992; 44(6):1183–1191. 10.1016/0006-2952(92)90383-T 1417940
39 Kudo N, Suzuki-Nakajima E, Mitsumoto A, Kawashima Y. Responses of the liver to perfluorinated fatty acids with different carbon chain length in male and female mice: In relation to induction of hepatomegaly, peroxisomal β-oxidation and microsomal 1-acylglycerophosphocholine acyltransferase. Biol Pharm Bull. 2006; 29(9):1952–1957. 10.1248/bpb.29.1952 16946516
40 Vanden Heuvel JP, Thompson JT, Frame SR, Gillies P. Differential activation of nuclear receptors by perfluorinated fatty acid analogs and natural fatty acids: A comparison of human, mouse, and rat peroxisome proliferator-activated receptor-α,-β, and-γ, liver X receptor-β, and retinoid X receptor-α. Toxicol Sci. 2006; 92(2):476–489. 10.1093/toxsci/kfl014 16731579
41 Wolf CJ, Takacs ML, Schmid JE, Lau C, Abbott BD. Activation of mouse and human peroxisome proliferator− activated receptor alpha by perfluoroalkyl acids of different functional groups and chain lengths. Toxicol Sci. 2008; 106(1):162–171. 10.1093/toxsci/kfn166 18713766
42 Bjork JA, Wallace KB. Structure-activity relationships and human relevance for perfluoroalkyl acid-induced transcriptional activation of peroxisome proliferation in liver cell cultures. Toxicol Sci. 2009; 111(1):89–99. 10.1093/toxsci/kfp093 19407336
43 Cheng X, Klaassen CD. Perfluorocarboxylic acids induce cytochrome P450 enzymes in mouse liver through activation of PPAR-alpha and CAR transcription factors. Toxicol Sci. 2008; 106(1):29–36. 10.1093/toxsci/kfn147 18648086
44 Rosen MB, Lee JS, Ren H, Vallanat B, Liu J, Waalkes MP, Abbott BD, Lau C, Corton JC. Toxicogenomic dissection of the perfluorooctanoic acid transcript profile in mouse liver: Evidence for the involvement of nuclear receptors PPAR alpha and CAR. Toxicol Sci. 2008; 103(1):46–56. 10.1093/toxsci/kfn025 18281256
45 Lieder PH, Chang SC, York RG, Butenhoff JL. Toxicological evaluation of potassium perfluorobutanesulfonate in a 90-day oral gavage study with Sprague-Dawley rats. Toxicology. 2009; 255(1-2):45–52. 10.1016/j.tox.2008.10.002 18992301
46 Lieder PH, York RG, Hakes DC, Chang SC, Butenhoff JL. A two-generation oral gavage reproduction study with potassium perfluorobutanesulfonate (K+PFBS) in Sprague Dawley rats. Toxicology. 2009; 259(1-2):33–45. 10.1016/j.tox.2009.01.027 19428941
47 Butenhoff JL, Chang S-C, Ehresman DJ, York RG. Evaluation of potential reproductive and developmental toxicity of potassium perfluorohexanesulfonate in Sprague Dawley rats. Reprod Toxicol. 2009; 27(3-4):331–341. 10.1016/j.reprotox.2009.01.004 19429404
48 Lee I, Viberg H. A single neonatal exposure to perfluorohexane sulfonate (PFHxS) affects the levels of important neuroproteins in the developing mouse brain. Neurotoxicology. 2013; 37:190–196. 10.1016/j.neuro.2013.05.007 23701969
49 Chang S, Butenhoff JL, Parker GA, Coder PS, Zitzow JD, Krisko RM, Bjork JA, Wallace KB, Seed JG. Reproductive and developmental toxicity of potassium perfluorohexanesulfonate in CD-1 mice. Reprod Toxicol. 2018; 78:150–168. 10.1016/j.reprotox.2018.04.007 29694846
50 Seacat AM, Thomford PJ, Hansen KJ, Clemen LA, Eldridge SR, Elcombe CR, Butenhoff JL. Sub-chronic dietary toxicity of potassium perfluorooctanesulfonate in rats. Toxicology. 2003; 183(1-3):117–131. 10.1016/S0300-483X(02)00511-5 12504346
51 Luebker DJ, Case MT, York RG, Moore JA, Hansen KJ, Butenhoff JL. Two-generation reproduction and cross-foster studies of perfluorooctanesulfonate (PFOS) in rats. Toxicology. 2005; 215(1-2):126–148. 10.1016/j.tox.2005.07.018 16146667
52 Thibodeaux JR, Hanson RG, Rogers JM, Grey BE, Barbee BD, Richards JH, Butenhoff JL, Stevenson LA, Lau C. Exposure to perfluorooctane sulfonate during pregnancy in rat and mouse. I: Maternal and prenatal evaluations. Toxicol Sci. 2003; 74(2):369–381. 10.1093/toxsci/kfg121 12773773
53 Lau C, Thibodeaux JR, Hanson RG, Rogers JM, Grey BE, Stanton ME, Butenhoff JL, Stevenson LA. Exposure to perfluorooctane sulfonate during pregnancy in rat and mouse. II: Postnatal evaluation. Toxicol Sci. 2003; 74(2):382–392. 10.1093/toxsci/kfg122 12773772
54 DeWitt JC, Shnyra A, Badr MZ, Loveless SE, Hoban D, Frame SR, Cunard R, Anderson SE, Meade BJ, Peden-Adams MM, et al. Immunotoxicity of perfluorooctanoic acid and perfluorooctane sulfonate and the role of peroxisome proliferator-activated receptor alpha. Crit Rev Toxicol. 2009; 39(1):76–94. 10.1080/10408440802209804 18802816
55 National Toxicology Program (NTP). NTP monograph on immunotoxicity associated with exposure to perfluorooctanoic acid or perfluorooctane sulfonate. Research Triangle Park, NC : U.S. Department of Health and Human Services, National Institutes of Health, National Institute of Environmental Health Sciences, Office of Health Assessment and Translation; 2016. https://ntp.niehs.nih.gov/ntp/ohat/pfoa_pfos/pfoa_pfosmonograph_508.pdf
56 Melzer D, Rice N, Depledge MH, Henley WE, Galloway TS. Association between serum perfluorooctanoic acid (PFOA) and thyroid disease in the U.S. National Health and Nutrition Examination Survey. Environ Health Perspect. 2010; 118(5):686–692. 10.1289/ehp.0901584 20089479
57 Lopez-Espinosa MJ, Fletcher T, Armstrong B, Genser B, Dhatariya K, Mondal D, Ducatman A, Leonardi G. Association of perfluorooctanoic acid (PFOA) and perfluorooctane sulfonate (PFOS) with age of puberty among children living near a chemical plant. Environ Sci Technol. 2011; 45(19):8160–8166. 10.1021/es1038694 21534542
58 Joensen UN, Bossi R, Leffers H, Jensen AA, Skakkebaek NE, Jorgensen N. Do perfluoroalkyl compounds impair human semen quality? Environ Health Perspect. 2009; 117(6):923–927. 10.1289/ehp.0800517 19590684
59 Sakr CJ, Leonard RC, Kreckmann KH, Slade MD, Cullen MR. Longitudinal study of serum lipids and liver enzymes in workers with occupational exposure to ammonium perfluorooctanoate. J Occup Environ Med. 2007; 49(8):872–879. 10.1097/JOM.0b013e318124a93f 17693785
60 Lin CY, Chen PC, Lin YC, Lin LY. Association among serum perfluoroalkyl chemicals, glucose homeostasis, and metabolic syndrome in adolescents and adults. Diabetes Care. 2009; 32(4):702–707. 10.2337/dc08-1816 19114613
61 Lin CY, Lin LY, Chiang CK, Wang WJ, Su YN, Hung KY, Chen PC. Investigation of the associations between low-dose serum perfluorinated chemicals and liver enzymes in US adults. Am J Gastroenterol. 2010; 105(6):1354–1363. 10.1038/ajg.2009.707 20010922
62 Mogensen U, Grandjean P, Heilmann C, Nielsen F, Weihe P, Budtz-Jørgensen E. Structural equation modeling of immunotoxicity associated with exposure to perfluorinated alkylates. Environ Health. 2015;14:47. 10.1186/s12940-015-0032-9 26041029
63 Grandjean P, Clapp R. Perfluorinated alkyl substances: Emerging insights into health risks. New Solut. 2015; 25(2):147–163. 10.1177/1048291115590506 26084549
64 Granum B, Haug L, Namork E, Stølevik S, Thomsen C, Aaberge I, van Loveren H, Løvik M, Nygaard U. Pre-natal exposure to perfluoroalkyl substances may be associated with altered vaccine antibody levels and immune-related health outcomes in early childhood. J Immunotoxicol. 2013; 10(4):373–379. 10.3109/1547691X.2012.755580 23350954
65 Stein CR, McGovern KJ, Pajak AM, Maglione PJ, Wolff MS. Perfluoroalkyl and polyfluoroalkyl substances and indicators of immune function in children aged 12-19 y: National Health and Nutrition Examination Survey (NHANES). Pediatr Res. 2016; 79(2):348–357. 10.1038/pr.2015.213 26492286
66 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for perfluoroalkyls: Draft for public comment. Atlanta, GA: U.S. Department of Health and Human Services; 2018. https://www.atsdr.cdc.gov/toxprofiles/tp200.pdf
67 C8 Science Panel. Probable link evaluation of birth defects. Parkersburg, WV; 2011. http://www.c8sciencepanel.org/prob_link.html
68 C8 Science Panel. Probable link evaluation of pregnancy-induced hypertension and preeclampsia. Parkersburg, WV; 2011. http://www.c8sciencepanel.org/prob_link.html
69 C8 Science Panel. Probable link evaluation of miscarriage and stillbirths. Parkersburg, WV; 2011. http://www.c8sciencepanel.org/prob_link.html
70 C8 Science Panel. Probable link evaluation of preterm birth and low birthweight. Parkersburg, WV; 2011. http://www.c8sciencepanel.org/prob_link.html
71 Butenhoff JL, Chang S-C, Olsen GW, Thomford PJ. Chronic dietary toxicity and carcinogenicity study with potassium perfluorooctanesulfonate in Sprague Dawley rats. Toxicology. 2012; 293(1-3):1–15. 10.1016/j.tox.2012.01.003 22266392
72 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of the carcinogenic risk of chemicals to humans. Some chemicals used as solvents and in polymer manufacture. Vol. 110. Lyon, France: IARC; 2016.
73 Wielsøe M, Long M, Ghisari M, Bonefeld-Jørgensen EC. Perfluoroalkylated substances (PFAS) affect oxidative stress biomarkers in vitro. Chemosphere. 2015; 129:239–245. 10.1016/j.chemosphere.2014.10.014 25455676
74 Florentin A, Deblonde T, Diguio N, Hautemaniere A, Hartemann P. Impacts of two perfluorinated compounds (PFOS and PFOA) on human hepatoma cells: Cytotoxicity but no genotoxicity? Int J Hyg Environ Health. 2011; 214(6):493–499. 10.1016/j.ijheh.2011.05.010 21676652
75 Repine JE, Pfenninger OW, Talmage DW, Berger EM, Pettijohn DE. Dimethyl sulfoxide prevents DNA nicking mediated by ionizing radiation or iron/hydrogen peroxide-generated hydroxyl radical. Proc Natl Acad Sci USA. 1981; 78(2):1001–1003. 10.1073/pnas.78.2.1001 6940118
76 Çelik A, Eke D, Ekinci SY, Yıldırım S. The protective role of curcumin on perfluorooctane sulfonate-induced genotoxicity: Single cell gel electrophoresis and micronucleus test. Food Chem Toxicol. 2013; 53:249–255. 10.1016/j.fct.2012.11.054 23246701
77 Färber H, Jones P, Giesy J, Engwall M. Perfluorooctane sulfonate increases the genotoxicity of cyclophosphamide in the micronucleus assay with V79 cells: Further proof of alterations in cell membrane properties caused by PFOS. Environ Sci Pollut Res Int. 2007; 14(2):85–87. 10.1065/espr2007.01.384 17455816
78 Nakamura R, Takeuchi R, Kuramochi K, Mizushina Y, Ishimaru C, Takakusagi Y, Takemura M, Kobayashi S, Yoshida H, Sugawara F, et al. Chemical properties of fatty acid derivatives as inhibitors of DNA polymerases. Org Biomol Chem. 2007; 5(24):3912–3921. 10.1039/b710944j 18043794
79 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of perfluorooctanoic acid (CAS No. 335-67-1) in Sprague Dawley (Hsd:Sprague Dawley SD) rats (perinatal and nonperinatal feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health; 2019. Technical Report Series No. 598. 10.22427/NTP-TR-598
80 Slotkin TA, MacKillop EA, Melnick RL, Thayer KA, Seidler FJ. Developmental neurotoxicity of perfluorinated chemicals modeled in vitro. Environ Health Perspect. 2008; 116(6):716–722. 10.1289/ehp.11253 18560525
81 Wallace KB, Kissling G, Melnick R, Blystone C. Structure–activity relationships for perfluoroalkane-induced in vitro interference with rat liver mitochondrial respiration. Toxicol Lett. 2013; 222(3):257–264. 10.1016/j.toxlet.2013.07.025 23954199
82 Corsini E, Avogadro A, Galbiati V, dell’Agli M, Marinovich M, Galli CL, Germolec DR. In vitro evaluation of the immunotoxic potential of perfluorinated compounds (PFCs). Toxicol Appl Pharmacol. 2011; 250(2):108–116. 10.1016/j.taap.2010.11.004 21075133
83 Corsini E, Sangiovanni E, Avogadro A, Galbiati V, Viviani B, Marinovich M, Galli CL, Dell’Agli M, Germolec DR. In vitro characterization of the immunotoxic potential of several perfluorinated compounds (PFCs). Toxicol Appl Pharmacol. 2012; 258(2):248–255. 10.1016/j.taap.2011.11.004 22119708
84 Frawley RP, Smith M, Cesta MF, Hayes-Bouknight S, Blystone C, Kissling GE, Harris S, Germolec D. Immunotoxic and hepatotoxic effects of perfluoro-n-decanoic acid (PFDA) on female Harlan Sprague-Dawley rats and B6C3F1/N mice when administered by oral gavage for 28 days. J Immunotoxicol. 2018; 15(1):41–52. 10.1080/1547691X.2018.1445145 29514525
85 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
86 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
87 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
88 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
89 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero-dose control. Biometrics. 1971; 27:103–117. 10.2307/2528930 5547548
90 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972:519-531. 10.2307/2556164
91 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
92 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
93 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
94 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. 10.2307/2333011
95 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill Book Company, Inc.; 1957. p. 276–278, 412.
96 Girard DM, Sager DB. The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. 10.2307/2531963 3567307
97 Code of Federal Regulations (CFR). 21:Part 58.
98 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 S21:2–141. 10.1002/em.2850190603 1541260
99 MacGregor JT, Bishop ME, McNamee JP, Hayashi M, Asano N, Wakata A, Nakajima M, Saito J, Aidoo A, Moore MM, et al. Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: II. An efficient method of monitoring chromosomal damage in the rat. Toxicol Sci. 2006; 94(1):92–107. 10.1093/toxsci/kfl076 16888079
100 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry-and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
101 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
102 Igl BW, Bitsch A, Bringezu F, Chang S, Dammann M, Frotschl R, Harm V, Kellner R, Krzykalla V, Lott J, et al. The rat bone marrow micronucleus test: Statistical considerations on historical negative control data. Regul Toxicol Pharmacol. 2019; 102:13–22. 10.1016/j.yrtph.2018.12.009 30572081
103 National Toxicology Program (NTP). Toxicity studies of perfluorinated carboxylic acids (perfluorohexanoic acid, perfluorooctanoic acid, perfluorononanoic acid, and perfluorodecanoic acid) administered by gavage to Sprague Dawley (Hsd:Sprague Dawley SD) rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health; 2019. Toxicity Study Report Series No. 97.
104 Karrman A, van Bavel B, Jarnberg U, Hardell L, Lindstrom G. Perfluorinated chemicals in relation to other persistent organic pollutants in human blood. Chemosphere. 2006; 64(9):1582–1591. 10.1016/j.chemosphere.2005.11.040 16403420
105 Ehresman DJ, Froehlich JW, Olsen GW, Chang S-C, Butenhoff JL. Comparison of human whole blood, plasma, and serum matrices for the determination of perfluorooctanesulfonate (PFOS), perfluorooctanoate (PFOA), and other fluorochemicals. Environ Res. 2007; 103(2):176–184. 10.1016/j.envres.2006.06.008 16893538
106 Chang ET, Adami HO, Boffetta P, Cole P, Starr TB, Mandel JS. A critical review of perfluorooctanoate and perfluorooctanesulfonate exposure and cancer risk in humans. Crit Rev Toxicol. 2014; 44 Suppl 1:1–81. 10.3109/10408444.2014.905767 24793953
107 Li K, Gao P, Xiang P, Zhang X, Cui X, Ma LQ. Molecular mechanisms of PFOA-induced toxicity in animals and humans: Implications for health risks. Environ Int. 2017; 99:43–54. 10.1016/j.envint.2016.11.014 27871799
108 Thompson MB. Bile acids in the assessment of hepatocellular function. Toxicol Pathol. 1996; 24(1):62–71. 10.1177/019262339602400109 8839282
109 Ennulat D, Magid-Slav M, Rehm S, Tatsuoka KS. Diagnostic performance of traditional hepatobiliary biomarkers of drug-induced liver injury in the rat. Toxicol Sci. 2010; 116(2):397–412. 10.1093/toxsci/kfq144 20466777
110 Cattley RC, Cullen JM. Liver and gall bladder. In: Haschek WM, Rousseaux CG, Wallig MA, editors. Haschek and Rousseaux’s Handbook of Toxicologic Pathology. 3rd ed. London, UK: Elsevier; 2013. p. 1509–1566. 10.1016/B978-0-12-415759-0.00045-5
111 Ennulat D, Walker D, Clemo F, Magid-Slav M, Ledieu D, Graham M, Botts S, Boone L. Effects of hepatic drug-metabolizing enzyme induction on clinical pathology parameters in animals and man. Toxicol Pathol. 2010; 38(5):810–828. 10.1177/0192623310374332 20585144
112 Hall AP, Elcombe CR, Foster JR, Harada T, Kaufmann W, Knippel A, Kuttler K, Malarkey DE, Maronpot RR, Nishikawa A, et al. Liver hypertrophy: A review of adaptive (adverse and non-adverse) changes—conclusions from the 3rd International ESTP Expert Workshop. Toxicol Pathol. 2012; 40(7):971–994. 10.1177/0192623312448935 22723046
113 Luebker DJ, York RG, Hansen KJ, Moore JA, Butenhoff JL. Neonatal mortality from in utero exposure to perfluorooctanesulfonate (PFOS) in Sprague-Dawley rats: Dose-response, and biochemical and pharamacokinetic parameters. Toxicology. 2005; 215(1-2):149–169. 10.1016/j.tox.2005.07.019 16129535
114 Curran I, Hierlihy SL, Liston V, Pantazopoulos P, Nunnikhoven A, Tittlemier S, Barker M, Trick K, Bondy G. Altered fatty acid homeostasis and related toxicologic sequelae in rats exposed to dietary potassium perfluorooctanesulfonate (PFOS). J Toxicol Environ Health A. 2008; 71(23):1526–1541. 10.1080/15287390802361763 18923995
115 Konig B, Koch A, Spielmann J, Hilgenfeld C, Stangl GI, Eder K. Activation of PPARalpha lowers synthesis and concentration of cholesterol by reduction of nuclear SREBP-2. Biochem Pharmacol. 2007; 73(4):574–585. 10.1016/j.bcp.2006.10.027 17126302
116 Chen X, Matthews J, Zhou L, Pelton P, Liang Y, Xu J, Yang M, Cryan E, Rybczynski P, Demarest K. Improvement of dyslipidemia, insulin sensitivity, and energy balance by a peroxisome proliferator-activated receptor alpha agonist. Metabolism. 2008; 57(11):1516–1525. 10.1016/j.metabol.2008.06.005 18940388
117 Yan J, Chen B, Lu J, Xie W. Deciphering the roles of the constitutive androstane receptor in energy metabolism. Acta Pharmacol Sin. 2015; 36(1):62–70. 10.1038/aps.2014.102 25500869
118 Walker D, Tomlinson L. Lipids. In: Kurtz DM, Travlos GS, editors. The Clinical Chemistry of Laboratory Animals. Boca Raton, FL: CRC Press; 2018. p. 777–871.
119 Chang SC, Thibodeaux JR, Eastvold ML, Ehresman DJ, Bjork JA, Froehlich JW, Lau C, Singh RJ, Wallace KB, Butenhoff JL. Thyroid hormone status and pituitary function in adult rats given oral doses of perfluorooctanesulfonate (PFOS). Toxicology. 2008; 243(3):330–339. 10.1016/j.tox.2007.10.014 18063289
120 Rosol TJ, Delellis RA, Harvey PW, Sutcliffe C. Endocrine system. In: Haschek WM, Rousseaux CG, Wallig MA, editors. Haschek and Rousseaux’s Handbook of Toxicologic Pathology. 3rd ed. London, UK: Elsevier; 2013. p. 2391–2492. 10.1016/B978-0-12-415759-0.00058-3
121 Chang SC, Thibodeaux JR, Eastvold ML, Ehresman DJ, Bjork JA, Froehlich JW, Lau CS, Singh RJ, Wallace KB, Butenhoff JL. Negative bias from analog methods used in the analysis of free thyroxine in rat serum containing perfluorooctanesulfonate (PFOS). Toxicology. 2007; 234(1-2):21–33. 10.1016/j.tox.2007.01.020 17368689
122 Weiss JM, Andersson PL, Lamoree MH, Leonards PE, van Leeuwen SP, Hamers T. Competitive binding of poly-and perfluorinated compounds to the thyroid hormone transport protein transthyretin. Toxicol Sci. 2009; 109(2):206–216. 10.1093/toxsci/kfp055 19293372
123 Warner MH, Beckett GJ. Mechanisms behind the non-thyroidal illness syndrome: An update. J Endocrinol. 2010; 205(1):1–13. 10.1677/JOE-09-0412 20016054
124 Van Rafelghem MJ, Inhorn SL, Peterson RE. Effects of perfluorodecanoic acid on thyroid status in rats. Toxicol Appl Pharmacol. 1987; 87(3):430–439. 10.1016/0041-008X(87)90248-1 3564018
125 Damsch S, Eichenbaum G, Tonelli A, Lammens L, Van den Bulck K, Feyen B, Vandenberghe J, Megens A, Knight E, Kelley M. Gavage-related reflux in rats: Identification, pathogenesis, and toxicological implications [review]. Toxicol Pathol. 2011; 39(2):348–360. 10.1177/0192623310388431 21422261
126 Ling G, Gu J, Genter MB, Zhuo X, Ding X. Regulation of cytochrome P450 gene expression in the olfactory mucosa. Chem Biol Interact. 2004; 147(3):247–258. 10.1016/j.cbi.2004.02.003 15135081
127 Bach PH, Thanh NTK. Renal papillary necrosis—40 years on. Toxicol Pathol. 1998; 26(1):73–91. 10.1177/019262339802600110 9502390
128 Frazier KS, Seely JC, Hard GC, Betton G, Burnett R, Nakatsuji S, Nishikawa A, Durchfeld-Meyer B, Bube A. Proliferative and nonproliferative lesions of the rat and mouse urinary system. Toxicol Pathol. 2012; 40(4 Suppl) suppl:14S–86S. 10.1177/0192623312438736 22637735
129 Greaves P. Urinary tract. In: Greaves P, editor. Histopathology of Preclinical Toxicity Studies. 4th ed. Boston, MA: Academic Press; 2012. p. 537–614. 10.1016/B978-0-444-53856-7.00010-5
130 Fry MM. Anemia of inflammatory, neoplastic, renal, and endocrine diseases. In: Weiss DJ, Wardrop KJ, editors. Schalm’s Veterinary Hematology. 6th ed. Hoboken, NJ: Wiley-Blackwell; 2010. p. 246–250.
131 Everds NE, Snyder PW, Bailey KL, Bolon B, Creasy DM, Foley GL, Rosol TJ, Sellers T. Interpreting stress responses during routine toxicity studies: A review of the biology, impact, and assessment. Toxicol Pathol. 2013; 41(4):560–614. 10.1177/0192623312466452 23475558