# Discussion

Due to widespread exposure to several of the per/polyfluorinated alkyl substances (PFAS), and few in vivo studies available for direct comparisons of toxicity across the class, a class comparison was conducted by NTP. A large amount of research has focused on perfluorooctane sulfonic acid (PFOS) and perfluorooctane octanoic acid (PFOA), as they are the most prominent PFAS in terms of exposure levels to date. Toxicity Study Report 97^103^ and this report, Toxicity Study Report 96, detail results from 28-day studies evaluating the toxicity of seven straight-chained sulfonate and carboxylate PFAS of varying chain length. Wyeth-14,643 was included in the comparison studies as an indicator of potential peroxisome proliferator-activated receptor alpha (PPARα)-mediated toxicity. This section provides an overview of major endpoints of toxicity, a brief comparison across PFAS evaluated, and a discussion of potential mechanisms of toxicity.

These studies evaluated the plasma and liver (males only) concentrations after administration of perfluorobutane sulfonic acid (PFBS), perfluorohexane sulfonate potassium salt (PFHxSK), and PFOS for a comparison of toxicity. In general, the levels of each chemical were consistent with the literature on the kinetics of these particular PFAS, with the short-chain PFBS that has a shorter half-life displaying lower levels compared to the longer-chain (perfluorohexane sulfonate [PFHxS], PFOS) chemicals.^31,33,34,37^ In addition, the previously reported sex difference with PFHxS^31,34^ was apparent in this study, with female rats administered PFHxSK displaying much lower plasma concentrations. At the doses tested in this study, there was evidence of a nonlinear response occurring in males and females administered PFHxSK as evident in the steady decrease in plasma concentrations adjusted for dose. This is presumably due to saturation of protein or kidney transporter binding, resulting in a faster elimination rate. There was some evidence of saturation of kidney reuptake transporters or protein binding in males and females at the higher PFOS doses tested as plasma concentrations per dose administered were lower. However, this was not the case in PFBS males and females, which displayed an increase in plasma concentrations when adjusted for dose. The variation in nonlinear kinetics could be due to a multitude of factors (e.g., various protein or transporter binding constants) and highlights the individuality of kinetics across the PFAS. Overall, the levels of PFAS measured in these studies were generally orders of magnitude higher than measured in humans.^9^

To evaluate accumulation in the liver, the ratios of liver/plasma concentrations were examined in male rats. In human blood, PFAS are generally localized in the plasma compartment compared to whole blood with ratios of 1.1 to 2.0 reported,^104,105^ but this is not well understood in rodents. Liver/plasma ratios were highest in PFOS males, then PFHxSK males, and lowest in PFBS males. In general, the longer the chain length, the greater the distribution/accumulation observed within the liver. At the doses tested in these studies, the liver/plasma ratios decreased with increasing dose in PFOS males, suggesting a level of liver saturation or high plasma protein binding was reached.

The toxicity comparisons of a chemical could be evaluated from an exposure standpoint in several ways (e.g., comparing external dose versus internal dose metrics such as C_max_, area under the curve [AUC], or final plasma measurements). In addition, each toxicity or effect may be better explained using a different exposure paradigm. An extensive evaluation of these possible exposure comparisons and response models is beyond the scope of this report, but a comparison of findings based on external dose (mmol/kg/day) and plasma levels on day 29 (μM) allows for a qualitative summary of the findings and highlights the challenges in potency estimations. Liver and thyroid hormone findings in males and females were highlighted as they were generally present across all the chemicals (Figure 23, Figure 24, Figure 25, Figure 26, Figure 27, Figure 28, Figure 29, Figure 30, Figure 31, and Figure 32). Toxicity comparisons based on dose administered show PFOS to be the most potent and PFBS to be the least potent with PFHxSK closer to PFOS in potency than to PFBS. If plasma concentrations at day 29 are used for comparison, PFBS is generally the most potent (Figure 29, Figure 30, Figure 31, and Figure 32). However, it should be acknowledged that a significantly higher amount of PFBS had to be administered to the animals to attain these plasma levels and that AUC or C_max_ approaches may be better exposure metrics for comparison.

Figure 23

Comparison of Magnitude of Change for Select Liver Endpoints in Sprague Dawley Rats Administered Perfluorobutane Sulfonic Acid by Gavage for 28 Days

PFBS = perfluorobutane sulfonic acid.

Figure 24

Comparison of Magnitude of Change for Select Liver Endpoints in Sprague Dawley Rats Administered Perfluorohexane Sulfonate Potassium Salt by Gavage for 28 Days

PFHxSK = perfluorohexane sulfonate potassium salt.

Figure 25

Comparison of Magnitude of Change for Select Liver Endpoints in Sprague Dawley Rats Administered Perfluorooctane Sulfonic Acid by Gavage for 28 Days

PFOS = perfluorooctane sulfonic acid.

Figure 26

Comparison of Magnitude of Change for Thyroid Hormone Endpoints in Sprague Dawley Rats Administered Perfluorobutane Sulfonic Acid by Gavage for 28 Days

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine; PFBS = perfluorobutane sulfonic acid.

Figure 27

Comparison of Magnitude of Change for Thyroid Hormone Endpoints in Sprague Dawley Rats Administered Perfluorohexane Sulfonate Potassium Salt by Gavage for 28 Days

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine; PFHxSK = perfluorohexane sulfonate potassium salt.

Figure 28

Comparison of Magnitude of Change for Thyroid Hormone Endpoints in Sprague Dawley Rats Administered Perfluorooctane Sulfonic Acid by Gavage for 28 Days

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine; PFOS = perfluorooctane sulfonic acid.

Figure 29

Average Magnitude of Change for Cyp4a1 Expression (A, B), Cyp2b1 Expression (C, D), Liver Weight Increase (E, F), and Hepatocellular Hypertrophy (G, H) in Male Sprague Dawley Rats Administered Perfluorobutane Sulfonic Acid, Perfluorohexane Sulfonate Potassium Salt, or Perfluorooctane Sulfonic Acid

PFBS = perfluorobutane sulfonic acid; PFHxSK = perfluorohexane sulfonate potassium salt; PFOS = perfluorooctane sulfonic acid; WY = Wyeth-14,643.

Comparisons are made on a dose administered (mmol/kg/day) basis (A, C, E, G) and plasma level (μM) basis (B, D, F, H). Wyeth-14,643 (PPARα agonist) used for comparison on a dose administered (mmol/kg/day) basis (A, C, E, G).

Figure 30

Average Magnitude of Change for Cyp4a1 Expression (A, B), Cyp2b1 Expression (C, D), Liver Weight Increase (E, F), and Hepatocellular Hypertrophy (G, H) in Female Sprague Dawley Rats Administered Perfluorobutane Sulfonic Acid, Perfluorohexane Sulfonate Potassium Salt, or Perfluorooctane Sulfonic Acid

PFBS = perfluorobutane sulfonic acid; PFHxSK = perfluorohexane sulfonate potassium salt; PFOS = perfluorooctane sulfonic acid; WY = Wyeth-14,643.

Comparisons are made on a dose administered (mmol/kg/day) basis (A, C, E, G) and plasma level (μM) basis (B, D, F, H). Wyeth-14,643 (PPARα agonist) used for comparison on a dose administered (mmol/kg/day) basis (A, C, E, G).

Figure 31

Comparison of Magnitude of Change for Effects on Serum Levels of Thyroid Stimulating Hormone (A, B), Triiodothyronine (C, D), Thyroxine (E, F), and Free Thyroxine (G, H) for Perfluorobutane Sulfonic Acid, Perfluorohexane Sulfonate Potassium Salt, or Perfluorooctane Sulfonic Acid in Male Rats

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine; PFBS = perfluorobutane sulfonic acid; PFHxSK = perfluorohexane sulfonate potassium salt; PFOS = perfluorooctane sulfonic acid; WY = Wyeth-14,643.

Comparisons are made on a dose administered (mmol/kg/day) basis (A, C, E, G) and plasma level (μM) basis (B, D, F, H). Wyeth-14,643 (PPARα agonist) used for comparison on a dose administered (mmol/kg/day) basis (A, C, E, G).

Figure 32

Comparison of Magnitude of Change for Effects on Serum Levels of Thyroid Stimulating Hormone (A, B), Triiodothyronine (C, D), Thyroxine (E, F), and Free Thyroxine (G, H) for Perfluorobutane Sulfonic Acid, Perfluorohexane Sulfonate Potassium Salt, or Perfluorooctane Sulfonic Acid in Female Rats

TSH = thyroid stimulating hormone; T3 = triiodothyronine; T4 = total thyroxine; free T4 = free thyroxine; PFBS = perfluorobutane sulfonic acid; PFHxSK = perfluorohexane sulfonate potassium salt; PFOS = perfluorooctane sulfonic acid; WY = Wyeth-14,643.

Comparisons are made on a dose administered (mmol/kg/day) basis (A, C, E, G) and plasma level (μM) basis (B, D, F, H) Wyeth-14,643 (PPARα agonist) used for comparison on a dose administered (mmol/kg/day) basis (A, C, E, G).

A major target organ for these three PFAS was the liver (Figure 23, Figure 24, and Figure 25), which is consistent with the PFAS class in general. In this study, all three alkyl sulfonates increased liver weights in both males and females. However, histologic lesions of the liver varied somewhat across these chemicals and between sexes. Hepatocyte cytoplasmic alteration was only observed in PFBS males and females and PFOS females. Hepatocyte hypertrophy was observed for each chemical in each sex except for female rats administered PFHxSK, which had no significant histologic effect in the liver (Table 16 and Figure 24). Although considerable amounts of PFHxSK were measured in female plasma (90 to 240 μM), and liver weight and Cyp2b1 expression increased significantly, there was no evidence of PPARα activity via Acox1 or Cyp4a1 expression levels (Figure 24). PFOS females had a somewhat similar response of increased liver weights, Cyp2b1 expression, and hepatocellular hypertrophy (Figure 25) in the presence of minimal increases in Cyp4a1 expression. The lack of a PPARα response in females in the PFHxSK study may be a reason for the lack of hepatocellular hypertrophy response. Previous studies with PFHxS show hepatocellular hypertrophy at 3 mg/kg and higher in male rats^47^ similar to what was observed in this study of PFHxSK. In a 90-day PFBS study, doses up to 600 mg/kg were administered once per day and hepatocyte hypertrophy was not reported.^45^ It is unclear if the lack of hepatocyte hypertrophy in the PFBS 90-day study versus the observation in the current study is due to once-daily dosing versus the twice-daily dosing (e.g., C_max_ differences). Hepatocyte hypertrophy and cytoplasmic alteration were also observed with the PPARα agonist Wyeth-14,643. There was some evidence of necrosis in the highest dose group of PFBS males and females, but this was not observed in PFHxSK, PFOS, or Wyeth-14,643 groups at the doses administered.

All three alkyl sulfonates were inducers of Cyp4a1 expression to a comparable magnitude in males (Figure 29) with PFBS being the least or most potent depending on the exposure metric. Within female rats, the induction of Cyp4a1 was minimal with PFBS displaying the greatest magnitude of change, although it was still considerably lower than the male response. PFOS males displayed the greatest increase in Cyp2b1 expression (Figure 29), whereas increases in Cyp2b1 were observed in PFOS and PFBS females (Figure 30). The liver weight changes were of similar magnitude across the three chemicals, maxing at about 60% at the doses administered in males (Figure 29). There was no consistency in the magnitude of liver weight increases in females with a minimal response in PFHxSK compared to PFBS and PFOS (Figure 30). The lack of or minimal liver response in the PFHxSK females was very apparent (Figure 30) compared to the other chemicals and likely due to the lack of presumed activation of PPARα.

Perfluorinated compounds are known to mediate their effects through PPARα, CAR, pregnane X receptor (PXR), and other mechanisms.^106,107^ Hepatocyte hypertrophy observed with PFAS is likely due to the peroxisome proliferation. This is also supported by the elevated Acox1 and Cyp4a1 levels known to be inducible by PPARα agonists. Hepatocyte hypertrophy can also partially be mediated through CAR, because CAR-activated Cyp2b1 is also elevated.

Increases in serum biomarkers associated with hepatobiliary injury were observed in the PFBS and PFOS groups. In general, total bile acid concentrations had ≥ twofold increases in the higher-dose groups compared to concurrent vehicle controls. Increases of this magnitude are indicative of impaired bile flow or (intrahepatic) cholestasis, the causes of which include physical disruption of bile flow through the biliary system or perturbation of bile acid formation and excretion at the cellular level.^108^ Direct bilirubin concentration, another marker of cholestasis, was minimally elevated in the high-dose groups of PFBS and PFOS. Alkaline phosphatase (ALP) activity was mildly increased, but is considered a poor marker of cholestasis in rats.^109,110^ Thus, while it may be increased due to cholestasis, limited studies have shown an association between the administration of PPARα agonists and mild increases in serum ALP activity when the only histologic effect observed was centrilobular hypertrophy.^109,111^ In general, there were mild increases in serum ALT, AST and SDH activities in the higher-dose groups of PFBS and PFOS. These enzymes are biomarkers of hepatocellular injury. Hepatocellular necrosis was not observed on histologic evaluation; however, hepatocellular injury resulting in enzyme leakage is associated with cholestasis.^109^ In addition and similar to ALP activity, it has been shown that mild (≤1.5-fold) increases in hepatic and serum transaminases is associated with the administration of hepatic microsomal enzyme inducer compounds, including PPARα agonists.^109,111,112^ (Note: hepatocellular necrosis was observed in the early death animals administered 1,000 mg/kg/day PFBS; however, there is no corresponding clinical chemistry.) Hepatobiliary injury biomarker changes similar to those observed in the current studies have been reported in the literature.^20,47,113,114^

There were consistent decreases in cholesterol concentrations in PFBS, PFHxSK, and PFOS males and to a much lesser extent in PFBS and PFOS females (high dose only). The magnitude of the effect was greatest in PFBS males and least in PFHxSK males. Similarly, a decrease in triglyceride concentrations was observed in PFBS, PFHxSK, and PFOS males and PFOS females. These changes are consistent with the known effects of PPARα activation on lipid metabolism, which include increases in peroxisomal fatty acid β-oxidation and effects on lipid transport. Studies have shown that administration of PPARα agonists, including PFAS, to rats results in lowered circulating triglyceride and cholesterol concentrations.^47,113-116^ CAR is also an important regulator of cholesterol homeostasis and its activation may also be related to the observed lipid alterations.^117^ In addition, thyroid hormone triiodothyronine (T3) directly influences activities of critical enzymes in lipolytic pathways, and hypothyroidism in rats results in decreased blood triglyceride concentrations.^118^

Globulin concentration was decreased in males administered all three perfluoroalkyl sulfonates. In most cases, the decrease in the globulin concentration resulted in an increase in the albumin/globulin ratio. The globulin fraction of serum total protein consists of the α-, β-, and γ-globulins. Alpha- and β-globulins are produced by hepatocytes and the γ-globulins (immunoglobulins) by B-lymphocytes. It is not known whether these chemicals are causing perturbation of the hepatic or lymphocytic production/metabolism of these proteins.

In addition, changes in thyroid hormone concentrations were observed across these three perfluoroalkyl sulfonates (Figure 26, Figure 27, and Figure 28). Total thyroxine (T4), free T4, and total T3 largely decreased in a dose-response manner. In general, the magnitude of the effect was stronger in PFBS and PFOS rats compared to the PFHxSK rats (Figure 31 and Figure 32). As the thyroid hormone levels decreased in a dose-response manner, thyroid stimulating hormone (TSH) concentration was not consistently increased across the chemicals or sexes in response to the lower thyroid hormone levels, nor were there any histopathologic changes in the thyroid gland (hyperplasia/hypertrophy). A study of PFHxS exposure reported follicular epithelial hypertrophy/hyperplasia presumably in response to lower thyroid hormones as thyroid hormones were not measured.^47^ Several other studies^20,52,53,119^ of PFOS reported a similar pattern of decreased thyroid hormones without an increase in TSH. Production and release of thyroid hormones is regulated by thyroid-releasing hormone (hypothalamus) and TSH (pituitary gland) in what is referred to as the hypothalamic-pituitary-thyroid axis where decreases in circulating levels of free T4 and free T3 result in a compensatory increase in TSH. Archetypal xenobiotics that disrupt this axis in rats, causing decreases in thyroid hormones (either as a direct or indirect thyroid effect) with compensatory increases in TSH and thyroid gland follicular cell hyperplasia include sulfonamides, FD&C Red No. 3, and phenobarbital.^120^

The reason for a lack of TSH response in the face of substantially low thyroid hormone concentrations in these sulfonate studies is not clear and not consistent with a disruption in the hypothalamic-pituitary-thyroid axis. It has been shown that PFAS can bind to proteins including albumin and transthyretin (previously prealbumin), which are transport proteins for thyroid hormones. Several PFOS studies (rat and monkey) have shown low free T4 levels as measured by analog radioimmunoassays (RIA) (the method used in the present studies), but no change in free T4 levels when measured by equilibrium dialysis followed by RIA (ED-RIA).^20,51,119,121^ ED-RIA is considered the reference method for the determination of free T4 and is the standard by which other methods are compared. These findings are consistent with PFOS competing with free T4 for binding to serum proteins, creating a negative bias in the (competitive-binding) analog RIA method. A study evaluating the competitive binding of various PFAS to transthyretin was done by Weiss et al.^122^ and confirmed the ability of these sulfonates to bind to transthyretin. Nevertheless, decreases in total T4 and T3 were found in the aforementioned studies and in the current studies. It is plausible that the decreases in total T4 and T3 are related to activation of PPARα and CAR resulting in an increase in thyroxine-UDP glucuronosyltransferase and accelerated degradation of thyroxine by the liver. It is noteworthy that PFHxSK had a lower response in CAR activity with a lower effect in thyroid hormones. While the total T4 was decreased, the lack of a TSH response and the ED-RIA findings of an unaffected free T4 from exposure to PFOS by several researchers does not support a state of classical hypothyroidism and is more similar to the profile of non-thyroidal illness syndrome (a.k.a., euthyroid sick syndrome).^123^ Other researchers have also concluded, in accordance with the thyroid-related results of their studies, that the administration of PFAS (PFDA, PFOS) does not cause a classical hypothyroid state.^113,119,124^

Other sites of toxicity were the nose, forestomach, and kidney. Olfactory epithelium degeneration, hyperplasia, and inflammation were observed in PFBS males and females and PFHxSK females. Olfactory epithelium necrosis was also observed in males and females in the highest dose group of PFBS, in which mortality was observed. In addition, forestomach epithelium hyperplasia was observed in PFBS males at the highest dose administered. These nasal effects have not been observed in other PFHxSK studies, but nasal and stomach lesions were observed in male and female Sprague Dawley rats after a 90-day exposure,^45^ which the authors suggested could have been due to irritation from an oral gavage route of exposure. The pattern of nasal pathology in these studies was not indicative of gavage-related reflux by rats described by Damsch et al.^125^ Because olfactory epithelium can metabolize xenobiotics,^126^ the changes could be a direct effect of administration of PFAS. However, it is not possible to identify the underlying mechanism with the available data. None of the above lesions were observed in the Wyeth-14,643 positive controls suggesting that the mechanisms for these toxicities were not related to PPARα activation. Papilla necrosis of the kidney was also observed in the high-dose groups of PFBS males and females. A similar lesion was observed in the 90-day exposure study.^45^ Papillary necrosis in the kidney has been reported to occur with numerous therapeutic agents and chemicals. However, the mechanism is still not completely understood.^127-129^

Hematology parameters were altered for some of these chemicals. There were significant decreases in reticulocytes in PFBS males and females, PFHxSK males, and PFOS males and females. In addition, the hematocrit, hemoglobin concentration, and erythrocyte numbers were all decreased in the PFBS males. These findings are consistent with the observed hypocellularity within the bone marrow of PFOS and PFBS males and females and the decreased extramedullary hematopoiesis in the spleen of PFOS males and females. The combination of these findings suggests a suppression in erythropoiesis. The suppression may be a direct effect or may be secondary to the stress of treatment (i.e., so-called anemia of chronic stress/disease). In addition, low thyroid hormones can cause decreases in the erythron.^130^ Because rat erythrocytes have a circulating life span of approximately 60 days and the current studies were 28 days in duration, the hypocellularity in the bone marrow might not have been fully reflected in the circulating total red blood cell mass (i.e., erythrocyte count). Decreases in the erythron have also been observed in other studies with PFBS^45^ and PFHxS,^47^ but not with PFOS. None of the above lesions were observed in the Wyeth-14,643 positive controls suggesting that the mechanisms for these toxicities were not related to PPARα activation.

PFBS and PFOS were equivocal and negative, respectively, in bacterial mutagenicity tests (PFHxSK and Wyeth-14,643 were not tested), and indication of chromosomal damage was negative or equivocal (PFOS females only), as measured in an erythrocyte micronucleus assay, in male or female rats exposed to PFBS, PFHxSK, PFOS, and Wyeth-14,643. The bone marrow clearly was a target for these PFAS, as all three reduced the %PCEs in male rats as did PFBS and PFOS in female rats; however, %PCEs were not affected by PFHxSK in female rats. The cytotoxic effects of the three PFAS on PCEs in the micronucleus assay were very similar to observations in clinical chemistry tests.

In PFBS males and females, there were increases in thymic atrophy in the 1,000 mg/kg/day groups, which corresponded with a decrease in thymus weight in 1,000 mg/kg/day females. There was also a decrease in thymus weight in the male and female 500 mg/kg/day groups. This change is most likely associated with stress, as thymic atrophy is one of the commonly recognized stress responses in toxicity studies.^131^ Globulin levels decreased in PFBS males, which corresponded to increases in albumin/globulin ratios. These effects were not observed in a 90-day study of PFBS in male and female Sprague Dawley rats,^45^ in which 600 mg/kg was the highest dose administered. It may be the case that this an effect occurring at very high doses at which mortality occurred in this study.

The studies reported here and in Toxicity Study Report 97^103^ provide data for a comparison of several members of the PFAS class. The liver and thyroid hormones were common targets for PFBS, PFHxSK, and PFOS, and similar effects were observed with the PFAS carboxylates.^103^ In addition, findings of bone marrow hypocellularity, lesions of the forestomach, and lesions within the nose were present in several of the carboxylates studied.^103^ Significant decreases in free T4, total T4, and total T3 levels occurred at the lowest doses tested for several of the PFAS except for PFHxSK females. In addition, increases in PPARα and CAR-related genes occurred at the lowest doses tested for PFBS and PFOS. In some cases, this corresponded with increased liver weights at the lowest dose tested. With the inclusion of the Wyeth-14,643 compound as a PPARα agonist, it was evident that several of the non-liver responses did not appear to be mediated via PPARα as they did not occur in rats administered Wyeth-14,643. Further comparison of these chemicals will require a more in-depth evaluation of the exposure between chemicals that could include AUC or C_max_ evaluations. The 28-day studies discussed in this report help to provide exposure and mechanistic context to facilitate extrapolation of findings.