# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-OTHER-1.

## Twenty-eight-day Studies

### Perfluorobutane Sulfonic Acid (PFBS)

Nine male rats died from day 15 to day 25 in the 1,000 mg/kg/day group, and one died due to a dosing accident on day 6 (Table 4). One 250 mg/kg/day female, one 500 mg/kg/day female, and eight 1,000 mg/kg/day females died on day 25, day 21, and from day 16 to day 27, respectively (Table 4). Except for the one dosing accident, the deaths of male and female rats were considered related to treatment but cause of death was unknown. All other male and female rats survived to the end of the study.

Table 4 Mean Body Weights and Survival of Rats in the 28-day Gavage Study of Perfluorobutane Sulfonic Acid^a^

Day | Vehicle Control | | 62.6 mg/kg/day | | | 125 mg/kg/day | | | 250 mg/kg/day | | | 500 mg/kg/day | | | 1,000 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 263 | 10 | 264 | 100 | 10 | 265 | 101 | 10 | 267 | 102 | 10 | 266 | 101 | 10 | 263 | 100 | 10
8 | 285 | 10 | 282 | 99 | 10 | 290 | 102 | 10 | 291 | 102 | 10 | 284 | 100 | 10 | 266 | 93 | 9
15 | 306 | 10 | 301 | 98 | 10 | 310 | 102 | 10 | 312 | 102 | 10 | 296 | 97 | 10 | 254 | 83 | 8
22 | 326 | 10 | 318 | 98 | 10 | 332 | 102 | 10 | 331 | 102 | 10 | 311 | 95 | 10 | 262 | 81 | 3
29 | 342 | 10 | 335 | 98 | 10 | 349 | 102 | 10 | 348 | 102 | 10 | 317 | 93 | 10 | –^b^ | –^b^ | 0
Female
1 | 199 | 10 | 199 | 100 | 10 | 199 | 100 | 10 | 202 | 101 | 10 | 199 | 100 | 10 | 201 | 101 | 10
8 | 207 | 10 | 210 | 102 | 10 | 204 | 98 | 10 | 205 | 99 | 10 | 208 | 100 | 10 | 198 | 96 | 10
15 | 216 | 10 | 218 | 101 | 10 | 216 | 100 | 10 | 212 | 98 | 10 | 207 | 96 | 10 | 183 | 85 | 10
22 | 225 | 10 | 226 | 100 | 10 | 222 | 99 | 10 | 219 | 97 | 10 | 209 | 93 | 9 | 190 | 84 | 5
29 | 230 | 10 | 230 | 100 | 10 | 224 | 97 | 10 | 224 | 97 | 9 | 213 | 92 | 9 | 198 | 86 | 2

^a^ One-half the dose was administered twice daily.

^b^ No animals survived to this time point.

Seizures were recorded for one 1,000 mg/kg/day male, one 250 mg/kg/day female, two 500 mg/kg/day females, and one 1,000 mg/kg/day female; seizures were reported only once for each animal. For all the female rats, the seizures were noted prior to blood collection on day 29, and for the one male, the seizure was noted on day 22; the male animal recovered and then died on day 24. The cause of the seizures was unknown, and they were not repetitive. Additionally, in 1,000 mg/kg/day females, one rat was lethargic, two had ruffled fur, and two were thin; these findings were considered related to treatment.

The mean body weights of 62.6, 125, 250, and 500 mg/kg/day males were within 10% of the vehicle controls throughout the study (Table 4 and Figure 1). There were 17% and 19% reductions in the mean body weights of the surviving 1,000 mg/kg/day males at 15 and 22 days, respectively. The mean body weights of 62.6, 125, 250, and 500 mg/kg/day females were within 10% of the vehicle controls throughout the study. The mean body weight of females in the 1,000 mg/kg/day group was 14% less than that of the vehicle controls at the end of the study.

Figure 1

Growth Curves for Rats Administered Perfluorobutane Sulfonic Acid by Gavage for 28 Days

Parent compound concentrations are reported in ng/mL and μM for comparison to other PFAS tested (Table 5). Plasma concentrations of PFBS increased with increasing dose in both males and females. Males generally had higher (5- to 18-fold) plasma concentrations compared to females across all dose groups. Plasma concentrations normalized to dose administered (μM/mmol/kg) increased with increasing dose. In females, the normalized plasma concentration was consistent between 62.6 and 250 mg/kg/day but was more than fourfold higher in the 500 and 1,000 mg/kg/day groups compared to the lower doses (note that the 1,000 mg/kg/day group is based on sampling of two animals). There were quantifiable levels of PFBS in male controls that were 25 times lower than the lowest dose. The source of this exposure is not clear and may be a result of contamination from background exposure.

Table 5 Perfluorobutane Sulfonic Acid Concentrations in the Plasma and Liver of Rats in the 28-day Gavage Study of Perfluorobutane Sulfonic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day | 1,000 mg/kg/day
Molar Dose (mmol/kg/day) | 0 | 0.209 | 0.417 | 0.833 | 1.666 | 3.332
Male
n | 9 | 10 | 10 | 10 | 10 | 0
Plasma
Plasma Concentration (ng/mL) | 90 ± 16 | 2,222 ± 477** | 5,366 ± 1,042** | 12,430 ± 908** | 43,160 ± 6,912** | –
Plasma Concentration (μM) | 0.3 ± 0.1 | 7.4 ± 1.6** | 17.9 ± 3.5** | 41.4 ± 3.0** | 143.8 ± 23.0** | –
Normalized Plasma Concentration (μM/mmol/kg) | NA | 35.5 ± 7.6 | 42.9 ± 8.3 | 49.7 ± 3.6 | 86.3 ± 13.8 | –
Liver
Liver Concentration (ng/g) | BD | 1,245 ± 217 | 2,437 ± 528 | 4,461 ± 400 | 15,381 ± 2,590 | –
Liver Concentration (μM)^b^ | BD | 4.1 ± 0.7 | 8.1 ± 1.8 | 14.9 ± 1.3 | 51.3 ± 8.6 | –
Normalized Liver Concentration (μM/mmol/kg) | NA | 19.9 ± 3.5 | 19.5 ± 4.2 | 17.8 ± 1.6 | 30.8 ± 5.2 | –
Liver/Plasma Ratio | BD | 0.59 ± 0.05 | 0.44 ± 0.02 | 0.36 ± 0.01 | 0.35 ± 0.01 | –
Female
n | 10 | 10 | 10 | 8 | 9 | 2
Plasma
Plasma Concentration (ng/mL) | BD | 154 ± 48 | 309 ± 90 | 931 ± 207 | 8,171 ± 3,385 | 25,455 ± 23,145
Plasma Concentration (μM) | BD | 0.5 ± 0.2 | 1.0 ± 0.3 | 3.1 ± 0.7 | 27.2 ± 11.3 | 84.8 ± 77.1
Normalized Plasma Concentration (μM/mmol/kg) | NA | 2.5 ± 0.8 | 2.5 ± 0.7 | 3.7 ± 0.8 | 16.3 ± 6.8 | 25.5 ± 23.1

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s test.

BD = below detection; group did not have over 20% of its values above the limit of quantification and no statistical analyses were conducted for the endpoint. One-half the dose was administered twice daily. NA = not applicable; normalized value could not be calculated when the dose value was 0.

^a^ Tissue concentration data are presented as mean ± standard error. Tissue concentrations were not measured in 1,000 mg/kg/day males due to 100% mortality. If over 20% of the values in a group were above the limit of quantification (plasma LOQ = 25 ng/mL; liver LOQ = 500 ng/g), then values that were below the limit of quantification were substituted with half the limit of quantification value.

^b^ Density assumed to be 1.0.

Liver concentrations were measured only in males and data are presented in ng/g and μM for comparison to other PFAS tested (conversion assumed 1 g/mL for weight to volume) (Table 5). Concentrations increased with dose and were consistent between 62.6 and 250 mg/kg/day when normalized to dose administered. However, the normalized liver concentration was higher (about 30 versus about 20 μM/mmol/kg) at 500 mg/kg/day compared to the lower doses. The liver/plasma ratio in males was less than one across the doses.

Compared to vehicle controls, there were dose-related and significant increases in the relative liver weight in 62.6 mg/kg/day males and absolute and relative liver weights in the 125, 250, and 500 mg/kg/day males (Table 6). In females, there were dose-related and significant increases in the relative liver weight in the 125 mg/kg/day group and absolute and relative liver weights in the 250, 500, and 1,000 mg/kg/day groups. The organ weight changes in liver appeared to correlate with histopathologic changes observed in the liver.

Table 6 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day Gavage Study of Perfluorobutane Sulfonic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10
Necropsy Body Wt. | 342 ± 7 | 335 ± 8 | 349 ± 9 | 348 ± 9 | 317 ± 6
Heart
Absolute | 1.22 ± 0.03 | 1.15 ± 0.04 | 1.19 ± 0.03 | 1.20 ± 0.03 | 1.07 ± 0.02**
Relative | 3.56 ± 0.04 | 3.42 ± 0.06 | 3.41 ± 0.06 | 3.46 ± 0.03 | 3.36 ± 0.06*
R. Kidney
Absolute | 1.00 ± 0.04 | 0.98 ± 0.03 | 1.05 ± 0.03 | 1.07 ± 0.03 | 1.11 ± 0.03*
Relative | 2.93 ± 0.06 | 2.93 ± 0.05 | 3.01 ± 0.07 | 3.07 ± 0.04 | 3.49 ± 0.08**
Liver
Absolute | 12.06 ± 0.46 | 13.40 ± 0.42 | 15.30 ± 0.53** | 17.99 ± 0.78** | 18.52 ± 0.40**
Relative | 35.23 ± 0.79 | 39.90 ± 0.48** | 43.78 ± 0.75** | 51.48 ± 0.88** | 58.33 ± 0.43**
Thymus
Absolute | 0.417 ± 0.026 | 0.394 ± 0.018 | 0.429 ± 0.021 | 0.390 ± 0.019 | 0.300 ± 0.015**
Relative | 1.22 ± 0.07 | 1.17 ± 0.03 | 1.23 ± 0.06 | 1.12 ± 0.04 | 0.94 ± 0.04**
Female
n | 10 | 10 | 10 | 9 | 9
Necropsy Body Wt. | 230 ± 4 | 230 ± 3 | 224 ± 4 | 224 ± 3 | 213 ± 4**
Heart
Absolute | 0.86 ± 0.02 | 0.86 ± 0.02 | 0.84 ± 0.02 | 0.80 ± 0.02 | 0.78 ± 0.02*
Relative | 3.73 ± 0.08 | 3.75 ± 0.07 | 3.76 ± 0.07 | 3.56 ± 0.07 | 3.68 ± 0.09
R. Kidney
Absolute | 0.67 ± 0.01 | 0.71 ± 0.02 | 0.70 ± 0.01 | 0.71 ± 0.02 | 0.69 ± 0.02
Relative | 2.93 ± 0.05 | 3.07 ± 0.04* | 3.11 ± 0.04* | 3.17 ± 0.08** | 3.25 ± 0.05**
Liver
Absolute | 7.79 ± 0.26 | 8.14 ± 0.17 | 8.17 ± 0.20 | 9.39 ± 0.17** | 10.49 ± 0.35**
Relative | 33.83 ± 0.90 | 35.48 ± 0.46 | 36.46 ± 0.50* | 41.87 ± 0.59** | 49.32 ± 1.10**
Spleen
Absolute | 0.591 ± 0.028 | 0.586 ± 0.013 | 0.540 ± 0.022 | 0.556 ± 0.014 | 0.522 ± 0.012*
Relative | 2.56 ± 0.10 | 2.56 ± 0.06 | 2.41 ± 0.09 | 2.48 ± 0.06 | 2.46 ± 0.03
Thymus
Absolute | 0.288 ± 0.013 | 0.273 ± 0.008 | 0.286 ± 0.015 | 0.274 ± 0.016 | 0.236 ± 0.013**
Relative | 1.25 ± 0.06 | 1.19 ± 0.03 | 1.28 ± 0.07 | 1.23 ± 0.08 | 1.11 ± 0.06

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). No data presented for 1,000 mg/kg/day males or females due to high mortality. One-half the dose was administered twice daily.

In males, absolute and relative heart and thymus weights in the 500 mg/kg/day group were significantly decreased (Table 6). Male kidney weights (absolute and relative to body weight) were increased in the 500 mg/kg/day group. In females, dose-related and significant increases in the relative right kidney weights occurred in all the dose groups. Absolute spleen, heart, and thymus weights in the 500 mg/kg/day females were significantly lower than those of the vehicle controls. The biological significance of these changes is not clear.

There was no clinical pathology interpretation for the 1,000 mg/kg/day male and female rats due to the high mortality in these groups. Mild significant decreases in the male rat erythron were observed, most consistently in those administered 125 mg/kg/day or greater; this was characterized by significantly decreased hematocrit values, hemoglobin concentrations, and erythrocyte and reticulocyte counts compared to those of the vehicle control group (Table 7). In the female rats, the reticulocyte count was significantly decreased in the 125 mg/kg/day and higher-dose groups. Several other significant changes were observed but were not considered toxicologically relevant.

Table 7 Selected Hematology and Clinical Chemistry Data for Rats in the 28-day Gavage Study of Perfluorobutane Sulfonic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
Male
Hematology
n | 9 | 10 | 10 | 10 | 10
Hematocrit (%) | 52.1 ± 0.7 | 50.5 ± 0.4* | 50.3 ± 0.6* | 49.9 ± 0.5** | 47.9 ± 0.5**
Manual Hematocrit (%) | 47 ± 1 | 46 ± 1 | 45 ± 1 | 45 ± 1 | 44 ± 1
Hemoglobin (g/dL) | 15.6 ± 0.2 | 15.3 ± 0.1 | 15.1 ± 0.2* | 15.0 ± 0.1* | 14.4 ± 0.2**
Erythrocytes (10^6^/μL) | 8.80 ± 0.08 | 8.50 ± 0.08* | 8.50 ± 0.10* | 8.40 ± 0.12** | 8.10 ± 0.11**
Reticulocytes (10^3^/μL) | 200.1 ± 6.3 | 179.1 ± 8.4 | 175.2 ± 8.1* | 161.0 ± 8.4** | 137.6 ± 9.5**
Clinical Chemistry
n | 9 | 10 | 10 | 10 | 9
Urea Nitrogen (mg/dL) | 18.0 ± 0.6 | 17.8 ± 0.4 | 18.6 ± 0.4 | 20.0 ± 0.4** | 20.7 ± 1.2*
Total Protein (g/dL) | 6.6 ± 0.0 | 6.4 ± 0.1* | 6.4 ± 0.1** | 6.3 ± 0.1** | 6.0 ± 0.1**
Albumin (g/dL) | 4.3 ± 0.0 | 4.2 ± 0.1 | 4.2 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0
Globulin (g/dL) | 2.3 ± 0.0 | 2.3 ± 0.1* | 2.2 ± 0.0** | 2.0 ± 0.1** | 1.7 ± 0.0**
Albumin/Globulin Ratio | 1.8 ± 0.0 | 1.9 ± 0.1 | 2.0 ± 0.0* | 2.2 ± 0.1** | 2.6 ± 0.1**
Cholesterol (mg/dL) | 133 ± 6 | 110 ± 4** | 93 ± 2** | 75 ± 5** | 33 ± 2**
Triglycerides (mg/dL) | 111 ± 8 | 149 ± 18 | 121 ± 13 | 101 ± 15 | 34 ± 6**
Alanine Aminotransferase (IU/L) | 60 ± 2^b^ | 59 ± 2 | 52 ± 2 | 65 ± 2 | 91 ± 7**
Alkaline Phosphatase (IU/L) | 208 ± 6 | 207 ± 10 | 220 ± 9 | 239 ± 9* | 297 ± 14**
Aspartate Aminotransferase (U/L) | 61 ± 1^b^ | 65 ± 2 | 62 ± 2 | 66 ± 2 | 75 ± 3**^c^
Sorbitol Dehydrogenase (IU/L) | 5 ± 1^b^ | 5 ± 1 | 5 ± 1 | 8 ± 1 | 8 ± 1*
Direct Bilirubin (mg/dL) | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.03 ± 0.00 | 0.04 ± 0.00**^c^
Total Bile Acids (μmol/L) | 16.0 ± 3.4 | 14.0 ± 2.9 | 8.5 ± 1.2 | 17.5 ± 1.4 | 30.6 ± 4.5*
Total Thyroxine (μg/dL) | 3.34 ± 0.18 | 0.90 ± 0.09** | 0.22 ± 0.05** | 0.10 ± 0.03** | 0.29 ± 0.07**
Free Thyroxine (ng/dL) | 2.09 ± 0.09 | 0.64 ± 0.04** | 0.32 ± 0.01** | 0.30 ± 0.00** | 0.30 ± 0.00**
Total Triiodothyronine (ng/dL) | 117.76 ± 8.31 | 87.85 ± 5.00* | 64.48 ± 3.08** | 60.20 ± 4.10** | 50.44 ± 0.44**
Thyroid Stimulating Hormone (ng/mL) | 23.27 ± 2.79 | 26.64 ± 3.93 | 25.51 ± 2.53 | 23.76 ± 2.58 | 32.19 ± 3.15
Female
n | 10 | 10 | 10 | 9 | 9
Hematology
Reticulocytes (10^3^/μL) | 208.5 ± 16.6 | 181.2 ± 10.5 | 152.1 ± 6.3** | 122.4 ± 17.7** | 110.9 ± 15.8**
Clinical Chemistry
Cholesterol (mg/dL) | 103 ± 4 | 94 ± 3 | 94 ± 5 | 105 ± 7 | 85 ± 4*
Alanine Aminotransferase (IU/L) | 48 ± 1 | 46 ± 2 | 48 ± 3 | 60 ± 2** | 71 ± 5**
Alkaline Phosphatase (IU/L) | 147 ± 4 | 147 ± 8 | 153 ± 10 | 167 ± 11 | 195 ± 8**
Aspartate Aminotransferase (IU/L) | 54 ± 1 | 58 ± 1 | 63 ± 7 | 58 ± 1 | 61 ± 2**
Total Bilirubin (mg/dL) | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0**
Direct Bilirubin (mg/dL) | 0.03 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.03 ± 0.00 | 0.04 ± 0.00*
Total Bile Acids (μmol/L) | 9.8 ± 2.3 | 7.6 ± 1.0 | 14.9 ± 3.3 | 26.2 ± 5.4** | 52.4 ± 6.7**
Total Thyroxine (μg/dL) | 3.10 ± 0.15 | 1.48 ± 0.09** | 1.12 ± 0.05** | 0.90 ± 0.08** | 0.97 ± 0.09**
Free Thyroxine (ng/dL) | 1.54 ± 0.08 | 0.72 ± 0.05** | 0.55 ± 0.03** | 0.48 ± 0.04** | 0.36 ± 0.03**
Total Triiodothyronine (ng/dL) | 89.29 ± 5.57 | 61.81 ± 3.34** | 61.53 ± 3.33** | 52.37 ± 1.87** | 51.28 ± 0.87**
Thyroid Stimulating Hormone (ng/mL) | 11.92 ± 1.29 | 14.56 ± 1.06 | 12.55 ± 1.06 | 14.40 ± 1.15 | 13.76 ± 0.99

* Significantly different (p ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. No data presented for 1,000 mg/kg/day males or females due to high mortality. Statistical tests were performed on unrounded data. One-half the dose was administered twice daily.

^b^ n = 8.

^c^ n = 10.

Mild significant increases in blood urea nitrogen (BUN) concentrations were observed in the 250 and 500 mg/kg/day male rats (Table 7). Mild increases in BUN without increases in creatinine is most consistent with decreased water intake (i.e., dehydration). Total protein concentrations were decreased in all male dose groups; these decreases were due to decreases in globulin concentrations, which resulted in increases in the albumin/globulin ratio. Cholesterol concentrations were decreased in all male dose groups and in the 500 mg/kg/day females, and triglyceride concentrations were decreased in the 500 mg/kg/day males.

Alkaline phosphatase (ALP), alanine aminotransferase (ALT), and aspartate aminotransferase (AST) activities were significantly increased in the 500 mg/kg/day groups; occasionally, one of these enzyme activities was also increased in the 250 mg/kg/day groups (Table 7). Additionally, sorbitol dehydrogenase (SDH) activity was significantly increased in the 500 mg/kg/day male rats. Direct bilirubin concentrations in the 500 mg/kg/day males, and total and direct bilirubin concentrations in the 500 mg/kg/day females were significantly increased. Total bile acid concentrations were significantly increased in the 500 mg/kg/day males and the 250 and 500 mg/kg/day females.

Total thyroxine (T4), free T4, and total triiodothyronine (T3) concentrations were significantly decreased in all male and female dose groups (Table 7). TSH levels were unchanged.

Male and female rats administered PFBS exhibited a significant increase in expression of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2 compared to the controls, indicating significant increased peroxisome proliferator-activated receptor alpha (PPARα) and CAR activity (Table 8). Males displayed a greater fold increase in PPARα-related gene expression (Cyp4a1) compared to controls than females when compared to their controls, whereas increases in expression of CAR-related genes (Cyp2b1, Cyp2b2) were more prominent in female rats. Expression of Acox1 was the least sensitive of the genes evaluated, whereas Cyp2b1 displayed the greatest fold changes in both males and females when compared to their respective controls. Acyl-CoA oxidase activity was increased in the 250 and 500 mg/kg/day groups of males compared to controls.

Table 8 Hepatic Parameters for Rats in the 28-day Gavage Study of Perfluorobutane Sulfonic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day | 1,000 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10 | 0
Enzyme Activity
Acyl-CoA Oxidase (nmol/min/mg) | 2.048 ± 0.063 | 2.042 ± 0.073 | 2.110 ± 0.067 | 4.051 ± 0.114** | 8.896 ± 0.575** | –
Gene Expression
Acox1 | 1.04 ± 0.10 | 1.15 ± 0.17 | 1.60 ± 0.15* | 2.44 ± 0.22** | 5.04 ± 0.63** | –
Cyp4a1 | 1.12 ± 0.17 | 2.83 ± 0.49** | 5.57 ± 0.64** | 11.85 ± 1.43** | 26.72 ± 3.26** | –
Cyp2b1 | 1.59 ± 0.41 | 11.66 ± 2.78** | 32.78 ± 6.98** | 50.37 ± 17.55** | 99.69 ± 24.85** | –
Cyp2b2 | 1.27 ± 0.25 | 7.72 ± 1.42** | 12.21 ± 1.03** | 18.34 ± 1.83** | 32.92 ± 4.06** | –
Female
n | 10 | 10 | 10 | 9 | 9 | 2
Gene Expression
Acox1 | 1.10 ± 0.18 | 1.44 ± 0.15 | 1.84 ± 0.29 | 2.56 ± 0.33** | 3.45 ± 0.48** | 5.04 ± 0.07**
Cyp4a1 | 1.13 ± 0.19 | 1.61 ± 0.17* | 1.93 ± 0.36* | 2.43 ± 0.26** | 5.12 ± 1.27** | 8.83 ± 1.71**
Cyp2b1 | 1.51 ± 0.42 | 48.97 ± 12.36** | 152.85 ± 27.72** | 392.32 ± 125.3** | 770.07 ± 189.3** | 2,102.7 ± 1,712**
Cyp2b2 | 1.89 ± 0.75 | 36.89 ± 6.65** | 81.44 ± 15.88** | 131.73 ± 19.14** | 220.07 ± 40.68** | 265.25 ± 1.42**

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Hepatic parameters were not measured in 1,000 mg/kg/day males due to 100% mortality. Gene expression data are presented as fold change values from the base-signal values. One-half the dose was administered twice daily.

Cauda epididymal sperm counts (both total and normalized to weight) were generally lower (7% to 16%) in assessed males administered PFBS than in the vehicle controls; however, none of these changes attained statistical significance (Table A-1). The testicular spermatid count in 250 mg/kg/day males was lower (10%) than the vehicle control group. When normalized to total testicular weight, counts in the 250 and 500 mg/kg/day groups were 12% and 10% lower, respectively, than the vehicle control group. These differences did not attain statistical significance, but the trend was significant. Left testis and left epididymis weights were not affected by PFBS administration. The histopathologic finding of germinal epithelium degeneration in the testis was noted in one male in the 1,000 mg/kg/day group (sperm assessments were not made in this group due to early mortality). Serum testosterone levels assessed at necropsy in dosed males were similar to the vehicle control group level (Table A-1).

Inspection of the daily vaginal cytology data indicated that the 250 and 500 mg/kg/day females displayed abnormal cyclicity with respect to diestrus (which comprised 68% and 94% of the daily observations for these groups versus 55% in the vehicle control) (Table 9 and Table A-2, Figure A-1). Markov analysis demonstrated that females administered 250 or 500 mg/kg/day PFBS displayed alteration in the estrous cycle (extended diestrus in the 250 mg/kg/day females, irregular or not cycling in the 500 mg/kg/day females). Females in the 500 mg/kg/day dose group were not cycling (Table 9 and Figure A-1).

Table 9 Estrous Cycle Characterization for Female Rats in the 28-day Gavage Study of Perfluorobutane Sulfonic Acid^a^

| Vehicle Control | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
n | 10 | 10 | 5 | 0
Necropsy Body Wt. (g) | 230 ± 4 | 224 ± 4 | 224 ± 3^b^ | 213 ± 4**^b^
Number of Estrous Cycles | 2.0 ± 0.21 | 2.0 ± 0.21 | 1.2 ± 0.20 | –^c^
Estrous Cycle Length (days) | 5.0 ± 0.20 | 5.0 ± 0.09 | 5.1 ± 0.10 | –
Estrous Stages (% of cycle)
Diestrus | 55.0 | 55.1 | 67.8 | 93.6
Proestrus | 8.8 | 5.1 | 5.9 | 0.9
Estrus | 33.8 | 38.5 | 21.7 | 3.6
Metestrus | 1.9 | 1.3 | 1.3 | 1.8
Uncertain Diagnosis | 0.6 | 0.0 | 3.3 | 0.0
Markov Analysis
| Overall | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
Overall Tests | p < 0.001 | p = 0.449 | p < 0.001 | p < 0.001
Extended Diestrus | p < 0.001 | p = 0.063 | p < 0.001 | p < 0.001

** Significantly different (p ≤ 0.01) from the vehicle control group by Williams’ or Dunnett’s test.

^a^ Necropsy body weights, number of estrous cycles, and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunn’s test (estrous cycle number and length). N indicates that the dose group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dose group had more departures from normal cycling than did the vehicle control group. Tests for equality of all transition matrices are shown in the vehicle control column (Markov analysis). One-half the dose was administered twice daily.

^b^ n = 9.

^c^ Animals were not cycling.

#### Pathology

The morphologic features of the lesions discussed in this section are presented in the Histopathologic Descriptions section following the Wyeth-14,643 results.

Liver: Compared to the respective vehicle control groups, the incidences of hepatocyte hypertrophy were significantly increased in 125 mg/kg/day and greater groups of males and in 500 and 1,000 mg/kg/day groups of females (Table 10). Hepatocyte cytoplasmic alteration was significantly increased in 500 and 1,000 mg/kg/day males and females. The average severity of these changes increased with increasing dose. In general, both lesions were of minimal to mild severity. Hepatocyte necrosis was increased, but not significantly, in 1,000 mg/kg/day females, and the necrosis was of minimal severity. One male in the 1,000 mg/kg/day group had hepatocyte necrosis.

Table 10 Incidences of Selected Nonneoplastic Lesions in Rats in the 28-day Gavage Study of Perfluorobutane Sulfonic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day | 1,000 mg/kg/day
Male
Liver^b^ | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration^c^ | 0 | 0 | 1 (1.0)^d^ | 0 | 10** (1.0) | 9** (1.6)
Hepatocyte, Hypertrophy | 0 | 0 | 9** (1.0) | 10** (1.3) | 10** (1.7) | 9** (2.1)
Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (3.0)
Bone Marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hypocellularity | 0 | 0 | 0 | 0 | 0 | 10** (2.6)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Degeneration | 0 | 0 | 3 (1.0) | 7** (1.4) | 9** (1.6) | 9** (2.3)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 2 (1.0) | 5* (1.2) | 9** (1.6) | 5* (1.4)
Olfactory Epithelium, Inflammation, Suppurative | 0 | 0 | 0 | 2 (1.0) | 2 (1.5) | 9** (2.4)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 7** (2.0)
Stomach, Forestomach | (10) | (0) | (0) | (10) | (10) | (10)
Epithelium, Hyperplasia | 0 | – | – | 0 | 1 (1.0) | 6** (1.2)
Thymus | (10) | (10) | (10) | (10) | (10) | (10)
Atrophy | 0 | 0 | 0 | 0 | 0 | 5* (3.2)
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Papilla, Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Female
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration | 0 | 0 | 0 | 0 | 9** (1.0) | 10** (2.2)
Hepatocyte, Hypertrophy | 0 | 0 | 0 | 0 | 8** (1.0) | 10** (2.1)
Necrosis | 0 | 0 | 0 | 0 | 0 | 3 (1.0)
Bone Marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hypocellularity | 0 | 0 | 0 | 0 | 0 | 9** (2.9)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Degeneration | 0 | 0 | 4* (1.0) | 9** (1.3) | 9** (1.9) | 7** (2.0)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 8** (1.1) | 9** (1.4) | 4* (1.5)
Olfactory Epithelium, Inflammation, Suppurative | 0 | 0 | 1 (1.0) | 1 (1.0) | 2 (1.5) | 8** (2.5)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 6** (1.8)
Thymus | (10) | (10) | (10) | (10) | (10) | (10)
Atrophy | 0 | 0 | 0 | 0 | 0 | 5* (3.0)
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Papilla, Necrosis | 0 | 0 | 0 | 0 | 0 | 4* (1.5)

* Significantly different (p ≤ 0.05) from the vehicle control group by the Fisher exact test.

** p ≤ 0.01.

^a^ One-half the dose was administered twice daily. High mortality observed in the 1,000 mg/kg/day groups (survival at terminal necropsy: 0/10 males, 2/10 females).

^b^ Number of animals with tissue examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Bone Marrow: The incidence of bone marrow hypocellularity was significantly increased in the 1,000 mg/kg/day males and females (Table 10). Bone marrow hypocellularity was mild to marked in severity.

Nose: In males, the incidences of olfactory epithelium degeneration and olfactory epithelium hyperplasia in the 250, 500, and 1,000 mg/kg/day groups and olfactory epithelium inflammation suppurative and olfactory epithelium necrosis in the 1,000 mg/kg/day groups were significantly increased compared to those of the vehicle controls (Table 10). The average severity of these changes, except olfactory epithelium hyperplasia, increased with increasing dose. In females, the incidences of olfactory epithelium degeneration at 125, 250, 500, and 1,000 mg/kg/day, olfactory epithelium hyperplasia at 250, 500, and 1,000 mg/kg/day, and olfactory epithelium inflammation suppurative and olfactory epithelium necrosis at 1,000 mg/kg/day were significantly increased compared to vehicle controls (Table 10). The average severity of these changes increased with increasing dose.

Stomach, Forestomach: In males, the incidence of epithelium hyperplasia was significantly increased in the 1,000 mg/kg/day group (Table 10). Epithelium hyperplasia was of minimal to mild severity.

Thymus: The incidences of atrophy were significantly increased in the 1,000 mg/kg/day males and females (Table 10). Severity of atrophy was mild to marked.

Kidney: The incidence of papilla necrosis was significantly increased in 1,000 mg/kg/day females (Table 10). One male rat in the 1,000 mg/kg/day group also had papilla necrosis (Table 10). The change was of minimal to mild severity.

### Perfluorohexane Sulfonate Potassium Salt (PFHxSK)

All rats survived to scheduled euthanasia (Table 11). There were no significant treatment-related clinical observations in male or female rats.

Table 11 Mean Body Weights and Survival of Rats in the 28-day Gavage Study of Perfluorohexane Sulfonate Potassium Salt

Day | Vehicle Control | | 0.625 mg/kg/day | | | 1.25 mg/kg/day | | | 2.5 mg/kg/day | | | 5 mg/kg/day | | | 10 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 275 | 10 | 272 | 99 | 10 | 271 | 99 | 10 | 272 | 99 | 10 | 273 | 100 | 10 | 273 | 100 | 10
8 | 292 | 10 | 295 | 101 | 10 | 292 | 100 | 10 | 292 | 100 | 10 | 292 | 100 | 10 | 291 | 100 | 10
15 | 314 | 10 | 316 | 101 | 10 | 309 | 99 | 10 | 310 | 99 | 10 | 314 | 100 | 10 | 312 | 99 | 10
22 | 322 | 10 | 329 | 102 | 10 | 322 | 100 | 10 | 326 | 101 | 10 | 327 | 102 | 10 | 323 | 100 | 10
29 | 336 | 10 | 346 | 103 | 10 | 342 | 102 | 10 | 343 | 102 | 10 | 341 | 102 | 10 | 335 | 100 | 10
| Vehicle Control | | 3.12 mg/kg/day | | | 6.25 mg/kg/day | | | 12.5 mg/kg/day | | | 25 mg/kg/day | | | 50 mg/kg/day
| Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Female
1 | 201 | 10 | 200 | 100 | 10 | 202 | 100 | 10 | 199 | 99 | 10 | 198 | 99 | 10 | 200 | 99 | 10
8 | 205 | 10 | 208 | 101 | 10 | 206 | 101 | 10 | 210 | 102 | 10 | 206 | 100 | 10 | 208 | 101 | 10
15 | 213 | 10 | 219 | 103 | 10 | 217 | 102 | 10 | 219 | 103 | 10 | 216 | 101 | 10 | 216 | 101 | 10
22 | 217 | 10 | 224 | 103 | 10 | 229 | 105 | 10 | 225 | 104 | 10 | 223 | 103 | 10 | 222 | 102 | 10
29 | 224 | 10 | 233 | 104 | 10 | 236 | 106 | 10 | 227 | 102 | 10 | 230 | 103 | 10 | 230 | 103 | 10

The mean body weights of dose groups of males and females were within 10% of the respective vehicle control groups throughout the study (Table 11 and Figure 2).

Figure 2

Growth Curves for Rats Administered Perfluorohexane Sulfonate Potassium Salt by Gavage for 28 Days

Parent chemical concentrations are reported in ng/mL and μM for comparison to other PFAS tested (Table 12). Plasma concentrations of PFHxS increased with increasing dose in males and females. Although females were administered doses five times higher than those administered to males, the female plasma concentrations were about half of male concentrations. When adjusted for dose (μM/mmol/kg), plasma concentrations were 9- to 10-fold higher in males compared to females. In both males and females, normalized plasma concentrations steadily decreased with increasing dose. The quantifiable levels of PFHxS in male and female vehicle controls were 556 and 231 times lower than the lowest doses, respectively. The source of this exposure is not clear and may be a result of contamination from background exposure.

Table 12 Perfluorohexane Sulfonic Acid Concentrations in the Plasma and Liver of Rats in the 28-day Gavage Study of Perfluorohexane Sulfonate Potassium Salt^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
n | 10 | 10 | 10 | 10 | 10 | 10
Molar Dose (mmol/kg/day) | 0 | 0.0016 | 0.0031 | 0.0062 | 0.0125 | 0.025
Male
Plasma
Plasma Concentration (ng/mL) | 102 ± 14 | 66,760 ± 3,518** | 92,080.0 ± 3,348** | 129,000.0 ± 5,504** | 161,700 ± 2,512** | 198,300 ± 4,996**
Plasma Concentration (μM) | 0.3 ± 0.0 | 166.9 ± 8.8** | 230.1 ± 8.4** | 322.4 ± 13.8** | 404.1 ± 6.3** | 495.6 ± 12.5**
Normalized Plasma Concentration (μM/mmol/kg) | NA | 106,816.0 ± 5,629.3 | 73,664.0 ± 2,678.3 | 51,600.0 ± 2,201.4 | 32,340.0 ± 502.5 | 19,830.0 ± 499.6
Liver
Liver Concentration (ng/g) | BD | 39,880 ± 1,314 | 58,590 ± 1,976 | 98,250 ± 3,073** | 161,700 ± 9,669 | 241,300 ± 9,090
Liver Concentration (μM)b | BD | 99.7 ± 3.3 | 146.4 ± 4.9 | 245.6 ± 7.7 | 404.1 ± 24.2 | 603.1 ± 22.7
Normalized Liver Concentration (μM/mmol/kg) | NA | 63,808.0 ± 2,102.7 | 46,872.0 ± 1,580.6 | 39,300.0 ± 1,229.1 | 32,340.0 ± 1,933.8 | 24,130.0 ± 909.0
Liver/Plasma Ratio | BD | 0.61 ± 0.03 | 0.64 ± 0.02 | 0.77 ± 0.04 | 1.00 ± 0.05 | 1.22 ± 0.04
| Vehicle Control | 3.12 mg/kg/day | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day
Molar Dose (mmol/kg/day) | 0 | 0.0078 | 0.0156 | 0.0312 | 0.0625 | 0.125
Female
Plasma
Plasma Concentration (ng/mL) | 175 ± 22 | 37,030 ± 1,651** | 50,410 ± 1,552** | 63,820 ± 3,201** | 83,820 ± 3,740** | 95,510 ± 3,745**
Plasma Concentration (μM) | 0.4 ± 0.1 | 92.5 ± 4.1** | 126.0 ± 3.9** | 159.5 ± 8.0** | 209.5 ± 9.3** | 238.7 ± 9.4**
Normalized Plasma Concentration (μM/mmol/kg) | NA | 11,868.6 ± 529.1 | 8,065.6 ± 248.3 | 5,105.6 ± 256.1 | 3,352.8 ± 149.6 | 1,910.2 ± 74.9

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s test.

BD = below detection; group did not have over 20% of its values above the limit of quantification and no statistical analyses were conducted for the endpoint.

^a^ Tissue concentration data are presented as mean ± standard error. If over 20% of the values in a group were above the limit of quantification (plasma LOQ = 23.4 ng/mL; liver LOQ = 500 ng/g), then values that were below the limit of quantification were substituted with half the limit of quantification value. NA = not applicable; normalized value could not be calculated when the dose value was 0.

^b^ Density assumed to be 1.0.

Liver concentrations were measured only in males and data are presented in ng/g and μM for comparison to other PFAS tested (conversion assumed 1 g/mL for weight to volume) (Table 12). Concentrations increased with dose, but when normalized to dose, liver concentrations steadily decreased as dose increased similar to the normalized plasma concentrations. The liver/plasma ratio ranged from 0.61 to 1.22.

In males, there were dose-related and significant increases in the absolute and relative liver weights in the 1.25 mg/kg/day and greater groups (Table 13). In females, there were dose-related and significant increases in the absolute and relative liver weights in all dose groups. Liver weights appeared to correlate with histopathologic changes in the liver.

Table 13 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day Gavage Study of Perfluorohexane Sulfonate Potassium Salt^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy Body Wt. | 336 ± 7 | 346 ± 8 | 342 ± 7 | 343 ± 6 | 341 ± 5 | 335 ± 6
R. Adrenal gland
Absolute | 0.0212 ± 0.0006 | 0.0211 ± 0.0008 | 0.0212 ± 0.0008 | 0.0192 ± 0.0006 | 0.0185 ± 0.0005* | 0.0196 ± 0.0007*
Relative | 0.06 ± 0.00 | 0.06 ± 0.00 | 0.06 ± 0.00 | 0.06 ± 0.00* | 0.05 ± 0.00* | 0.06 ± 0.00*
R. Kidney
Absolute | 1.01 ± 0.03 | 0.99 ± 0.03 | 1.01 ± 0.02 | 1.01 ± 0.02 | 1.03 ± 0.03 | 1.08 ± 0.03
Relative | 3.01 ± 0.07 | 2.85 ± 0.07 | 2.97 ± 0.04 | 2.94 ± 0.05 | 3.02 ± 0.08 | 3.23 ± 0.05*
Liver
Absolute | 11.36 ± 0.32 | 12.10 ± 0.36 | 12.58 ± 0.25* | 13.30 ± 0.35** | 15.24 ± 0.56** | 17.43 ± 0.52**
Relative | 33.77 ± 0.36 | 34.91 ± 0.43 | 36.81 ± 0.39** | 38.79 ± 0.62** | 44.61 ± 1.16** | 51.96 ± 1.24**
| Vehicle Control | 3.12 mg/kg/day | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day
Female
Necropsy Body Wt. | 224 ± 3 | 233 ± 4 | 236 ± 5* | 227 ± 4 | 230 ± 3 | 230 ± 3
R. Adrenal gland
Absolute | 0.0237 ± 0.0008 | 0.0247 ± 0.0015 | 0.0248 ± 0.0013 | 0.0273 ± 0.0004* | 0.0267 ± 0.0011* | 0.0283 ± 0.0011**
Relative | 0.11 ± 0.00 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.01*
Liver
Absolute | 7.14 ± 0.20 | 8.02 ± 0.26* | 8.24 ± 0.30* | 7.86 ± 0.25* | 8.07 ± 0.16** | 8.80 ± 0.24**
Relative | 31.92 ± 0.68 | 34.36 ± 0.88* | 34.80 ± 0.72** | 34.58 ± 0.66** | 35.14 ± 0.51** | 38.16 ± 0.75**

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

In males, the relative right adrenal gland weight in the 2.5 mg/kg/day group and absolute and relative weights in the 5 and 10 mg/kg/day groups were significantly lower than those of the vehicle control group (Table 13). Relative right kidney weight in the 10 mg/kg/day males was significantly increased. In females, absolute right adrenal gland weights in the 12.5, 25, and 50 mg/kg/day groups and the relative right adrenal gland weight in the 50 mg/kg/day group were significantly increased. Biological significance of these changes is not clear.

Reticulocyte counts were significantly decreased in the 1.25 mg/kg/day and higher male groups (Table 14).

Table 14 Selected Hematology and Clinical Chemistry Data for Rats in the 28-day Gavage Study of Perfluorohexane Sulfonate Potassium Salt^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematology
Reticulocytes (10^3^/μL) | 182.0 ± 7.4 | 163.6 ± 9.1 | 155.4 ± 7.6* | 152.6 ± 5.7* | 133.7 ± 7.4** | 141.0 ± 6.6**
Clinical Chemistry
Total Protein (g/dL) | 6.4 ± 0.1 | 6.2 ± 0.0 | 6.3 ± 0.1 | 6.2 ± 0.1 | 6.4 ± 0.1 | 6.3 ± 0.1
Albumin (g/dL) | 4.2 ± 0.1 | 4.0 ± 0.0 | 4.1 ± 0.0 | 4.1 ± 0.1 | 4.2 ± 0.1 | 4.4 ± 0.1
Globulin (g/dL) | 2.2 ± 0.0 | 2.2 ± 0.0 | 2.3 ± 0.1 | 2.1 ± 0.0 | 2.1 ± 0.0 | 1.9 ± 0.1**
Albumin/Globulin Ratio | 1.9 ± 0.0 | 1.9 ± 0.0 | 1.8 ± 0.1 | 1.9 ± 0.1 | 2.0 ± 0.0 | 2.3 ± 0.1**
Cholesterol (mg/dL) | 109 ± 4 | 101 ± 3 | 96 ± 3* | 92 ± 3** | 87 ± 5** | 73 ± 3**
Triglycerides (mg/dL) | 138 ± 6 | 124 ± 7 | 136 ± 13 | 107 ± 14* | 89 ± 8** | 87 ± 11**
Testosterone (ng/mL) | 4.60 ± 0.68 | 7.74 ± 1.44 | 6.50 ± 1.66 | 8.11 ± 1.75 | 5.88 ± 1.14 | 7.14 ± 1.27
Total Thyroxine (μg/dL) | 4.24 ± 0.23 | 2.39 ± 0.08** | 1.70 ± 0.06** | 1.47 ± 0.07** | 1.54 ± 0.09** | 1.66 ± 0.05**
Free Thyroxine (ng/dL) | 1.74 ± 0.10 | 0.82 ± 0.07** | 0.48 ± 0.03** | 0.36 ± 0.02** | 0.39 ± 0.03** | 0.39 ± 0.03**
Total Triiodothyronine (ng/dL) | 85.18 ± 5.74 | 66.21 ± 4.20* | 58.67 ± 2.87** | 54.25 ± 2.31** | 52.50 ± 1.42** | 56.83 ± 3.96**
Thyroid Stimulating Hormone (ng/mL) | 17.31 ± 2.39 | 18.58 ± 1.95 | 20.78 ± 1.82 | 21.88 ± 3.13 | 19.69 ± 1.75 | 24.96 ± 4.31
| Vehicle Control | 3.12 mg/kg/day | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day
Female
Clinical Chemistry
Total Thyroxine (μg/dL) | 3.99 ± 0.19 | 3.53 ± 0.20 | 3.37 ± 0.17* | 2.97 ± 0.11** | 2.96 ± 0.19** | 2.69 ± 0.14**
Free Thyroxine (ng/dL) | 1.52 ± 0.10 | 1.32 ± 0.10 | 1.28 ± 0.13 | 1.01 ± 0.05** | 1.07 ± 0.09** | 0.94 ± 0.08**
Total Triiodothyronine (ng/dL) | 111.83 ± 7.60 | 98.89 ± 4.94 | 99.05 ± 7.29 | 96.71 ± 6.36 | 96.89 ± 6.04 | 91.51 ± 5.49
Thyroid Stimulating Hormone (ng/mL) | 12.40 ± 0.89 | 15.66 ± 1.07 | 15.72 ± 1.64 | 17.46 ± 1.94 | 14.02 ± 1.04 | 14.50 ± 1.13

* Significantly different (p ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

The globulin concentration was significantly decreased in the 10 mg/kg/day male group; this decrease resulted in an increase in the albumin:globulin ratio in this group (Table 14). Cholesterol concentrations were significantly decreased in the 1.25 mg/kg/day and higher males, whereas triglycerides were decreased in the 2.5 mg/kg and higher males.

Free T4, total T4, and total T3 concentrations were significantly decreased in all dose groups of male rats (Table 14). In female rats, significant decreases were seen in total T4 at 6.25 mg/kg/day and greater and free T4 at 12.5 mg/kg/day and greater.

Male rats administered PFHxSK exhibited significant increases in expression of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2 compared to controls, indicating significantly increased PPARα and CAR activity (Table 15). Acox1 expression was the least sensitive of the genes evaluated. Female rats displayed increases in Cyp2b1 and Cyp2b2 expression compared to the control only without any significant increase in expression of PPARα-related genes (Acox1 and Cyp4a1) compared to controls. Cyp2b1 expression displayed the greatest fold changes in both males and females compared to the respective controls. Acyl-CoA oxidase activity was increased in the male liver in the 5 and 10 mg/kg/day groups compared to the controls.

Table 15 Hepatic Parameters for Rats in the 28-day Gavage Study of Perfluorohexane Sulfonate Potassium Salt^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Enzyme Activity
Acyl-CoA Oxidase (nmol/min/mg) | 2.014 ± 0.039 | 2.1612 ± 0.062 | 1.906 ± 0.029 | 2.077 ± 0.062 | 2.783 ± 0.247** | 4.579 ± 0.173**
Gene Expression
Acox1 | 1.03 ± 0.10 | 0.86 ± 0.08 | 1.00 ± 0.07 | 1.35 ± 0.11 | 1.90 ± 0.23** | 2.88 ± 0.20**
Cyp4a1 | 1.08 ± 0.14 | 1.32 ± 0.12 | 2.29 ± 0.26** | 5.62 ± 0.64** | 9.68 ± 1.32** | 17.10 ± 1.53**
Cyp2b1 | 1.10 ± 0.15 | 1.58 ± 0.31 | 3.97 ± 1.08** | 8.39 ± 2.15** | 22.08 ± 5.95** | 29.61 ± 8.67**
Cyp2b2 | 1.28 ± 0.34 | 1.75 ± 0.22* | 4.22 ± 0.51** | 5.77 ± 0.69** | 9.12 ± 1.29** | 13.35 ± 1.00**
| Vehicle Control | 3.12 mg/kg/day | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day
Female
n | 9 | 10 | 10 | 10 | 10 | 10
Gene Expression
Acox1 | 0.77 ± 0.06 | 0.74 ± 0.05 | 0.85 ± 0.05 | 0.58 ± 0.04 | 0.69 ± 0.04 | 0.77 ± 0.04
Cyp4a1 | 0.74 ± 0.06 | 0.80 ± 0.04 | 0.96 ± 0.06 | 0.68 ± 0.05 | 0.79 ± 0.05 | 0.77 ± 0.05
Cyp2b1 | 1.14 ± 0.42 | 4.40 ± 1.22* | 9.93 ± 1.67** | 8.08 ± 1.54** | 24.54 ± 4.40** | 43.46 ± 6.67**
Cyp2b2 | 1.02 ± 0.41 | 4.26 ± 1.35* | 8.12 ± 1.47** | 6.78 ± 1.34** | 17.95 ± 3.11** | 25.99 ± 2.91**

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Gene expression data are presented as fold change values from the base-signal values.

Assessed male rats did not display any changes in sperm counts or motility (Table A-3). Left testis and epididymis weights in rats administered PFHxSK were similar to the vehicle control group. No treatment-related testicular or epididymal lesions were noted and the serum testosterone levels assessed at necropsy were similar to the vehicle control group (Table A-3).

Inspection of the daily vaginal cytology data indicated that the females administered PFHxSK were cycling normally (Table A-4 and Table A-5; Figure A-2).

#### Pathology

The morphologic features of the lesions discussed in this section are presented in the Histopathologic Descriptions section following the Wyeth-14,643 results.

Liver: Compared to the incidence in vehicle controls, the incidences of hepatocyte hypertrophy were significantly increased in 2.5, 5, and 10 mg/kg/day males (Table 16). The severity of hepatocyte hypertrophy was generally mild to marked.

Table 16 Incidences of Selected Nonneoplastic Lesions in Rats in the 28-day Gavage Study of Perfluorohexane Sulfonate Potassium Salt

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
Male
Liver^a^ | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Hypertrophy^b^ | 0 | 0 | 0 | 4* (2.0)^c^ | 9** (2.0) | 10** (3.2)
| Vehicle Control | 3.12 mg/kg/day | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day
Female
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Degeneration | 0 | 0 | 0 | 0 | 0 | 8** (1.1)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 5* (1.0)
Olfactory Epithelium, Inflammation, Suppurative | 0 | 0 | 0 | 0 | 0 | 3 (1.0)

* Significantly different (p ≤ 0.05) from the vehicle control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Nose: The incidences of olfactory epithelium degeneration and olfactory epithelium hyperplasia in the 50 mg/kg/day females were significantly increased compared to the vehicle control incidences (Table 16). There was also an increase in the incidence of olfactory epithelium inflammation suppurative in this group. These changes were primarily minimal to mild in severity.

### Perfluorooctane Sulfonic Acid (PFOS)

All rats survived to scheduled euthanasia except for one female in the 5 mg/kg/day group (Table 17). There were no significant treatment-related clinical observations in male or female rats.

Table 17 Mean Body Weights and Survival of Rats in the 28-day Gavage Study of Perfluorooctane Sulfonic Acid

Day | Vehicle Control | | 0.312 mg/kg/day | | | 0.625 mg/kg/day | | | 1.25 mg/kg/day | | | 2.5 mg/kg/day | | | 5 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 267 | 10 | 267 | 100 | 10 | 266 | 100 | 10 | 267 | 100 | 10 | 266 | 100 | 10 | 266 | 100 | 10
8 | 288 | 10 | 289 | 100 | 10 | 289 | 100 | 10 | 285 | 99 | 10 | 286 | 99 | 10 | 283 | 98 | 10
15 | 309 | 10 | 310 | 100 | 10 | 308 | 100 | 10 | 303 | 98 | 10 | 308 | 100 | 10 | 296 | 96 | 10
22 | 326 | 10 | 325 | 100 | 10 | 323 | 99 | 10 | 319 | 98 | 10 | 321 | 99 | 10 | 307 | 94 | 10
29 | 337 | 10 | 340 | 101 | 10 | 338 | 100 | 10 | 331 | 98 | 10 | 333 | 99 | 10 | 309 | 92 | 10
Female
1 | 196 | 10 | 192 | 98 | 10 | 191 | 98 | 10 | 194 | 99 | 10 | 193 | 99 | 10 | 195 | 99 | 10
8 | 199 | 10 | 204 | 102 | 10 | 200 | 101 | 10 | 203 | 102 | 10 | 202 | 101 | 10 | 192 | 96 | 10
15 | 211 | 10 | 216 | 103 | 10 | 211 | 100 | 10 | 210 | 100 | 10 | 208 | 99 | 10 | 199 | 94 | 10
22 | 213 | 10 | 222 | 105 | 10 | 217 | 102 | 10 | 215 | 101 | 10 | 214 | 100 | 10 | 194 | 91 | 10
29 | 219 | 10 | 228 | 104 | 10 | 222 | 101 | 10 | 219 | 100 | 10 | 215 | 98 | 10 | 205 | 93 | 9

The mean body weights of all dose male and female groups were within 10% of those of the respective vehicle control groups throughout the study (Table 17 and Figure 3).

Figure 3

Growth Curves for Rats Administered Perfluorooctane Sulfonic Acid by Gavage for 28 Days

Parent compound concentrations are reported in ng/mL and μM for comparison to other PFAS tested (Table 18). Plasma concentrations of PFOS increased with increasing dose in males and females. Plasma concentrations in females were generally similar to males. Dose-normalized plasma concentrations (μM/mmol/kg) in males and females were generally similar (within 1.3-fold) across the dose groups, with the lowest concentration in the highest dose group in both sexes. There were quantifiable levels of PFOS in female controls that were 562 times lower than the lowest dose administered. The source of this exposure is not clear and may be a result of contamination from background exposure.

Table 18 Perfluorooctane Sulfonic Acid Concentrations in the Plasma and Liver of Rats in the 28-day Gavage Study of Perfluorooctane Sulfonic Acid^a^

| Vehicle Control | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day
Molar Dose (mmol/kg/day) | 0 | 0.00062 | 0.0013 | 0.0025 | 0.005 | 0.01
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Plasma
Plasma Concentration (ng/mL) | BD | 23,730 ± 1,114 | 51,560 ± 3,221 | 94,260 ± 3,144 | 173,700 ± 9,036 | 318,200 ± 8,868
Plasma Concentration (μM) | BD | 47.4 ± 2.2 | 103.1 ± 6.4 | 188.5 ± 6.3 | 347.3 ± 18.1 | 636.2 ± 17.7
Normalized Plasma Concentration (μM/mmol/kg) | NA | 76,057.7 ± 3,569.4 | 82,496.0 ± 5,154.4 | 75,408.0 ± 2,515.1 | 69,480.0 ± 3,614.3 | 63,640.0 ± 1,773.6
Liver
Liver Concentration (ng/g) | BD | 87,170 ± 3,039 | 160,100 ± 7,209 | 286,100 ± 7,882 | 468,200 ± 12,136 | 867,100 ± 26,802
Liver Concentration (μM)^b^ | BD | 174.3 ± 6.1 | 320.1 ± 14.4 | 572.1 ± 15.8 | 936.2 ± 24.3 | 1,733.7 ± 53.6
Normalized Liver Concentration (μM/mmol/kg) | NA | 279,391.0 ± 9,739.2 | 256,160.0 ± 11,533.9 | 228,880.0 ± 6,305.4 | 187,280.0 ± 4,854.4 | 173,420.0 ± 5,360.4
Liver/Plasma Ratio | BD | 3.76 ± 0.24 | 3.29 ± 0.35 | 3.06 ± 0.11 | 2.75 ± 0.13 | 2.74 ± 0.08
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Plasma
Plasma Concentration (ng/mL) | 54 ± 4 | 30,530 ± 918** | 66,970 ± 1,629** | 135,100 ± 3,877** | 237,500 ± 5,218** | 413,556 ± 8,071**
Plasma Concentration (μM) | 0.1 ± 0.0 | 61.0 ± 1.8** | 133.9 ± 3.3** | 270.1 ± 7.8** | 474.9 ± 10.4** | 826.9 ± 16.1**
Normalized Plasma Concentration (μM/mmol/kg) | NA | 97,852.6 ± 2,941.1 | 107,152.0 ± 2,607.1 | 108,080.0 ± 3,101.7 | 95,000.0 ± 2,087.2 | 82,711.1 ± 1,614.2

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s test.

BD = below detection; group did not have over 20% of its values above the limit of quantification and no statistical analyses were conducted for the endpoint. NA = not applicable; normalized value could not be calculated when the dose value was 0.

^a^ Tissue concentration data are presented as mean ± standard error. If over 20% of the values in a group were above the limit of quantification (plasma LOQ = 25 ng/mL; liver LOQ = 500 ng/g), then values that were below the limit of quantification were substituted with half the limit of quantification value.

^b^ Density assumed to be 1.0.

Liver concentrations were measured only in males and data are presented in ng/g and μM for comparison to other PFAS tested (conversion assumed 1 g/mL for weight to volume) (Table 18). Concentrations in males increased with increasing dose, but when normalized with dose, there was a steady decrease as dose increased. This corresponded with a decreasing liver/plasma ratio as dose increased.

In all treated male and female groups, compared to the vehicle controls, there were dose-related and significant increases in the absolute and relative liver weights (Table 19). Organ weight changes in the liver appear to correlate with histopathologic changes in the liver.

Table 19 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day Gavage Study of Perfluorooctane Sulfonic Acid^a^

| Vehicle Control | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy Body Wt. | 337 ± 7 | 340 ± 5 | 338 ± 7 | 331 ± 4 | 333 ± 4 | 309 ± 4**
R. Adrenal Gland
Absolute | 0.0211 ± 0.0008 | 0.0180 ± 0.0010 | 0.0210 ± 0.0006 | 0.0177 ± 0.0008* | 0.0190 ± 0.0012* | 0.0173 ± 0.0005**
Relative | 0.06 ± 0.00 | 0.05 ± 0.00 | 0.06 ± 0.00 | 0.05 ± 0.00 | 0.06 ± 0.00 | 0.06 ± 0.00
Heart
Absolute | 1.19 ± 0.03 | 1.20 ± 0.02 | 1.18 ± 0.03 | 1.17 ± 0.02 | 1.19 ± 0.01 | 1.08 ± 0.03*
Relative | 3.53 ± 0.04 | 3.54 ± 0.05 | 3.50 ± 0.08 | 3.55 ± 0.06 | 3.57 ± 0.03 | 3.50 ± 0.07
Liver
Absolute | 11.79 ± 0.29 | 13.14 ± 0.28** | 14.21 ± 0.32** | 15.34 ± 0.37** | 17.37 ± 0.36** | 18.81 ± 0.41**
Relative | 34.92 ± 0.22 | 38.66 ± 0.47** | 42.04 ± 0.48** | 46.38 ± 0.99** | 52.21 ± 0.93** | 60.80 ± 0.77**
Spleen
Absolute | 0.688 ± 0.014 | 0.708 ± 0.019 | 0.686 ± 0.021 | 0.617 ± 0.025* | 0.611 ± 0.033* | 0.593 ± 0.019**
Relative | 2.04 ± 0.05 | 2.09 ± 0.05 | 2.04 ± 0.09 | 1.87 ± 0.08 | 1.84 ± 0.10 | 1.92 ± 0.06
Thymus
Absolute | 0.431 ± 0.023 | 0.465 ± 0.013 | 0.412 ± 0.023 | 0.401 ± 0.022 | 0.385 ± 0.011 | 0.322 ± 0.018**
Relative | 1.28 ± 0.08 | 1.37 ± 0.04 | 1.21 ± 0.05 | 1.21 ± 0.05 | 1.16 ± 0.03 | 1.04 ± 0.04**
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Necropsy Body Wt. | 219 ± 3 | 228 ± 4 | 222 ± 2 | 219 ± 4 | 215± 4 | 205 ± 4**
Heart
Absolute | 0.84 ± 0.01 | 0.87 ± 0.02 | 0.86 ± 0.02 | 0.87 ± 0.02 | 0.82 ± 0.02 | 0.72 ± 0.01**
Relative | 3.84 ± 0.08 | 3.79 ± 0.06 | 3.89 ± 0.06 | 3.96 ± 0.07 | 3.80 ± 0.05 | 3.51 ± 0.06**
Liver
Absolute | 7.37 ± 0.18 | 8.26 ± 0.22* | 8.20 ± 0.17* | 8.59 ± 0.26** | 9.17 ± 0.28** | 10.92 ± 0.29**
Relative | 33.56 ± 0.66 | 36.15 ± 0.54* | 36.95 ± 0.73* | 39.25 ± 1.06** | 42.67 ± 0.87** | 53.37 ± 1.48**
Lung
Absolute | 1.58 ± 0.07 | 1.78 ± 0.12 | 1.85 ± 0.05 | 2.03 ± 0.12* | 1.87 ± 0.13 | 1.84 ± 0.12
Relative | 7.23 ± 0.34 | 7.78 ± 0.43 | 8.35 ± 0.27 | 9.30 ± 0.55* | 8.69 ± 0.54** | 8.99 ± 0.58*
Thymus
Absolute | 0.312 ± 0.021 | 0.276 ± 0.007 | 0.297 ± 0.010 | 0.258 ± 0.014* | 0.295 ± 0.013 | 0.251 ± 0.015*
Relative | 1.42 ± 0.09 | 1.21 ± 0.03 | 1.34 ± 0.04 | 1.18 ± 0.06* | 1.37 ± 0.05 | 1.23 ± 0.07

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

In males, body weights were lower in the high-dose group. Absolute right adrenal gland and spleen weights in the 1.25, 2.5, and 5 mg/kg/day groups, and absolute and relative thymus weights in the 5 mg/kg/day group were significantly decreased. Absolute heart weight was decreased in the 5 mg/kg/day group (Table 19). In females, body weights were lower in the high-dose group. Absolute and relative heart weights in the 5 mg/kg/day group, absolute and relative thymus weights in the 1.25 mg/kg/day group, and absolute thymus weight in the 5 mg/kg/day group were significantly decreased. Relative lung weights in 1.25, 2.5, and 5 mg/kg/day females and absolute lung weight in 1.25 mg/kg/day females were significantly increased. Biological significance of these changes is not clear.

In male rats, the total leukocyte count and the neutrophil count were significantly decreased at 5 mg/kg/day (Table 20). The reticulocyte count was decreased in 2.5 and 5.0 mg/kg/day males and females.

Table 20 Selected Hematology and Clinical Chemistry Data for Rats in the 28-day Gavage Study of Perfluorooctane Sulfonic Acid^a^

| Vehicle Control | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Hematology
Reticulocytes (10^3^/μL) | 181.1 ± 6.1 | 169.4 ± 11.6^b^ | 156.9 ± 8.0 | 154.2 ± 9.0^c^ | 140.0 ± 10.3** | 104.4 ± 7.2**
Leukocytes (10^3^/μL) | 12.84 ± 0.61 | 14.18 ± 0.64 | 11.42 ± 0.64 | 11.15 ± 0.71 | 12.24 ± 0.63 | 10.72 ± 0.64*
Segmented Neutrophils (10^3^/μL) | 1.31 ± 0.11 | 1.28 ± 0.09^b^ | 1.17 ± 0.06 | 1.22 ± 0.13^c^ | 1.17 ± 0.05 | 0.97 ± 0.06*
Clinical Chemistry
Urea Nitrogen (mg/dL) | 17.7 ± 0.4 | 18.1 ± 1.0 | 16.8 ± 0.5 | 19.1 ± 0.8 | 18.0 ± 0.5 | 21.1 ± 0.7**
Total Protein (g/dL) | 6.5 ± 0.1 | 6.4 ± 0.1 | 6.5 ± 0.1 | 6.7 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1
Albumin (g/dL) | 4.3 ± 0.1 | 4.2 ± 0.0 | 4.2 ± 0.1 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.7 ± 0.0**
Globulin (g/dL) | 2.2 ± 0.1 | 2.3 ± 0.1 | 2.3 ± 0.1 | 2.3 ± 0.1 | 2.1 ± 0.0 | 1.9 ± 0.1**
Albumin/Globulin Ratio | 1.9 ± 0.1 | 1.9 ± 0.1 | 1.9 ± 0.1 | 1.9 ± 0.1 | 2.1 ± 0.0* | 2.5 ± 0.1**
Direct Bilirubin (mg/dL) | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.04 ± 0.00**
Cholesterol (mg/dL) | 115 ± 2 | 97 ± 3** | 84 ± 2** | 83 ± 4** | 54 ± 3** | 24 ± 3**
Triglycerides (mg/dL) | 104 ± 6 | 156 ± 18 | 108 ± 10 | 118 ± 12 | 82 ± 10 | 24 ± 5**
Alanine Aminotransferase (IU/L) | 48 ± 1 | 52 ± 2 | 66 ± 5** | 56 ± 3** | 75 ± 8** | 71 ± 4**
Alkaline Phosphatase (IU/L) | 187 ± 7 | 192 ± 5 | 217 ± 9* | 218 ± 6** | 215 ± 10* | 252 ± 10**
Aspartate Aminotransferase (IU/L) | 56 ± 2 | 60 ± 2 | 68 ± 4** | 63 ± 2 | 68 ± 5* | 61 ± 2
Total Bile Acids (μmol/L) | 10.1 ± 3.8 | 12.3 ± 2.3 | 6.6 ± 1.2 | 10.8 ± 1.8 | 16.2 ± 1.7 | 34.7 ± 2.0**
Testosterone (ng/mL) | 3.78 ± 0.75 | 5.81 ± 1.60 | 5.07 ± 1.72^b^ | 4.43 ± 1.72 | 5.58 ± 1.17 | 1.87 ± 1.37
Total Thyroxine (μg/dL) | 3.51 ± 0.30 | 1.33 ± 0.19** | 0.53 ± 0.09** | 0.26 ± 0.07** | 0.22 ± 0.04** | 0.48 ± 0.07**
Free Thyroxine (ng/dL) | 2.53 ± 0.22 | 0.95 ± 0.10** | 0.47 ± 0.05** | 0.40 ± 0.02** | 0.36 ± 0.05** | 0.33 ± 0.01**
Total Triiodothyronine (ng/dL) | 87.37 ± 5.32 | 77.81 ± 5.44 | 60.63 ± 4.64** | 57.50 ± 2.67** | 55.35 ± 2.75** | 50.00 ± 0.00**
Thyroid Stimulating Hormone (ng/mL) | 20.39 ± 1.40 | 14.94 ± 1.74 | 14.79 ± 1.20^b^ | 23.33 ± 2.94 | 24.19 ± 3.38 | 18.90 ± 2.39
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Hematology
Reticulocytes (10^3^/μL) | 218.3 ± 25.2 | 208.5 ± 14.0 | 214.3 ± 15.9 | 164.7 ± 8.7 | 132.8 ± 11.2** | 112.0 ± 10.3**
Clinical Chemistry
Total Protein (g/dL) | 6.4 ± 0.1 | 6.3 ± 0.1 | 6.6 ± 0.1 | 6.7 ± 0.1 | 6.7 ± 0.1 | 6.9 ± 0.1**
Albumin (g/dL) | 4.5 ± 0.1 | 4.4 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.1* | 4.8 ± 0.1** | 5.0 ± 0.1**
Globulin (g/dL) | 1.9 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.1 | 2.0 ± 0.1 | 1.9 ± 0.1 | 1.9 ± 0.1
Albumin/Globulin Ratio | 2.4 ± 0.1 | 2.4 ± 0.0 | 2.5 ± 0.1 | 2.4 ± 0.1 | 2.6 ± 0.1* | 2.6 ± 0.1*
Total Bilirubin (mg/dL) | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0*
Direct Bilirubin (mg/dL) | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.03 ± 0.00* | 0.05 ± 0.00**
Cholesterol (mg/dL) | 105 ± 5 | 113 ± 3 | 100 ± 4 | 109 ± 6 | 93 ± 3 | 69 ± 5**
Triglycerides (mg/dL) | 73 ± 9 | 75 ± 7 | 66 ± 3 | 64 ± 6 | 49 ± 3* | 52 ± 7*
Alanine Aminotransferase (IU/L) | 45 ± 2 | 44 ± 2 | 47 ± 1 | 48 ± 3 | 55 ± 2** | 73 ± 3**
Alkaline Phosphatase (IU/L) | 147 ± 5 | 142 ± 6 | 150 ± 6 | 170 ± 8 | 168 ± 8* | 198 ± 10**
Total Bile Acids (μmol/L) | 16.6 ± 2.8 | 12.5 ± 2.4 | 13.3 ± 1.9 | 21.0 ± 3.3 | 36.3 ± 4.3** | 61.7 ± 7.4**
Total Thyroxine (μg/dL) | 2.21 ± 0.24 | 1.11 ± 0.12** | 0.55 ± 0.07** | 0.33 ± 0.07** | 0.35 ± 0.09** | 0.38 ± 0.05**
Free Thyroxine (ng/dL) | 1.74 ± 0.23 | 1.07 ± 0.09** | 0.70 ± 0.03** | 0.64 ± 0.05** | 0.56 ± 0.05** | 0.48 ± 0.03**
Total Triiodothyronine (ng/dL) | 93.05 ± 5.04 | 81.40 ± 3.02 | 72.52 ± 4.27** | 69.20 ± 3.63** | 62.03 ± 1.78** | 51.57 ± 1.43**
Thyroid Stimulating Hormone (ng/mL) | 12.86 ± 0.73 | 14.76 ± 0.88 | 12.76 ± 0.85 | 13.25 ± 1.15 | 14.914 ± 1.95^b^ | 15.36 ± 0.73

* Significantly different (p ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 8.

A mild significant elevation in BUN concentration was observed in the 5 mg/kg/day males (Table 20). Mild increases in BUN without increases in creatinine are most consistent with decreased water intake (i.e., dehydration). The globulin concentration was significantly decreased and albumin concentration significantly increased in the 5 mg/kg/day males, which resulted in an increase in the albumin:globulin ratio. In females, the albumin concentrations and albumin:globulin ratios were significantly elevated in the 2.5 and 5 mg/kg/day groups; total protein was also elevated in the 5 mg/kg/day group. In male rats, cholesterol concentrations were significantly decreased in all dose groups and triglycerides decreased in the 5 mg/kg/day group. In females, the cholesterol and triglyceride concentrations decreased at 5 mg/kg/day and at 2.5 and 5 mg/kg/day, respectively.

ALP and ALT activities were significantly elevated at 0.625 mg/kg/day and greater in male rats; AST activities were also elevated in several male dose groups (Table 20). In females, ALP and ALT activities were increased in the 2.5 and 5 mg/kg/day groups. Total bile acid concentrations were significantly elevated in 5 mg/kg/day males and in 2.5 and 5 mg/kg/day females; direct bilirubin concentrations were elevated in the 5 mg/kg/day males and the 2.5 and 5 mg/kg/day females, and total bilirubin was elevated in the 5 mg/kg/day females.

Total T4 and free T4 concentrations were significantly decreased in all dose groups of male and female rats (Table 20). Total T3 concentrations were significantly decreased in the 0.625 mg/kg/day and higher male and female groups.

Male and female rats administered PFOS exhibited significant increases in expression of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2 compared to their respective controls, indicating significantly increased PPARα and CAR activity (Table 21). Males displayed a greater fold increase in Cyp4a1 activity compared to controls than females compared to their controls, whereas CAR increases were more prominent in female rats compared to males. Expression of Acox1 was the least sensitive of the genes evaluated in males, whereas Cyp2b1 displayed the greatest fold changes compared to controls in both males and females.

Table 21 Hepatic Parameters for Rats in the 28-day Gavage Study of Perfluorooctane Sulfonic Acid^a^

| Vehicle Control | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Enzyme Activity
Acyl-CoA Oxidase (nmol/min/mg) | 1.987 ± 0.049 | 1.959 ± 0.076 | 1.736 ± 0.026 | 2.029 ± 0.049 | 2.793 ± 0.090** | 6.053 ± 0.226**
Gene Expression
Acox1 | 1.02 ± 0.06 | 1.02 ± 0.08 | 1.13 ± 0.06 | 1.82 ± 0.15** | 2.92 ± 0.26** | 5.36 ± 0.58**
Cyp4a1 | 1.04 ± 0.10 | 2.09 ± 0.18** | 3.38 ± 0.25** | 6.43 ± 0.51** | 14.45 ± 1.56** | 30.69 ± 3.62**
Cyp2b1 | 1.17 ± 0.21 | 5.87 ± 1.05** | 11.61 ± 2.61** | 88.63 ± 32.83** | 135.34 ± 29.33** | 408.63 ± 89.38**
Cyp2b2 | 1.22 ± 0.23 | 6.60 ± 1.01** | 10.24 ± 0.91** | 20.73 ± 2.022** | 32.41 ± 3.23** | 49.58 ± 4.69**
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Gene Expression
Acox1 | 1.02 ± 0.06 | 1.32 ± 0.05** | 1.72 ± 0.15 | 1.41 ± 0.12** | 2.05 ± 0.14** | 3.10 ± 0.15**
Cyp4a1 | 1.03 ± 0.08 | 1.75 ± 0.12** | 2.08 ± 0.20** | 1.63 ± 0.16** | 1.93 ± 0.18** | 2.46 ± 0.24**
Cyp2b1 | 1.53 ± 0.44 | 32.47 ± 4.28** | 99.63 ± 17.06** | 260.11 ± 61.66** | 671.64 ± 200.4** | 1,226.9 ± 422.5**
Cyp2b2 | 1.56 ± 0.47 | 34.78 ± 6.76** | 92.07 ± 13.79** | 116.41 ± 11.01** | 175.77 ± 17.26** | 288.29 ± 21.56**

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Gene expression data are presented as fold change values from the base-signal values.

Assessed male rats did not display any changes in sperm counts, motility, or testicular/epididymal weights (Table A-6). No treatment-related testicular or epididymal lesions were noted. Male serum testosterone levels assessed at necropsy in all treated groups were similar to the vehicle control level (Table 20).

The daily vaginal cytology data indicated that the female rats displayed similar amounts of time in each respective estrous stage (Table 22 and Table A-7; Figure A-3). Although summary statistics based on these data suggested that the proportion of time female rats spent in each stage of the cycle was similar across assessed groups, Markov analyses demonstrated that females in all assessed groups had a higher probability than the vehicle control group of transitioning to extended diestrus (Table 22 and Table A-7).

Table 22 Estrous Cycle Characterization for Female Rats in the 28-day Gavage Study of Perfluorooctane Sulfonic Acid^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
n | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 219 ± 3 | 222 ± 2 | 219 ± 4 | 215 ± 4
Number of Estrous Cycles | 1.9 ± 0.18 | 2.3 ± 0.15 | 2.0 ± 0.00 | 1.9 ± 0.18
Estrous Cycle Length (days) | 4.8 ± 0.20 | 4.9 ± 0.15 | 5.1 ± 0.15 | 5.2 ± 0.14
Estrous Stages (% of cycle)
Diestrus | 50.6 | 56.3 | 51.9 | 56.3
Proestrus | 10.0 | 8.8 | 10.0 | 8.1
Estrus | 34.4 | 30.0 | 35.0 | 33.8
Metestrus | 3.8 | 5.0 | 3.1 | 1.9
Uncertain Diagnosis | 1.3 | 0.0 | 0.0 | 0.0
Markov Analysis
| Overall | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day
Overall Test | p < 0.001 | p < 0.001 | p = 0.004 | p = 0.001
Extended Diestrus | p < 0.001 | p = 0.001 | p = 0.028 | p < 0.001

^a^ Necropsy body weights, number of estrous cycles, and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle number and length). N indicates that the dose group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dose group had more departures from normal cycling than did the vehicle control group. Tests for equality of all transition matrices are shown in the vehicle control column (Markov analysis).

#### Pathology

The morphologic features of the lesions discussed in this section are presented in the Histopathologic Descriptions section following the Wyeth-14,643 results.

Liver: The incidences of hepatocyte hypertrophy were increased at 1.25, 2.5, and 5 mg/kg/day in males and females (Table 23). Hepatocyte hypertrophy was in general of minimal to mild severity. The incidences of hepatocyte, vacuolization cytoplasmic were increased in 2.5 and 5 mg/kg/day males, and in general, the lesion was of minimal severity. The incidences of hepatocyte cytoplasmic alteration were increased in 1.25, 2.5, and 5 mg/kg/day females, and the lesion was in general of minimal severity.

Table 23 Incidences of Selected Nonneoplastic Lesions in Rats in the 28-day Gavage Study of Perfluorooctane Sulfonic Acid

| Vehicle Control | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day
Male
Liver^a^ | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Hypertrophy^b^ | 0 | 0 | 0 | 3 (1.3)^c^ | 8** (1.3) | 10** (2.1)
Hepatocyte, Vacuolization Cytoplasmic | 0 | 0 | 0 | 0 | 2 (1.0) | 4* (1.0)
Bone Marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hypocellularity | 0 | 0 | 0 | 5* (1.0) | 4* (1.0) | 8** (1.0)
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Extramedullary Hematopoiesis, Decreased | 1 (1.0) | 1 (1.0) | 2 (1.0) | 7** (1.0) | 8** (1.0) | 10** (1.0)
Female
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration | 0 | 0 | 0 | 3 (1.0) | 5* (1.0) | 10** (1.0)
Hepatocyte, Hypertrophy | 0 | 0 | 0 | 2 (1.0) | 3 (1.0) | 10** (1.7)
Bone Marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hypocellularity | 0 | 2 (1.0) | 1 (1.0) | 1 (1.0) | 5* (1.0) | 9** (1.8)
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Extramedullary Hematopoiesis, Decreased | 2 (1.0) | 3 (1.0) | 3 (1.0) | 8* (1.0) | 10** (1.0) | 10** (1.0)

* Significantly different (p ≤ 0.05) from the vehicle control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Bone Marrow: The incidences of hypocellularity were significantly increased in the 1.25, 2.5, and 5 mg/kg/day males and 2.5 and 5 mg/kg/day females (Table 23). Hypocellularity was minimal to mild in severity.

Spleen: Extramedullary hematopoiesis is a normal occurrence in the spleen of rodents. There were significant increases in the incidences of decreased extramedullary hematopoiesis, in 1.25, 2.5, and 5 mg/kg/day males and females (Table 23). The severity of the lesion was minimal in all dose groups.

### Wyeth-14,643

Wyeth-14,643 (WY) was used as a PPARα agonist (positive control) reference agent. All rats survived to scheduled euthanasia (Table 24). There were no significant treatment-related clinical observations in male or female rats.

Table 24 Mean Body Weights and Survival of Male Rats in the 28-day Gavage Study of Wyeth-14,643

Day | Vehicle Control | | 6.25 mg/kg/day | | | 12.5 mg/kg/day | | | 25 mg/kg/day
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 271 | 10 | 273 | 101 | 10 | 272 | 100 | 10 | 272 | 100 | 10
8 | 291 | 10 | 297 | 102 | 10 | 292 | 101 | 10 | 293 | 101 | 10
15 | 310 | 10 | 310 | 100 | 10 | 303 | 98 | 10 | 300 | 97 | 10
22 | 321 | 10 | 320 | 100 | 10 | 313 | 97 | 10 | 309 | 96 | 10
29 | 336 | 10 | 324 | 96 | 10 | 316 | 94 | 10 | 308 | 92 | 10
Female
1 | 197 | 10 | 198 | 100 | 10 | 198 | 100 | 10 | 198 | 100 | 10
8 | 204 | 10 | 208 | 102 | 10 | 208 | 102 | 10 | 209 | 102 | 10
15 | 215 | 10 | 218 | 102 | 10 | 216 | 101 | 10 | 216 | 101 | 10
22 | 220 | 10 | 224 | 102 | 10 | 225 | 103 | 10 | 224 | 102 | 10
29 | 224 | 10 | 230 | 103 | 10 | 229 | 102 | 10 | 229 | 103 | 10

The mean body weights of dose groups of males and females were within 10% of the respective vehicle control groups throughout the study (Table 24 and Figure 4).

Figure 4

Growth Curves for Rats Administered Wyeth-14,643 by Gavage for 28 Days

In all treated male and female groups, compared to vehicle controls, there were dose-related and significant increases in the absolute and relative liver and right kidney weights (Table 25). Changes in the liver weights appear to correlate with histopathologic changes in the liver.

Table 25 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 10 | 10
Male
Necropsy Body Wt. | 337 ± 4 | 324 ± 5 | 316 ± 5** | 308 ± 5**
Heart
Absolute | 1.19 ± 0.02 | 1.17 ± 0.02 | 1.16 ± 0.02 | 1.10 ± 0.03*
Relative | 3.54 ± 0.05 | 3.60 ± 0.06 | 3.67 ± 0.06 | 3.56 ± 0.04
R. Kidney
Absolute | 1.00 ± 0.02 | 1.10 ± 0.04* | 1.13 ± 0.03** | 1.13 ± 0.02**
Relative | 2.98 ± 0.07 | 3.38 ± 0.08** | 3.59 ± 0.08** | 3.68 ± 0.05**
Liver
Absolute | 11.57 ± 0.21 | 15.35 ± 0.31** | 15.97 ± 0.49** | 16.56 ± 0.44**
Relative | 34.33 ± 0.49 | 47.35 ± 0.46** | 50.55 ± 1.22** | 53.90 ± 1.67**
Spleen
Absolute | 0.723 ± 0.022 | 0.635 ± 0.017* | 0.668 ± 0.022 | 0.631 ± 0.019**
Relative | 2.14 ± 0.05 | 1.96 ± 0.06 | 2.11 ± 0.06 | 2.05 ± 0.05
Female
Necropsy Body Wt. | 224 ± 4 | 230 ± 4 | 229 ± 3 | 229 ± 5
R. Kidney
Absolute | 0.67 ± 0.01 | 0.74 ± 0.02** | 0.75 ± 0.02** | 0.76 ± 0.01**
Relative | 3.02 ± 0.05 | 3.22 ± 0.08* | 3.30 ± 0.09** | 3.31 ± 0.04**
Liver
Absolute | 7.32 ± 0.19 | 10.25 ± 0.27** | 11.07 ± 0.27** | 11.98 ± 0.40**
Relative | 32.78 ± 0.71 | 44.52 ± 0.90** | 48.45 ± 1.05** | 52.21 ± 1.14**

* Significantly different (p ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Absolute heart weight in 25 mg/kg/day males and absolute spleen weights in 6.25 and 25 mg/kg/day males were significantly decreased; biological significance of these changes is not clear.

There were several statistically significant changes, when compared to the respective vehicle control groups, in the hematology parameters of male and female rats. These changes, however, were mild and inconsistent and not considered toxicologically relevant.

BUN concentrations were significantly increased in all male dose groups (Table 26). Cholesterol concentrations were significantly decreased in all male dose groups. In all male dose groups, the total protein and globulin concentrations were significantly decreased, and the albumin concentrations were significantly increased; the combination of these changes resulted in significantly increased albumin:globulin ratios in male dose groups. In the female rats, globulin concentrations were significantly decreased in all dose groups, and total protein and albumin concentrations significantly increased in most dose groups; the combination of these changes resulted in significantly increased albumin:globulin ratios in all dose groups. ALT, ALP, and SDH activities were significantly increased in all male dose groups; AST was significantly increased in 25 mg/kg/day males. In addition, direct bilirubin concentrations were significantly increased in 25 mg/kg/day males and total bile acid concentrations were significantly increased in all male dose groups. In female rats, ALP and SDH activities were significantly increased in all dose groups and ALT and AST activities were significantly increased in the 25 mg/kg/day group.

Table 26 Selected Clinical Chemistry Data for Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 10 | 10
Male
Urea Nitrogen (mg/dL) | 18.6 ± 0.7 | 20.2 ± 0.5* | 21.3 ± 0.5** | 23.1 ± 0.6**
Total Protein (g/dL) | 6.59 ± 0.05 | 6.24 ± 0.13* | 6.37 ± 0.05* | 6.25 ± 0.07**
Albumin (g/dL) | 4.30 ± 0.03 | 4.74 ± 0.06** | 4.78 ± 0.04** | 4.86 ± 0.09**
Globulin (g/dL) | 2.29 ± 0.03 | 1.50 ± 0.07** | 1.59 ± 0.04** | 1.39 ± 0.04**
Albumin/Globulin Ratio | 1.88 ± 0.02 | 3.22 ± 0.13** | 3.02 ± 0.08** | 3.53 ± 0.14**
Cholesterol (mg/dL) | 125.0 ± 2.7 | 106.6 ± 5.0** | 116.2 ± 4.0* | 101.8 ± 3.5**
Alanine Aminotransferase (IU/L) | 52.20 ± 1.32 | 62.80 ± 4.29* | 59.50 ± 2.36* | 62.70 ± 2.10**
Alkaline Phosphatase (IU/L) | 202.8 ± 7.5 | 286.2 ± 12.2** | 325.1 ± 14.7** | 386.5 ± 31.2**
Aspartate Aminotransferase (IU/L) | 60.00 ± 1.26 | 64.70 ± 3.45 | 62.50 ± 1.90 | 70.00 ± 3.35*
Sorbitol Dehydrogenase (IU/L) | 5.7 ± 0.4 | 9.9 ± 1.4** | 7.9 ± 0.5** | 8.4 ± 0.4**
Direct Bilirubin (mg/dL) | 0.024 ± 0.003 | 0.021 ± 0.002 | 0.025 ± 0.002 | 0.030 ± 0.002*
Total Bile Acids (μmol/L) | 11.8 ± 1.6 | 40.9 ± 6.5** | 73.1 ± 11.2** | 83.2 ± 9.5**
Total Triiodothyronine (ng/dL) | 106.35 ± 5.53 | 113.62 ± 4.21 | 102.40 ± 3.39 | 103.95 ± 4.98
Total Thyroxine (μg/dL) | 3.58 ± 0.13 | 2.90 ± 0.15** | 2.94 ± 0.20* | 2.78 ± 0.17**
Free Thyroxine (ng/dL) | 2.35 ± 0.09 | 1.43 ± 0.13** | 1.41 ± 0.14** | 1.31 ± 0.13**
Thyroid Stimulating Hormone (ng/mL) | 18.56 ± 1.16 | 21.46 ± 3.59 | 15.64 ± 2.13 | 13.07 ± 1.01*
Testosterone | 4.03 ± 0.48 | 3.14 ± 0.91 | 4.37 ± 1.29 | 1.56 ± 0.39*
Female
Total Protein (g/dL) | 6.37 ± 0.08 | 6.54 ± 0.05 | 6.85 ± 0.12** | 6.85 ± 0.08**
Albumin (g/dL) | 4.46 ± 0.05 | 5.03 ± 0.05** | 5.20 ± 0.08** | 5.20 ± 0.05**
Globulin (g/dL) | 1.91 ± 0.05 | 1.51 ± 0.04** | 1.65 ± 0.05* | 1.65 ± 0.05*
Albumin/Globulin Ratio | 2.34 ± 0.05 | 3.35 ± 0.10** | 3.17 ± 0.08** | 3.17 ± 0.09**
Alanine Aminotransferase (IU/L) | 41.80 ± 1.24 | 49.50 ± 3.85 | 46.80 ± 1.85 | 54.80 ± 2.58**
Alkaline Phosphatase (IU/L) | 142.6 ± 6.9 | 181.7 ± 10.2** | 179.2 ± 5.4** | 217.3 ± 11.4**
Aspartate Aminotransferase (IU/L) | 55.30 ± 1.08 | 64.70 ± 8.15 | 56.50 ± 1.70 | 61.90 ± 1.55*
Sorbitol Dehydrogenase (IU/L) | 4.2 ± 0.5 | 9.9 ± 2.4** | 7.7 ± 0.7** | 8.3 ± 0.6**
Total Triiodothyronine (ng/dL) | 65.66 ± 2.47 | 71.86 ± 4.31 | 83.09 ± 4.79** | 83.57 ± 3.72**
Total Thyroxine (μg/dL) | 1.79 ± 0.13 | 1.99 ± 0.16 | 2.28 ± 0.15 | 1.70 ± 0.12
Free Thyroxine (ng/dL) | 1.13 ± 0.08 | 1.44 ± 0.10 | 1.67 ± 0.14** | 1.34 ± 0.09
Thyroid Stimulating Hormone (ng/mL) | 10.07 ± 0.51^b^ | 16.19 ± 2.03** | 14.96 ± 1.71** | 17.21 ± 1.25**
Testosterone | 0.33 ± 0.03 | 0.52 ± 0.07* | 0.49 ± 0.06 | 0.57 ± 0.08*

* Significantly different (p ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

Free T4 and total T4 concentrations were significantly decreased in all male dose groups, and TSH was significantly decreased in the 25 mg/kg/day male group (Table 26). Additionally, testosterone concentration was significantly decreased in 25 mg/kg/day males. In females, T3 and TSH concentrations were significantly increased in most dose groups, and testosterone concentrations were significantly increased at 6.25 and 25 mg/kg/day. Free T4 was significantly increased in the 12.5 mg/kg/day females; the relevance of this change was not certain and may have been due to biological variability.

There were significant increases in expression of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2 compared to controls, indicating significantly increased PPARα and CAR activities in treated male and female rats (Table 27). Males displayed a greater fold increase in Cyp4a1 activity compared to controls than females compared to their controls, whereas CAR increases compared to controls were more prominent in female rats than males.

Table 27 Hepatic Parameters for Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 10 | 10
Male
Enzyme Activity
Acyl-CoA Oxidase (nmol/min/mg) | 2.028 ± 0.044 | 11.731 ± 0.692** | 14.560 ± 1.027** | 17.370 ± 0.592**
Gene Expression
Acox1 | 1.05 ± 0.10 | 3.54 ± 0.60** | 4.77 ± 0.55** | 6.86 ± 0.44**
Cyp4a1 | 1.06 ± 0.10 | 29.92 ± 4.63** | 33.96 ± 2.45** | 45.82 ± 3.31**
Cyp2b1 | 1.21 ± 0.21 | 3.77 ± 0.94** | 3.69 ± 0.67** | 4.45 ± 0.95**
Cyp2b2 | 1.27 ± 0.28 | 2.32 ± 0.23** | 1.93 ± 0.20* | 2.43 ± 0.19**
Female
Gene Expression
Acox1 | 1.01 ± 0.05 | 3.11 ± 0.26** | 4.08 ± 0.27** | 5.65 ± 0.49**
Cyp4a1 | 1.02 ± 0.07 | 2.90 ± 0.52** | 3.85 ± 1.12** | 7.26 ± 1.22**
Cyp2b1 | 1.18 ± 0.24 | 24.05 ± 4.59** | 28.82 ± 3.36** | 38.79 ± 4.74**
Cyp2b2 | 1.18 ± 0.21 | 19.59 ± 2.67** | 29.41 ± 1.48** | 30.41 ± 3.22**

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Gene expression data are presented as fold change values from the base-signal values.

Male rats administered 6.25, 12.5, or 25 mg/kg/day for 28 days displayed lower testicular spermatid counts (9%, 14%, 13%, respectively) relative to vehicle controls (Table 28). When normalized to total testicular weight, counts were slightly lower in the dose groups, with the 12.5 and 25 mg/kg/day groups exhibiting lower (11% and 10%) counts relative to vehicle control. These differences did not attain statistical significance, but the trend was significant. Wyeth-14,643 administration did not affect motility or testis weight. Cauda epididymal sperm counts (both total and normalized to total weight) were generally lower (22% to 25%) in the dose rats; however, none of these changes attained statistical significance. Epididymis weights in treated males were 10% to 12% lower than vehicle controls with the observed decrease in 25 mg/kg/day males attaining statistical significance. The trend test was also significant. One rat in the 25 mg/kg/day group displayed histopathologic findings in the testis (germinal epithelium degeneration) and epididymis duct (exfoliated germ cell). Testosterone measured at time of necropsy was significantly lower (61%) in the 25 mg/kg/day group (positive trend test).

Table 28 Summary of Reproductive Tissue Evaluations for Male Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy Body Wt. | 337 ± 4 | 324 ± 5 | 316 ± 5 | 308 ± 5**
L. Cauda Epididymis | 0.230 ± 0.035** | 0.197 ± 0.007 | 0.188 ± 0.004 | 0.179 ± 0.006
L. Epididymis | 0.584 ± 0.037* | 0.519 ± 0.008 | 0.524 ± 0.012 | 0.512 ± 0.011*
L. Testis | 1.840 ± 0.029 | 1.786 ± 0.040 | 1.780 ± 0.043 | 1.774 ± 0.036
Spermatid Measurements
Spermatid Heads (10^6^/testis) | 294.3 ± 13.6 | 269.2 ± 13.7 | 253.9 ± 13.7 | 255.8 ± 11.5
Spermatid Heads (10^6^/g testis) | 159.8 ± 6.3* | 150.7 ± 6.9 | 141.9 ± 4.8 | 144.4 ± 6.4
Epididymal Spermatozoal Measurements
Sperm Motility (%) | 88.5 ± 0.5 | 87.9 ± 0.3 | 87.9 ± 0.3 | 88.2 ± 0.5
Sperm (10^6^/g cauda epididymis) | 148.4 ± 17.4 | 111.0 ± 8.2 | 115.3 ± 7.8 | 116.3 ± 8.4
Sperm (10^6^/cauda epididymis) | 671 ± 46 | 562 ± 31 | 616 ± 44 | 643 ± 33
Testosterone (ng/mL) | 4.03 ± 0.48 | 3.14 ± 0.91 | 4.37 ± 1.29 | 1.56 ± 0.39*

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group were analyzed for significance by Williams’ or Dunnett’s test (cauda epididymis and testis weights) or Shirley’s or Dunn’s test (spermatid and epididymal spermatozoal measurements). A Jonckheere trend test was performed on each endpoint.

Summary statistics based on the daily vaginal cytology data suggested that the proportion of time female rats spent in each stage of the cycle was similar across assessed groups (Table 29 and Table A-8; Figure A-4). However, Markov analyses demonstrated that females in all assessed groups administered Wyeth-14,643 had a higher probability than the vehicle control group of transitioning to extended diestrus (Table 29 and Table A-8). Under the conditions of this study, these data indicate that Wyeth-14,643 via oral gavage exhibits the potential to be a reproductive toxicant in female Sprague Dawley rats based on altered estrus cyclicity (extended diestrus).

Table 29 Estrous Cycle Characterization for Female Rats in the 28-day Gavage Study of Wyeth-14,643^a^

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
n | 10 | 10 | 9 | 10
Necropsy Body Wt. (g) | 224 ± 4 | 230 ± 4 | 229 ± 3^b^ | 229 ± 5
Number of Estrous Cycles | 2.0 ± 0.15 | 2.0 ± 0.0 | 1.9 ± 0.11 | 1.8 ± 0.13
Estrous Cycle Length (days) | 5.0 ± 0.16 | 5.0 ± 0.09 | 4.8 ± 0.26 | 5.1 ± 0.16
Estrous Stages (% of cycle)
Diestrus | 55.6 | 61.9 | 58.1 | 61.9
Proestrus | 4.4 | 3.8 | 12.5 | 6.3
Estrus | 38.1 | 32.5 | 25.6 | 28.8
Metestrus | 1.9 | 1.9 | 3.1 | 3.1
Uncertain Diagnosis | 0.0 | 0.0 | 0.6 | 0.0
Markov Analysis
| Overall | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
Overall Tests | p = 0.002 | p = 0.085 | p < 0.001N | p = 0.983
Extended Diestrus | p < 0.001 | p = 0.005 | p = 0.001 | p = 0.009

^a^ Necropsy body weights, number of estrous cycles, and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle number and length). N indicates that the dose group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dose group had more departures from normal cycling than did the vehicle control group. Tests for equality of all transition matrices are shown in the vehicle control column (Markov analysis).

^b^ n = 10.

#### Pathology

The morphologic features of the lesions discussed in this section are presented in the Histopathologic Descriptions section following these results.

Liver: The incidences of hepatocyte hypertrophy were significantly increased in all dose groups of males and in 25 mg/kg/day females (Table 30). Hepatocyte hypertrophy was in general of minimal to mild severity in males and minimal in females. The average severity increased with increasing dose in males. The incidences of hepatocyte cytoplasmic alteration were significantly increased in all dose groups of males and females, and in general, the lesion was of minimal to marked severity in males and minimal to mild in females. The average severity increased with increasing dose.

Table 30 Incidences of Nonneoplastic Lesions of the Liver in Rats in the 28-day Gavage Study of Wyeth-14,643

| Vehicle Control | 6.25 mg/kg/day | 12.5 mg/kg/day | 25 mg/kg/day
Male
Number Examined Microscopically | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration^a^ | 0 | 9** (1.7)^b^ | 10** (2.2) | 10** (4.0)
Hepatocyte, Hypertrophy | 0 | 5* (1.4) | 10** (1.5) | 10** (2.0)
Female
Number Examined Microscopically | (10) | (10) | (10) | (10)
Hepatocyte, Cytoplasmic Alteration | 0 | 7** (1.0) | 10** (1.2) | 10** (1.9)
Hepatocyte, Hypertrophy | 0 | 0 | 2 (1.0) | 8** (1.1)

* Significantly different (p ≤ 0.05) from the vehicle control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

### Histopathologic Descriptions

In general, the histopathologic changes, when present, in the liver, bone marrow, nose, forestomach, thymus, kidney, and spleen were morphologically similar across the studies. However, the severities of the lesions varied among the studies.

Liver: Hepatocyte hypertrophy (Figure 5, Figure 6, Figure 7, and Figure 8) was characterized by an increase in the size of primarily centrilobular hepatocytes with cytoplasmic granule accumulation or an increase in homogenous eosinophilic cytoplasm (in the absence of distinct eosinophilic cytoplasmic granules). Hepatocyte hypertrophy was graded as minimal (Grade 1) when hepatocytes were enlarged in occasional lobules (up to 10% of the liver involved), mild (Grade 2) when 11% to 33% of the liver was involved, moderate (Grade 3) when 34% to 67% of the liver was involved and marked (Grade 4) when greater than 67% of the liver was involved.

Figure 5

Normal Liver of a Male Sprague Dawley Vehicle Control Rat from the 28-day Gavage Study of Perfluorobutane Sulfonic Acid (H&E)

Figure 6

Higher Magnification of Figure 5 Demonstrating Normal Hepatocytes (H&E)

Figure 7

Centrilobular Areas (Arrows) of Hepatocyte Hypertrophy in a Male Sprague Dawley Rat Administered 500 mg/kg/day Perfluorobutane Sulfonic Acid for 28 Days (H&E)

Hepatocytes are more eosinophilic in these areas.

Figure 8

Higher Magnification of Figure 7 Demonstrating Enlarged Hepatocytes with Eosinophilic Cytoplasm (H&E)

In the hypertrophied area (marked by arrowheads), hepatocyte nuclei are farther apart compared to normal area (asterisk).

Hepatocyte cytoplasmic alteration (Figure 9 and Figure 10) was characterized by an accumulation of eosinophilic granules within the cytoplasm of centrilobular hepatocytes. A grade of minimal (Grade 1) was used when eosinophilic granules were present within occasional centrilobar hepatocytes (up to 10% of the liver involved); mild (Grade 2) when 11% to 33% of the liver was involved, with most or all centrilobular zones affected; moderate (Grade 3) when 34% to 67% of the liver was involved, with widespread centrilobular and midzonal hepatocytes affected, and marked (Grade 4) when greater than 67% of the liver was involved.

Figure 9

Normal Hepatocytes in the Liver of a Male Sprague Dawley Vehicle Control Rat from the 28-day Gavage Study of Perfluorobutane Sulfonic Acid (H&E)

Figure 10

Cytoplasmic Alteration and Hypertrophy Characterized by Enlarged Hepatocytes with Eosinophilic Granular Cytoplasm in a Male Sprague Dawley Rat Administered 1,000 mg/kg/day Perfluorobutane Sulfonic Acid for 28 Days (H&E)

Cytoplasmic vacuolation was characterized by the presence of small round cytoplasmic vacuoles within the hepatocytes. A grade of minimal (Grade 1) was used when cytoplasmic vacuoles were present within occasional centrilobular to midzonal hepatocytes (up to 10% of the liver involved), mild (Grade 2) when 11% to 33% of the liver was involved, moderate (Grade 3) when 34% to 67% of the liver was involved and marked (Grade 4) when greater than 67% of the liver was involved.

Necrosis was characterized by one small area of coagulative necrosis containing hepatocytes with bright eosinophilic cytoplasm, indistinct cell borders, loss of nuclei, and infiltration of small numbers of macrophages and neutrophils. A severity grade of minimal was used for this lesion.

Bone Marrow: Bone marrow hypocellularity was characterized by a decrease in both erythroid and myeloid cell lines and adipocytes (fat cells) in the bone marrow appeared to be more numerous due to loss of hematopoietic cells. Minimal bone marrow hypocellularity was diagnosed when the bone marrow contained approximately 10% to 15% more adipocytes and a corresponding reduction in the number of hematopoietic cells than concurrent vehicle controls. Mild hypocellularity was diagnosed when the bone marrow contained 16% to 30% more adipocytes and a corresponding reduction in the number of hematopoietic cells than concurrent vehicle controls.

Nose: Olfactory epithelium degeneration (Figure 11 and Figure 12) was characterized by segmentally decreased nuclear density and decreased height of the olfactory epithelium due to loss of the olfactory epithelial cells. In the affected segments, the remaining epithelial cells had lost the surface cilia/microvillus border and contained cytoplasmic vacuoles, and there were scattered pyknotic nuclei within the epithelium. Olfactory epithelium degeneration was diagnosed as minimal (Grade 1) when epithelium on up to 25% of the nasal turbinates was affected, as mild (Grade 2) when epithelium on 26% to 50% of the nasal turbinates was affected, as moderate (Grade 3) when epithelium on 51% to 75% of the nasal turbinates was affected, and as marked (Grade 4) when epithelium on greater than 75% of the nasal turbinates was affected.

Figure 11

Normal Olfactory Epithelium in the Nose of a Male Sprague Dawley Vehicle Control Rat from the 28-day Gavage Study of Perfluorobutane Sulfonic Acid (H&E)

Asterisks indicate normal olfactory nerves.

Figure 12

Olfactory Epithelium Degeneration in a Male Sprague Dawley Rat Administered 1,000 mg/kg/day Perfluorobutane Sulfonic Acid for 28 Days (H&E)

Characterized by decreased nuclear density, decreased height of the olfactory epithelium due to the loss of cells (compare the black bar with the black bar in Figure 11) and atrophy of olfactory nerves (asterisks; compare this to asterisks in Figure 11). The surface cilia/microvillus border (arrowhead) is lost and there are pyknotic nuclei (arrows) within the epithelium.

Olfactory epithelium hyperplasia (Figure 13, Figure 14, Figure 15, and Figure 16) was characterized by multifocal to linear areas of proliferation and piling up of the olfactory epithelial cells resulting in disorganization and increased thickness of the epithelium. In some affected segments, focal proliferations of basal epithelial cells extended into the underlying propria effacing the normally distinct border between olfactory epithelium and the underlying lamina propria. A grade of minimal (Grade 1) was used when up to 15% of the olfactory epithelium in Level III was involved, and mild (Grade 2) was used when 16% to 50% of the Level III olfactory epithelium was hyperplastic. No grade higher than minimal was recorded for olfactory epithelial hyperplasia.

Figure 13

Normal Olfactory Epithelium (Arrows) in a Control Female Sprague Dawley Rat (H&E)

Figure 14

Magnified Area from the Section in Figure 13 (H&E) Showing Normal Olfactory Epithelium (Arrow)

Figure 15

Olfactory Epithelium Degeneration (Arrowheads), Associated with Areas of Olfactory Epithelium Hyperplasia (Arrows) in a Female Sprague Dawley Rat Administered 500 mg/kg/day Perfluorobutane Sulfonic Acid for 28 Days (H&E)

Hyperplastic areas are characterized by increased thickness of the epithelium. Compare this to normal olfactory epithelium in Figure 13.

Figure 16

Magnified Area from the Section in Figure 15 (H&E)

The thickness of epithelium is increased, epithelium is disorganized and basal cells extend into the underlying propria (arrows). Compare this to the normal olfactory epithelium in Figure 14.

Olfactory epithelium suppurative inflammation (Figure 17) was characterized by aggregates of neutrophils and cellular debris within the nasal passages and within the epithelium and lamina propria of the ethmoid turbinates. A grade of minimal (Grade 1) was used when up to 25% of the nasal cavity lumen contained neutrophils, mild (Grade 2) when 26% to 50% of the nasal cavity lumen contained neutrophils, moderate (Grade 3) when 51% to 75% of the nasal cavity lumen contained neutrophils and marked (Grade 4) when greater than 75% of the nasal cavity contained neutrophils.

Figure 17

Suppurative Inflammation in the Olfactory Epithelium Region (Asterisks) in a Female Sprague Dawley Rat Administered 1,000 mg/kg/day Perfluorobutane Sulfonic Acid for 28 Days (H&E)

Inflammation is characterized by the presence of degenerate neutrophils and cellular debris (asterisks and inset) within the nasal passages

Olfactory epithelium necrosis (Figure 18) was often limited to the superficial olfactory epithelial cells. Affected cells were swollen, contained condensed, darkly stained nuclei and had hypereosinophilic cytoplasm. Exfoliated necrotic cells were often present in the lumen admixed with degenerate neutrophils and cellular debris. Olfactory epithelium necrosis was diagnosed as minimal (Grade 1) when epithelium on up to 25% of the nasal turbinates was affected, as mild (Grade 2) when epithelium on 26% to 50% of the nasal turbinates was affected, as moderate (Grade 3) when epithelium on 51% to 75% of the nasal turbinates was affected, and as marked (Grade 4) when epithelium on greater than 75% of the nasal turbinates was affected.

Figure 18

Necrosis of Olfactory Epithelium in a Male Sprague Dawley Rat Administered 1,000 mg/kg/day Perfluorobutane Sulfonic Acid for 28 Days (H&E)

Necrosis is characterized by the presence of cells with hypereosinophilic cytoplasm, condensed nuclei, cellular debris with disorganized epithelium (arrows), and the presence of exfoliated cells and degenerate neutrophils in the nasal passage (asterisk).

Stomach, Forestomach: Epithelium hyperplasia was characterized by a focal area of increased cell numbers in the mucosa resulting in an increased thickness and folding of the mucosa. The epithelial cells maintained normal orientation, and atypia was not present. The change was diagnosed as minimal (Grade 1) when a focal area was involved with two times the thickness of normal mucosa, and as mild (Grade 2) when the thickness was three to four times the normal thickness.

Thymus: Atrophy was characterized by thinning of the cortex and loss of the corticomedullary demarcation. The severity of this finding was diagnosed as minimal (Grade 1) when there was up to a 25% reduction in cortex, mild (Grade 2) when there was a 26% to 50% reduction of the cortex, moderate (Grade 3) when there was a 51% to 75% reduction of the cortex and marked (Grade 4) when there was more than 75% reduction in the cortex and loss of the corticomedullary junction.

Kidney: Papilla necrosis (Figure 19, Figure 20, Figure 21, and Figure 22) was characterized by a region of well-defined loss of differential staining with sloughing of renal tubule/collecting duct epithelium from the basement membrane and accumulation of fibrin within the papillary interstitium. Variably, scattered degenerate neutrophils were present within and just adjacent to these foci. Papillary necrosis was diagnosed as minimal (Grade 1) when greater than 10 contiguous tubules were affected and as mild (Grade 2) when 11 to 25 contiguous tubules were affected.

Figure 19

Normal Renal Papilla (Asterisk) in a Vehicle Control Female Sprague Dawley Rat from the 28-day Gavage Study of Perfluorobutane Sulfonic Acid (H&E)

Figure 20

Necrosis of Renal Papilla (Arrow) in a Female Sprague Dawley Rat Administered 1,000 mg/kg/day Perfluorobutane Sulfonic Acid for 28 days (H&E)

Figure 21

Magnified Area of the Papilla of the Vehicle Control Rat Shown in Figure 19 Demonstrating Normal Papilla (H&E)

Figure 22

Magnified Area of the Papilla of the Treated Rat Shown in Figure 20 Demonstrating Necrosis of Papilla (H&E)

Necrosis is characterized by an area with the loss of differential staining, loss of cellular detail, and sloughing of epithelium.

Spleen: Extramedullary hematopoiesis, decreased was characterized by absence of or presence of very rare erythroid elements as compared to the presence of normal, minimal to moderate extramedullary hematopoiesis in vehicle controls.

## Genetic Toxicology

PFBS and PFOS were tested in assays that measure the potential for induction of mutations in bacteria (Salmonella typhimurium strains TA100 and TA98 and Escherichia coli strain WP2 uvrA/pKM101). Chromosomal damage in erythrocyte precursor cells in the peripheral blood was determined in male and female rats from all four of the 28-day studies. Although the damage is induced in the erythroblast population in the bone marrow, it is measured as micronuclei in immature red blood cells (reticulocytes, RET; polychromatic erythrocytes, PCEs) in peripheral blood.

PFBS (concentration range of 50 to 5,000 μg/plate) was judged to be equivocal in S. typhimurium strain TA98 due to a mix of negative and positive results that were observed both in the presence and absence of S9, and an equivocal result in the presence of S9 (Table B-1). No mutagenic activity was seen in S. typhimurium strain TA100 using a similar concentration range or in E. coli strain WP2 uvrA/pKM101 (concentration range of 50 to 1,000 μg/plate). No mutagenic activity was seen for PFOS in S. typhimurium TA100 or TA98 (concentration range of 100 to 5,000 μg/plate) or E. coli strain WP2 uvrA/pKM101 (concentration range of 100 to 10,000 μg/plate) (Table B-2).

In rats, the reticulocyte population is the only red blood cell population that can be accurately assessed for micronucleus frequency in peripheral blood due to efficient splenic scavenging of damaged erythrocytes soon after they emerge from the bone marrow. In females administered PFOS, the frequency of micronucleated PCEs was significantly increased at the highest dose of 5 mg/kg/day (Table B-5). The effect at this dose also resulted in a significant trend test, therefore meeting statistical criteria for a positive result (both a significant trend and at least one significant dose group). However, the frequency at the highest dose was within the historical control range, and therefore the result was judged to be equivocal. No increases in the frequencies of micronucleated erythrocytes (either immature or mature) were observed in peripheral blood samples from males administered PFOS. However, significant, generally dose-dependent decreases in the percentage of PCEs in the peripheral blood of male and female rats were observed, suggesting that the bone marrow was a target for PFOS-induced cytotoxicity.

No increases in the frequencies of micronucleated erythrocytes (either immature or mature) were observed in peripheral blood samples from male or female rats administered PFBS (concentration range of 62.6 to 500 mg/kg/day), PFHxSK (concentration ranges of 0.625 to 10 [males] or 3.12 to 50 [females] mg/kg/day), or Wyeth-14,643 (concentration range of 6.25 to 25 mg/kg/day) for 28 days (Table B-3, Table B-4, and Table B-6, respectively). However, PFBS caused significant, dose-dependent decreases in the percentage of PCEs in the peripheral blood of both sexes, as did PFHxSK in males, suggesting that the bone marrow was a target for cytotoxicity induced by these chemicals.