# Materials and Methods

## Procurement and Characterization

### Perfluoroalkyl Sulfonates

Perfluorobutane sulfonic acid (PFBS) was obtained from Sigma Aldrich (St. Louis, MO) in one lot (15414TE), perfluorohexane sulfonic acid potassium salt (PFHxSK) was obtained from Interchim (Montlucon Cedex, France) in one lot (230002), and perflourooctane sulfonic acid (PFOS) was obtained from Matrix Scientific (Columbia, SC) in one lot (T20G). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory and the study laboratory at Battelle (Columbus, OH) (Appendix C). Reports on analyses performed in support of the perfluorinated alkyl sulfonate studies are on file at the National Institute of Environmental Health Sciences.

Lot 15414TE (PFBS), a colorless liquid; lot 230002 (PFHxSK), a white solid; and lot T20G (PFOS), off-white particles, were identified using infrared (IR) spectroscopy, mass spectrometry (MS), and carbon-13 and fluorine-19 nuclear magnetic resonance (NMR) spectroscopy.

The purity of each perfluorinated alkyl sulfonate lot was determined by high-performance liquid chromatography (HPLC)/ion chromatography (IC) with suppressed conductivity (SC) detection, HPLC with MS detection, and proton-induced X-ray emission (PIXE) spectroscopy (measuring 72 elements from sodium to uranium). Differential scanning calorimetry (DSC) was used to determine the purity of lot T20G. In addition, Karl Fischer titration for lots 15414TE and T20G was performed by Galbraith Laboratories (Knoxville, TN).

For lot 15414TE (PFBS), Karl Fischer titration indicated 0.46% water. HPLC/IC/SC analysis indicated one major peak that was 97.7% of the total peak area and one impurity (2.3% of the total peak area). HPLC/MS analysis indicated one major peak (98.7%) and three impurities with a combined area of 1.3% of the total peak area. The overall purity of lot 15414TE was determined to be greater than 97% (Table 2).

Table 2 Purity of Chemicals in the 28-day Gavage Studies of Perfluoroalkyl Sulfonates

Chemical Name | Lot Number | Percent Purity | Number of Impurities | Percent Impurity
PFBS | 15414TE | >97 | 1 to 3 | 1.3 to 2.3
PFHxSK | 230002 | >98 | 1 to 4 | 0.1 to 1.4
PFOS | T20G | >96 | 1 to 9 | 0.38 to 3.3

PFBS = perfluorobutane sulfonic acid; PFHxSK = perfluorohexane sulfonic acid potassium salt; PFOS = perfluorooctane sulfonic acid.

For lot 230002 (PFHxSK), HPLC/IC/SC analysis indicated one major peak that was 99.9% of the total peak area and one impurity (0.1% of the total peak area). HPLC/MS indicated one major peak (98.6% of the total peak area) and four reportable impurities with areas ≥0.1% of the total peak area. Three of the impurities were identified as PFBS (0.28% of the total peak area), perfluoropentane sulfonic acid (0.42% of the total peak area), and PFOS (0.19% of the total peak area); one impurity (0.49% of the total peak area) was not identified. PIXE spectroscopy found lot 230002 to contain potassium consistent with the structure. The overall purity of lot 230002 was determined to be greater than 98% (Table 2).

For lot T20G (PFOS), Karl Fischer titration indicated 4.63% water. HPLC/IC/SC analysis indicated one major peak (96.7% of the total peak area) and one impurity that represented 3.3% of the total peak area. HPLC/MS indicated one major peak (68.3% of the total peak area) and nine other peaks with areas ≥0.1% of the total peak area. Four of the nine peaks were identified as PFOS isomers (cumulatively 27.7% of the total peak area). From the remaining peaks, two (cumulatively 2.5% of the total peak area) were identified as perfluoroheptane sulfonic acid isomers and one (0.38% of the total peak area) was identified as a perfluorohexane sulfonic acid isomer. Two unidentified peaks accounted for approximately 1% of the total peak area. PIXE spectroscopy indicated an absence of inorganic impurities. Purity estimated by DSC was approximately 98.8%. The overall purity of lot T20G was determined to be greater than 96% based on perfluorooctane sulfonic acid isomers (Table 2).

To ensure stability, the bulk chemicals were stored at refrigerated temperature (lot 15414TE), room temperature (lot 230002), or −20°C (lot T20G) in sealed amber glass containers under nitrogen (PFBS only). Reanalyses of the bulk chemicals were performed by the study laboratory, and no degradation was detected.

### Wyeth-14,643

Wyeth-14,643 was obtained from ChemSyn Laboratories (Lenexa, KS) in one lot (91-314-72-07/91-314-100-33A). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory and the study laboratory at Battelle (Columbus, OH) (Appendix C).

Lot 91-314-72-07/91-314-100-33A, a white powder, was identified using infrared (IR) spectroscopy and proton and carbon-13 NMR spectroscopy. The purity of Wyeth-14,643 was determined by HPLC with ultraviolet light (UV) detection and DSC.

For lot 91-314-72-07/91-314-100-33A, HPLC/UV analysis indicated one major peak (99.4% of the total peak area) and two impurities with areas ≥0.1% of the total peak area. DSC analysis indicated an average purity of 94.3%, which was considered an indication of thermal decomposition rather than impurity of the bulk chemical. The overall purity of lot 91-314-72-07/91-314-100-33A was determined to be greater than 99%.

To ensure stability, the bulk chemical was stored at room temperature in sealed amber glass containers. Reanalyses of the bulk chemical were performed by the study laboratory, and no degradation was detected.

### Tween^®^ 80

Tween 80 (polysorbate 80) was obtained from Spectrum Laboratory Products, Inc. (Gardena, CA), and was used at a 2% concentration as the vehicle in the 28-day gavage studies. The vehicle was prepared by mixing the appropriate amount of Tween 80 with deionized water in a calibrated carboy and stirring with an overhead stirrer until all the Tween 80 was dissolved.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing PFBS, PFHxSK, PFOS, or Wyeth-14,643 with 2% Tween 80 in deionized water to give the required concentrations (Table C-2). Each formulation pH was adjusted to between 6 to 8. The dose formulations were stored at room (PFBS and PFHxSK) or refrigerated (PFOS and Wyeth-14,643) temperatures in amber glass bottles sealed with Teflon^®^-lined lids for no more than 42 days.

Homogeneity studies of the 12.5 and 100 mg/mL dose formulations of PFBS and a stability study of the 12.5 mg/mL dose formulation were performed by the analytical chemistry laboratory using HPLC/IC/SC. Homogeneity was confirmed and stability was confirmed for at least 42 days for dose formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.12 mg/mL formulation and the 10 mg/mL dose formulation of PFHxSK and a stability study of a 0.12 mg/mL formulation were performed by the analytical chemistry laboratory using HPLC/IC/SC. Homogeneity was confirmed and stability was confirmed for at least 42 days for formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.06 mg/mL formulation and the 1 mg/mL dose formulation of PFOS and a stability study of a 0.06 mg/mL formulation were performed by the analytical chemistry laboratory using HPLC/IC/SC. Homogeneity was confirmed, and stability was confirmed for at least 41 days for formulations stored in amber glass bottles sealed with Teflon-lined lids at refrigerated temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of the 1.26 and 5 mg/mL dose formulations of Wyeth-14,643 and a stability study of a 1.26 mg/mL dose formulation were performed by the analytical chemistry laboratory using HPLC/UV. Homogeneity was confirmed, and stability was confirmed for at least 42 days for formulations stored in amber glass bottles sealed with Teflon-lined lids at refrigerated temperature and for at least 3 hours under simulated animal room conditions.

Analyses of the dose formulations for the 28-day studies of PFBS, PFHxSK, PFOS, and Wyeth-14,643 were conducted once for each study by the study laboratory using HPLC/IC/SC or HPLC/UV. All five dose formulations for the PFBS study were within 10% of the target concentrations (Table C-3). Animal room samples of these dose formulations were also analyzed; all six were within 10% of the target concentrations. For the PFHxSK study, all 10 dose formulations and all 10 animal room samples were within 10% of the target concentrations. For the PFOS study, all five dose formulations and all five animal room samples were within 10% of the target concentrations. For the Wyeth-14,643 study, all three dose formulations and all three of the animal room samples were within 10% of the target concentrations.

## Animal Source

Male and female Sprague Dawley (Hsd:Sprague Dawley SD) rats were obtained from Harlan Laboratories, Inc., Indianapolis, IN, now part of Envigo, Inc.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the AAALAC International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Twenty-eight-day Studies

On receipt, rats were approximately 6 to 8 weeks old. Animals were quarantined for 14 (males) or 15 (female) days for PFBS, 21 (male) or 22 (female) days for PFHxSK, 19 (male) or 20 (female) days for PFOS, and 20 (males) or 21 (females) days for Wyeth-14,643. The rats were 10 to 11 weeks old on the first day of each study. Before the studies began, five male and five female rats were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the NTP Sentinel Animal Program (Appendix E). All results were negative.

All dose groups consisted of 10 male and 10 female rats. All test compounds were administered in deionized water with 2% Tween 80 by gavage, 7 days per week for 28 days; control animals received the vehicle only. Doses were selected on the basis of a maximum tolerated daily dose and kinetic information obtained from toxicokinetic studies. PFBS was administered twice daily at one-half the dose for total daily doses of 0, 62.6, 125, 250, 500, or 1,000 mg/kg body weight. PFHxSK was administered once daily at 0, 0.625, 1.25, 2.5, 5, or 10 mg/kg (males) or 0, 3.12, 6.25, 12.5, 25, or 50 mg/kg (females). PFOS was administered once daily at 0, 0.312, 0.625, 1.25, 2.5, or 5 mg/kg. Wyeth-14,643 was administered once daily at 0, 6.25, 12.5, or 25 mg/kg. All formulations were administered at a volume of 5 mL/kg. NTP-2000 feed and water were available ad libitum. Rats were housed five per cage and were observed twice daily. The animals were weighed, and clinical observations were recorded initially, weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 3. Information on feed composition and contaminants is provided in Appendix D.

Table 3 Experimental Design and Materials and Methods in the 28-day Gavage Studies of Perfluoroalkyl Sulfonates

28-day Study
Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley SD) rats
Animal Source
Harlan Laboratories, Inc., Indianapolis, IN (now Envigo)
Time Held Before Studies
PFBS: 14 (males) or 15 (females) days
PFHxSK: 21 (males) or 22 (females) days
PFOS: 19 (males) or 20 (females) days
WY: 20 (males) or 21 (females) days
Average Age When Studies Began
10 to 11 weeks
Date of First Dose
PFBS: January 19 (males) or 20 (females), 2012
PFHxSK: February 9 (males) or 10 (females), 2012
PFOS: January 24 (males) or 25 (females), 2012
WY: January 26 (males) or 27 (females), 2012
Duration of Dosing
7 days per week for 28 Days
Date of Last Dose
PFBS: February 15 (males) or 16 (females), 2012
PFHxSK: March 7 (males) or 8 (females), 2012
PFOS: February 20 (males) or 21 (females), 2012
WY: February 22 (males) or 23 (females), 2012
Necropsy Dates
PFBS: February 16 (males) or 17 (females), 2012
PFHxSK: March 8 (males) or 9 (females), 2012
PFOS: February 21 (males) or 22 (females), 2012
WY: February 23 (males) or 24 (females), 2012
Average Age at Necropsy
14 to 15 weeks
Size of Study Groups
10 males and 10 females
Method of Randomization and Identification
Animals were distributed randomly into groups of approximately equal initial mean body weights and identified by tail tattoo.
Animals per Cage
5
Diet
NTP-2000 irradiated wafer (Zeigler Brothers, Inc., Gardners, PA), available ad libitum; changed weekly
Water
Tap water (City of Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE); changed twice weekly
Bedding
Irradiated Sani-Chips® (P.J. Murphy Forest Products Corp., Montville, NJ), changed twice weekly
Rack Filters
Spun-bonded polyester (Snow Filtration Co., Cincinnati, OH) changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F
Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day
Room air changes: at least 10/hour
Doses
PFBS: 0, 62.6, 125, 250, 500, or 1,000 mg/kg per day (males and females); one-half the dose was administered twice daily approximately 6 hours apart
PFHxSK: males: 0, 0.625, 1.25, 2.5, 5, or 10 mg/kg per day; females: 0, 3.12, 6.25, 12.5, 25, or 50 mg/kg per day
PFOS: 0, 0.312, 0.625, 1.25, 2.5, or 5 mg/kg per day (males and females)
WY: 0, 6.25, 12.5, or 25 mg/kg per day (males and females)
All doses were administered in deionized water with 2% Tween^®^ 80 by gavage (dosing volume, 5 mL/kg)
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical findings were recorded on day 1, weekly thereafter, and at the end of the study.
Method of Euthanasia
Anesthetization with CO_2_:O_2_ (70%:30%) followed by exsanguination by severing the abdominal aorta
Necropsy
Necropsies were performed on all rats. Organs weighed were right adrenal gland, heart, right kidney, liver, lung, spleen, right testis, thymus, thyroid gland, and uterus/cervix/vagina.
Clinical Pathology
Blood was collected from the abdominal aorta of all rats at the end of the studies for hematology and clinical chemistry.
Hematology: hematocrit; manual hematocrit, hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials, blood smear morphological evaluation
Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, globulin, total, direct, and indirect bilirubin, aspartate aminotransferase, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, cholesterol, triglycerides, total bile acids, total triiodothyronine, thyroid stimulating hormone, total and free thyroxine, and testosterone
Histopathology
PFBS: Complete histopathology was performed on rats in the 0, 500, and 1,000 mg/kg per day groups. In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: adrenal gland, bone with marrow, brain, clitoral gland, epididymis, esophagus, eyes, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), lung, lymph nodes (mandibular and mesenteric), mammary gland, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, stomach (forestomach and glandular), trachea, urinary bladder, and uterus. The bone marrow, kidney, liver, nose, ovary, pancreas, spleen, testes, thymus, and thyroid gland were examined in all dose groups.
PFHxSK: Complete histopathology was performed on rats in the 0, 10 (males), and 50 (females) mg/kg per day groups. The tissues examined to a no-effect level were the same as in the PFBS study but also included thymus. The bone marrow, kidney, liver, nose, ovary, pancreas, spleen, testes, and thyroid gland were examined in all dose groups.
PFOS: Complete histopathology was performed on rats in the 0 and 5 mg/kg per day groups. The tissues examined to a no-effect level and those examined in all dose groups were the same as in the PFHxSK study.
WY: Complete histopathology was performed on rats in the 0 and 25 mg/kg per day groups. The tissues examined to a no-effect level and those examined in all dose groups were the same as in the PFHxSK study.
Reproductive Parameters
PFBS: Blood was collected from the abdominal aorta of all rats at the end of the study and analyzed for testosterone levels. Spermatid and sperm samples were collected from 0, 125, 250, and 500 mg/kg per day males at study termination. The following parameters were evaluated: spermatid heads per testis and per gram testis, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for 16 consecutive days prior to the end of the study from females in the 0, 125, 250, and 500 mg/kg per day groups for vaginal cytology evaluations. The percentage of time spent in the various estrous cycle stages and estrous cycle length were evaluated.
PFHxSK: Same as PFBS study except sperm samples were collected from 0, 2.5, 5, and 10 mg/kg per day males, and vaginal samples were collected from 0, 12.5, 25, and 50 mg/kg per day females.
PFOS: Same as PFBS study except sperm samples were collected from 0, 1.25, 2.5, and 5 mg/kg per day males, and vaginal samples were collected from 0, 0.625, 1.25, and 2.5 mg/kg per day females.
WY: Same as PFBS study except sperm and vaginal samples were collected from rats in all dose groups.
Internal Dose Assessment
Approximately 24 hours after the last dose in the PFBS, PFHxSK, and PFOS studies, parent compound concentrations were determined in plasma from blood collected from the abdominal aorta of all rats and in liver samples from the right anterior and posterior lobes of male rats 24 hours after the last dose.
Liver Enzyme Levels and Gene Expression
Samples were collected from the median liver lobe of surviving male rats at study termination for determination of acyl-CoA oxidase activity. Samples were collected from the left liver lobe of all surviving rats at study termination for determination of Acox1, Cyp4a1, Cyp2b1, and Cyp2b2.

PFBS = perfluorobutane sulfonic acid; PFHxSK = perfluorohexane sulfonic acid potassium salt; PFOS = perfluorooctane sulfonic acid; WY = Wyeth-14,643.

Animals were anesthetized with a 70%:30% CO_2_:O_2_ mixture and blood was collected from the abdominal aorta at the end of the studies for hematology, clinical chemistry, thyroid hormone, and testosterone analyses; parent compound concentration; and micronucleus assays. For each animal, blood was collected into two tubes containing K_3_ EDTA and one tube devoid of an anticoagulant. An aliquot of whole blood was removed from one K_3_ EDTA tube and centrifuged, and the plasma was harvested and shipped to Battelle (Columbus, OH) for internal dose analyses^30,31^; the remaining whole blood was used for hematology analysis. The other K_3_ EDTA tube was shipped on wet ice to ILS, Inc. (Durham, NC), for micronuclei analysis the day it was collected. Any remaining plasma was frozen and shipped to the NTP Frozen Tissue Bank (Durham, NC). Blood collected in tubes devoid of anticoagulant was allowed to clot, and the serum harvested for clinical chemistry and hormone analysis, except aspartate aminotransferase activity and total and direct bilirubin concentrations, which were analyzed at a later date using an aliquot of the stored frozen plasma. The hematology analyses were conducted using an Advia 120 (Bayer Diagnostics Division, Tarrytown, NY) and reagents supplied by the manufacturer. A manual hematocrit was determined with the use of a microcentrifuge. Blood smears were stained with a Romanowsky-type stain and the morphology of the leukocytes, erythrocytes and platelets reviewed. Clinical chemistry analyses (including total thyroxine) were completed using a cobas c501 Chemistry Analyzer (Roche, Indianapolis, IN); aspartate aminotransferase activity and bilirubin concentrations were analyzed on an Olympus AU400 Analyzer (Irving, TX). The remaining thyroid hormones were determined by radioimmunoassay (free thyroxine [free T4], total thyroxine [T4], and total triiodothyronine [T3] [MP Biomedicals, Irvine, CA]; thyroid stimulating hormone [TSH] [Institute of Isotopes, Ltd., Budapest, Hungary]). Testosterone was determined by enzyme-linked immunosorbent assay (Calbiotech, Inc., Spring Valley, CA). The parameters measured are listed in Table 3.

Necropsies were performed on all rats. The right adrenal gland, heart, right kidney, liver, lung, spleen, right testis, thymus, thyroid gland, and uterus/cervix/vagina from each animal were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, testes, epididymides and vaginal tunics were first fixed in Davidson’s solution or modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with hematoxylin and eosin. Histopathologic examinations were performed on all rats. Table 3 lists the tissues and organs routinely examined.

At the end of the 28-day studies, samples were collected for sperm motility evaluations on male rats administered 0, 125, 250, or 500 mg/kg/day (PFBS); 0, 2.5, 5, or 10 mg/kg/day (PFHxSK); 0, 1.25, 2.5, or 5 mg/kg/day (PFOS), and 0, 6.25,12.5, or 25 mg/kg/day (Wyeth-14,643). It was recognized that the 28-day dosing duration would not cover the full spermatogenic cycle. The parameters evaluated are listed in Table 3. Male rats were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer. For vaginal cytology, samples were taken from females in the 0, 125, 250, and 500 mg/kg/day (PFBS); 0, 12.5, 25, and 50 mg/kg/day (PFHxSK); 0, 0.625, 1.25, and 2.5 mg/kg/day (PFOS); and 0, 6.25, 12.5, and 25 mg/kg/day (Wyeth-14,643) groups. For 16 consecutive days prior to scheduled terminal euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus).

At the end of the PFBS, PFHxSK, and PFOS studies, 500 mg liver samples from the right anterior and posterior lobes of male rats (male rat liver responses to PFAS are generally greater compared to females) were collected and shipped to Battelle’s Chemistry Technical Center for determination of parent compound concentrations. At the end of all studies, approximately 1 g of liver tissue was collected from the median lobe of male rats, homogenized, frozen, and stored until analyzed for acyl-CoA oxidase activity. From the left liver lobe, tissue samples were placed in RNAlater^®^ (Ambion, Inc., Austin, TX) and stored at 2° to 8°C overnight. The RNAlater supernatant was then removed from the samples, and the samples were frozen at −70° ± 10°C. Samples weighing between 22.0 and 30.0 mg were added to lysis buffer, homogenized, and stored at −80° ± 10°C until RNA was isolated. RNA was extracted from the supernatant, subjected to DNase digestion, and isolated using the Qiagen RNeasy Mini Kit (Qiagen, Valencia, CA). Each RNA sample was analyzed for quantity and purity by ultraviolet analysis using a NanoDrop ND-1000 Spectrophotometer (NanoDrop Technologies, Wilmington, DE). All samples were evaluated for RNA integrity using an RNA 6000 Nano Chip Kit with an Agilent 2100 Bioanalyzer (Agilent, Santa Clara, CA) and then stored at −80°C ± 10°C until further processing. Total RNA (1 μg), isolated from rat tissue samples was reverse transcribed into cDNA using Qiagen RT HT First Strand Kits (Qiagen, Valencia, CA). The cDNA samples were analyzed using Qiagen RT^2^ Custom Arrays in a 96-well plate format. Relative fold change was calculated within the analysis software based on the ∆∆Ct method for relative quantitation. Twelve samples were run on each array plate with a single sample in each column of the plate. The eight wells in each column of the array plates contained the four genes of interest: PPARα-related genes acyl-CoA oxidase (Acox1) and cytochrome P450 4a1 (Cyp4a1), CAR-related genes cytochrome P450 2b1 (Cyp2b1) and cytochrome P450 2b2 (Cyp2b2), a housekeeping gene glyceraldehyde-3-phosphate dehydrogenase (GAPDH), and three array plate quality controls. The parameters measured are listed in Table 3.

Quality control measurements for each sample on each qPCR array plate were evaluated to determine if the data generated from the sample were of sufficient quality prior to analysis using the web-based RT Profiler PCR Array Data Analysis software (version 3.5, SABiosciences, Valencia, CA). The controls on the qPCR array were analyzed for each sample and included a PCR positive/array reproducibility control (PPC), a reverse transcription control (RTC), and a genomic DNA contamination (GDC) control. A sample successfully passed all of these control parameters when the cycle threshold (Ct) value for the PPC was 20 ± 2, the Ct value for the GDC was greater than or equal to 35, and the Ct value of the PPC subtracted from the Ct value of the RTC was less than or equal to 5. If a sample failed the acceptance criteria for the GDC and/or RTC controls, the sample was repeated starting with the reverse transcription (cDNA synthesis) process followed by analysis on a new qPCR array plate. If a sample failed the PPC control, the cDNA sample was used to repeat the sample on a new qPCR array plate. Once all of the data from a single experiment were analyzed and collected (male or female, control animals and all dosages), the quality control data were assessed a second time after the total experimental data were uploaded into the web-based RT Array Data Analysis software (version 3.5, SABiosciences). This provided additional assurance that the data for the entire experiment passed the quality control criteria.

The relative fold change for each gene of interest (Acox1, Cyp4a1, Cyp2b1, and Cyp2b2) was calculated within the analysis software for relative quantitation based on the ∆∆Ct method. All of the samples were normalized using the housekeeping gene GAPDH and the geometric mean of all samples in a particular group was used for normalization. The p values (based on Student’s t-test of the replicate values for each gene in the vehicle control group and dose groups) and 95% confidence intervals for each fold change value were also calculated during analysis. The threshold for determining significant differential expression of each gene was a fold change of ≥2 or ≤−2 and a p value ≤0.05.

After a review of the laboratory reports, selected histopathology slides were submitted to quality assessment (QA) pathologists for review. After the review, diagnostic discrepancies/inconsistencies were discussed and resolved with NTP pathologists. The QA pathologist also served as the Pathology Working Group (PWG) pathologist and coordinator. Any remaining discrepancies/inconsistencies were resolved by the PWG. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist and the QA/PWG pathologist. Details of these review procedures have been described, in part, by Maronpot and Boorman^85^ and Boorman et al.^86^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in this report and in the CEBS database (https://manticore.niehs.nih.gov/cebssearch) as the numbers of animals bearing such lesions at a specific anatomic site and as the numbers of animals with that site examined microscopically. The Fisher exact test,^87^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dose and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^88^ and Williams.^89,90^ Hematology, clinical chemistry, hormones, estrous cycle length, number of estrous cycles, parent compound, spermatid, epididymal spermatozoal, hepatic enzymes, and hepatic gene expression data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^91^ (as modified by Williams^92^) and Dunn.^93^ Jonckheere’s test^94^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^95^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^96^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dose group was tested using chi-square statistics.

## Quality Assurance Methods

The 28-day studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^97^ In addition, as records from the 28-day studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at National Institute of Environmental Health Sciences. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.

## Genetic Toxicology

### Bacterial Mutagenicity Test Protocol

The test articles were coded prior to testing. Testing was conducted as reported by Zeiger et al.,^98^ with some modifications. PFBS and PFOS were incubated with the bacterial tester strains (Salmonella typhimurium strains TA98 and TA100 and Escherichia coli strain WP2 uvrA pKM101) either in buffer or S9 mix (metabolic activation enzymes and cofactors from livers of phenobarbital/benzoflavone-induced male Sprague Dawley rats) for 20 minutes at 37°C. Top agar supplemented with L-histidine or L-tryptophan (for the E. coli strain only) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted using an automatic colony counter following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of at least five doses of the test compound. The highest concentration tested was limited by toxicity in the absence of S9; with S9, concentrations were either limited by toxicity or achieved the limit concentration of 10,000 μg/plate. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, not reproducible, or not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. No minimum percentage or fold increase is required for a chemical to be judged positive or weakly positive.

### Rat Peripheral Blood Micronucleus Test Protocol

Blood samples (200 μL per animal) were collected at the end of the studies, stabilized in EDTA tubes and packaged on ice packs for shipment later that same day by overnight courier to ILS, Inc. (Durham, NC). Samples were kept chilled upon arrival at the laboratory the following day and were fixed within 4 hours of receipt. For each sample, 50 μL of blood were dispensed into a microcentrifuge tube containing heparin and mixed by inverting several times. A fixation tube containing ultra-cold methanol was then removed from a −80°C freezer and 180 μL of the heparinized blood sample was forcefully dispensed into the tube, rapidly mixed, and quickly transferred back to the −80°C freezer. The fixed blood samples were stored in the −80°C freezer for at least 3 days prior to flow cytometry analysis of micronucleated red blood cells.

Flow cytometry analysis was performed using MicroFlowPLUS Kit reagents (Litron Laboratories, Rochester, NY) and a Becton-Dickinson FACSCalibur™ dual-laser bench top system (BD Biosciences, San Jose, CA). The analysis was performed according to the kit’s instruction manual with minimal modification.^99,100^ For five peripheral blood samples per dose group, 20,000 (±2,000) immature CD71-positive erythrocytes (also referred to as polychromatic erythrocytes [PCE]) were analyzed by flow cytometry to determine the frequency of normal and micronucleated PCE (MN-PCE). Aggregates were excluded on the basis of forward and side scatter, platelets were excluded on the basis of staining with an anti-CD61 antibody, and nucleated leukocytes were excluded on the basis of intense propidium iodide staining. Normal and micronucleated mature erythrocytes (also referred to as normochromatic erythrocytes [NCE]) were enumerated concurrently during MN-PCE analysis, allowing for calculation of the percentage of PCE among total erythrocytes as a measure of bone marrow toxicity.

In rats, although both immature and mature erythrocytes are evaluated for presence of micronuclei concurrently, the appropriate cell population for determining the frequency of micronucleated cells is the youngest portion of the immature erythrocyte population, i.e., the fraction of immature erythrocytes that is newly emerged from the bone marrow, due to the efficiency with which the rat spleen removes micronucleated red blood cells from circulation.

Data were analyzed as described previously.^101,102^ Mean MN-PCE/1,000 RET and MN-NCE/1,000 erythrocytes, as well as %PCE, were calculated for each animal. These data are summarized in the tables as mean ± standard error of the mean. Levene’s test was used to determine if variances among dose groups were equal at p = 0.05. When variances were equal, linear regression analysis was used to test for linear trend and Williams’ test was used to evaluate pairwise differences between each dose group and the vehicle control group. When variances were unequal, nonparametric methods were used to analyze the data; Jonckheere’s test was used to evaluate linear trend and Dunn’s test was used to assess the significance of pairwise differences between each dose group and the vehicle control group. To maintain the overall significance level at 0.05, the trend as well as the pairwise differences from the vehicle control group were declared statistically significant if p ≤ 0.025. A result was considered positive if the trend test was significant and if at least one dose group was significantly elevated over the vehicle control group, or if two or more dose groups were significantly increased over the corresponding vehicle control group. A response was considered equivocal if only the trend test was significant or if only a single dose group was significantly increased over the vehicle control.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this report, Toxicity Study Report 96, represent a scientific judgment of the overall evidence for activity of the chemical in an assay.