# Introduction

## Chemical and Physical Properties

The per/polyfluorinated alkyl substances (PFAS) are a class of chemicals that consist of alkyl chains in which hydrogen is substituted with fluorines. The subclass of perfluoroalkyl sulfonates (or sulfonic acids) in this Toxicity Study Report consists of aliphatic sulfonates with four, six, or eight carbons (Table 1). The hydrophobic and lipophobic qualities of these chemicals make them useful in surfactants and polymers.^1^

Table 1 Perfluoroalkyl Sulfonates

Chemical Formula | CAS Number | Chemical Structure | Molecular Weight
Perfluorobutane Sulfonic Acid C_4_HF_9_O_3_S | 375-73-5 | | 300.1
Perfluorohexane Sulfonate Potassium Salt C_6_F_13_O_3_SK | 3871-99-6 | | 438.2
Perfluorooctane Sulfonic Acid C_8_HF_17_O_3_S | 1763-23-1 | | 500.1

Perfluorobutane sulfonic acid (PFBS) is a clear, colorless liquid with a boiling point of 210° to 212°C and a vapor pressure of 0.0268 mm Hg (25°C).^2^ Potassium perfluorohexane sulfonate (PFHxSK) is a chunky white solid with a boiling point of 238° to 239°C and a vapor pressure of 0.0046 mm Hg (25°C).^3^ Perfluorooctane sulfonic acid (PFOS) is an off-white powder with a boiling point of 249°C and a vapor pressure of 0.0020 mm Hg (25°C).^4^

## Production, Use, and Human Exposure

Production of PFAS occurs through two major processes. Initially, electrochemical fluorination—developed in the 1950s (using a precursor chemical and hydrogen fluoride)—was the method for producing these sulfonates. This method produced both linear and a variety of branched isomers. Telomerization was developed later and produced linear chemicals using a perfluoroalkyl iodide precursor and tetrafluoroethylene.

These sulfonic acids were primarily used in producing surfactants and polymers that were used in carpets, clothing, and nonstick commercial products such as cookware. PFOS was voluntarily phased out of production between 2000 and 2002^5^ along with perfluorohexane sulfonate (PFHxS). PFBS is considered a replacement for these longer-chain PFAS, exhibiting a faster elimination rate. Although production of the longer-chained PFOS has ceased, precursor compounds (e.g., fluorotelomers) used in products such as fire-fighting foams may breakdown to form PFOS and PFHxS,^1^ contributing to ongoing exposure.

The three sulfonates evaluated in this report display a wide range of human internal exposure.

PFBS: Examination of plasma concentrations of PFBS in American Red Cross donors from 2000 through 2010 found most values were below the limit of quantitation (LOQ = 0.0250 ng/mL).^6^ Serum measurements in Taiwanese children averaged 0.48 ng/mL.^7^ From 2005 to 2014, National Health and Nutrition Examination Survey (NHANES) serum measurements of PFBS have been almost entirely below the limit of detection (LOD = 0.1 ng/mL).

PFHxS: NHANES^8,9^ serum measurements of PFHxS from 1999 to 2014 range from 1 to 2 ng/mL (geometric mean). The most recent measurements suggest a slight decline compared to historical values with the 95th percentile declining from 8.7 ng/mL (1999–2000) to 5.60 ng/mL (2013–2014). Whole blood measurements in China from babies, infants, toddlers, children, and adults in 2009 showed a general increase with age (0.25 ng/mL in babies up to 0.40 ng/mL in adults).^10^ Serum plasma levels of PFHxS averaged 1 to 2 ng/mL in women from California in the 1960s,^11^ and these levels have decreased since the discontinuation of use in the early 2000s,^11,12^ a finding consistent with the NHANES data set.

PFOS: Of the PFAS measured in sera, PFOS generally has the highest exposure levels compared to all other PFAS. Since it was phased out in the early 2000s, the levels of this chemical have continued to drop in human serum. NHANES^8,9^ data of collected human sera show a steady decrease starting from a geometric mean of 30.4 ng/mL in 1999–2000 to 9.32 ng/mL in the most recent 2013–2014 assessment. Although discontinued from use over a decade ago, the long plasma half-life of PFOS and other PFAS that are potentially metabolized to PFOS will likely result in years of continued exposure.

## Regulatory Status

The U.S. Environmental Protection Agency (USEPA) is considering a human health toxicity value for PFBS and related compounds that will be based on a developmental exposure study in mice and other animal studies that show adverse kidney effects.^13,14^ The Minnesota Department of Health^15^ established a guidance value of 2 ppb for PFBS in drinking water.

PFHxS, as with other PFAS chemicals, is currently listed under USEPA’s UCMR3 (Third Unregulated Contaminant Monitoring Rule), which considers suspected contaminants. Production of PFHxS was discontinued at the same time as PFOS,^16^ and currently, there are no regulatory levels set by USEPA.

PFOS, the most prevalent of these three sulfonates, was voluntarily phased out of production between 2000 and 2002.^5^ USEPA published significant new use rules requiring notification for import or manufacturing of PFOS and related sulfonates.^17-19^ USEPA initially provided drinking water provisional advisories of 200 ng/L (parts per trillion) in 2009 predicated on effects on thyroid hormones in cynomolgus monkeys,^20^ which were updated with a lifetime health advisory of 70 ng/L PFOS in drinking water on the basis of decreased rat pup weight and survival.^21^ Recently, the European Food Safety Authority (EFSA) developed tolerable weekly intakes of 13 ng/kg/week for PFOS based on human endpoints.^22^

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

Several studies have evaluated the absorption, distribution, metabolism, excretion, and toxicokinetics of these PFAS; results of these studies indicate large differences in excretion rates and are summarized in this section. Generally, the PFAS sulfonates are water soluble and most of their elimination occurs via urine. The kinetics across the class is variable depending on species, and sex in some cases. Reuptake via renal absorption has been proposed to explain the differential elimination of the class across species and sexes. The notable sex difference of PFOA elimination in rats (female greater than male elimination rate) is reduced by castration of the male thus increasing clearance of PFOA, with evidence suggesting changes in organic anion transporters (OATs) OAT2 and OAT3 as the mechanism.^23^ This mechanism is assumed to apply to the other PFAS displaying similar sex differences. Physiologically based pharmacokinetic (PBPK) modeling of PFAS has included a saturable renal resorption function.^24-29^ The pharmacokinetic properties were evaluated for several PFAS in the Hsd:Sprague Dawley rat, the animal model used in these 28-day toxicity studies.^30-32^

PFBS: Oral administration of 30 mg potassium PFBS/kg body weight in Sprague Dawley rats led to beta half-lives of 4.7 and 7.4 hours in males and females, respectively.^33^ A similar half-life was observed in males after intravenous administration (4.5 hours), whereas females displayed a shorter half-life comparatively (4.0 hours).^33^ These half-lives are consistent with short half-lives reported in Huang et al.^31^ studies in Sprague Dawley rats (~5 hours in males, ~2 hours in females across multiple doses). An intravenous dose of 10 mg/kg potassium PFBS in cynomolgus monkeys demonstrated gamma half-lives of 11.3 hours in males and 83.2 hours in females, respectively. In both species, urine was a major route of elimination.^33^ In human subjects (six men and one woman), the geometric mean half-life was calculated to be 25.8 days, with urine as a major route of elimination.^33^ These studies show a pattern fairly consistent across PFAS of elimination rates highest in rats, lower in monkeys, and the lowest in humans.

PFHxS: A beta half-life of 29.1 days was calculated for Sprague Dawley male rats after a single dose of 10 mg/kg potassium PFHxS administered intravenously, whereas a half-life of 1.64 days was estimated for female rats.^34^ An oral dose of either 1 or 20 mg/kg yielded half-lives of 25 to 27 days in female CD-1 mice and 28 to 31 days in male mice, whereas monkeys administered 10 mg/kg intravenously had half-lives of 87 or 141 days, respectively, in males and females.^34^ NTP studies of PFHxSK showed a perfluorohexane sulfonic acid half-life of 15 to 18 days in male rats and 2 days in female rats after gavage administration of 4, 16, or 32 mg/kg.^31^

Data from 26 retired fluorochemical production workers (24 men, 2 women) indicate the average serum half-life of PFHxS is 7.3 years (8.5 years geometric mean)^35^—with a noted, although not statistically significant, higher average in women than in men (12.8 versus 8.2 years). A recent study of 106 participants of a previously exposed population found a shorter half-life of 5.3 years.^36^ Similar to PFBS, these studies show a pattern of elimination rates highest in rats, lower in monkeys, and the lowest in humans.

PFOS: Kinetics studies demonstrated half-lives of about 40 days in Sprague Dawley male rats, 60 to 70 days in female rats, and 30 to 40 days in CD-1 male and female mice after a single oral administration of 2 or 15 mg/kg in rats and 1 or 20 mg/kg in mice.^37^ Huang et al.^31^ studies in Hsd:Sprague Dawley SD rats showed a half-life of about 38 days in male and female rats after gavage administration of 2 or 20 mg/kg. In cynomolgus monkeys, half-lives of 132 days in males and 110 days in females were observed after intravenous administration.^37^

Data from 26 retired fluorochemical production workers (24 men, 2 women) indicate the average serum half-life of PFOS is 5.4 years (4.8 years geometric mean)^35^ with no noted differences between men and women. A recent study of a previously exposed population found a shorter half-life of 3.4 years.^36^ Similar to the above PFAS, these studies show a pattern of elimination rates highest in rats, lower in monkeys, and the lowest in humans.

## Toxicity

### Experimental Animals

The literature on potential PFAS toxicity is extensive, and the following summaries focus mainly on guideline studies (primarily in rats) for comparison to the results within this report. Liver toxicity is a common finding across this class, ranging from liver hypertrophy or necrosis to alterations in liver gene expression and clinical chemistry changes. Peroxisome proliferator-activated receptor alpha (PPARα) activation—leading to increased related gene expression and enzyme activity (e.g., cytochrome P450 4A1 and acyl-CoA oxidase 1 [Acox1] along with related enzyme activity of acyl-CoA oxidase) by PFAS in rodents—is a mechanistic pathway with varying potency across the class depending on chain length.^38-41^ Generally, longer-chain PFAS display a greater toxicity than shorter chain PFAS, and rodent species display a greater PPARα sensitivity than humans.^40-42^ Gene expression profiling of the liver suggests that constitutive androstane receptor (CAR) induction is another factor in liver toxicity and enzyme alteration.^43,44^

PFBS: A 90-day study in Sprague Dawley rats administered 60, 200, or 600 mg/kg PFBS identified spleen weight decreases in males, total protein and albumin decreases in females, decreases in red blood cell parameters in males, and histologic lesions in the kidney, stomach, and nasal cavity.^45^ A two-generation study in Sprague Dawley rats administered 30, 100, 300, or 1,000 mg/kg potassium PFBS identified liver lesions and no reproductive toxicity at the doses tested.^46^

PFHxS: A reproductive assessment, derived from a guideline OECD 442 design, did not show reproductive or developmental effects up to 10 mg/kg/day; however, changes in clinical chemistry and liver weights were noted in F_0_ males.^47^ Mice administered 6.1 or 9.2 mg/kg PFHxS on postnatal day (PND) 10 displayed differential neuroprotein levels 24 hours later, primarily in the hippocampus and to a lesser degree in the cerebral cortex, but the effects were not apparent later in adult mice.^48^ Another reproductive and developmental toxicity assessment in CD-1 mice noted decreases in litter size at doses of 1.0 and 3.0 mg/kg, and a number of liver-associated effects were observed in males and females.^49^

PFOS: Subchronic studies in cynomolgus monkeys^20^ and rats^50^ observed several effects in the liver, thyroid hormones, and clinical chemistry when administered up to 0.75 mg/kg/day in monkeys or 20 ppm in the diet to rats. A two-generation study in rats administered doses up to 3.2 mg/kg/day observed reduced pup survival and lower body weights at 1.6 and 3.2 mg/kg/day.^51^ Gestational exposure in mice and rats up to 10 or 20 mg/kg/day, respectively, led to reduced maternal weights, with fetal malformations at the highest doses^52^ and neonatal death at the higher doses.^53^ Immune toxicity studies have observed effects from PFOS exposure, which may be independent of PPARα activation.^54^

### Humans

Several epidemiological studies have associated PFAS exposure with disease, with many studies focused on PFOA exposure. Because coexposure to several PFAS is likely, it is difficult to ascertain the contribution of individual PFAS. PFAS have been associated with immune modulation,^55^ endocrine disruption,^56,57^ sperm quality,^58^ and clinical chemistry effects^59-61^ among other findings. Elevated serum PFOA levels during development has been associated with a reduced antibody response (postvaccination) as observed in the Norwegian and Faroe Island birth cohort studies^62-64^ and a cross-sectional study of adolescents using NHANES data.^65^ NTP^55^ conducted a systematic review of immune effects and concluded that PFOA is presumed to be an immune hazard due to evidence from human and animal studies. ATSDR^66^ and the C8 panel reports^67-70^ found associations between exposure and reproductive parameters. EFSA considered changes in clinical chemistry parameters as critical effects in their assessment.^22^

## Carcinogenicity

### Experimental Animals

PFOS (potassium PFOS) was evaluated in a two-year bioassay in Sprague Dawley rats via diet up to 20 ppm.^71^ Increases in hepatocellular adenomas in males and females were observed, whereas an increase in thyroid follicular cell adenoma was observed in a recovery group initially exposed to 20 ppm. Animal carcinogenicity studies for PFBS and PFHxS are not available.

### Humans

As with the toxicity studies, most epidemiological studies have focused on PFOA with similar impediments of coexposure to other PFAS. An International Agency for Research on Cancer (IARC)^72^ evaluation of PFOA classified the chemical as possibly carcinogenic to humans (Group 2B) on the basis of limited evidence in experimental animals and limited evidence in humans of positive associations with testis and kidney cancers.

## Genetic Toxicity

Of the three PFAS evaluated by NTP, the published genetic toxicity data have been focused primarily on PFOS, and with one exception, the genotoxicity data for this chemical derive from in vitro assays using human or rodent cells. Thus far, the small number of in vitro studies that are available for review have reported conflicting results for the genotoxicity of PFOS. Although one study reported positive results for the genotoxicity of this chemical in vivo, a suboptimal time point was used for assessment. Additional research is needed to determine whether PFOS, as well as PFBS and PFHxS, have a potential for inducing genetic damage in vivo and in vitro.

Significant increases in DNA damage were detected using the comet assay in HepG2 cells exposed to PFOS at concentrations ranging from 0.2 to 20 μM for 24 hours.^73^ However, negative comet assay results were reported in HepG2 cells exposed to PFOS at concentrations ranging from 5 to 300 μM for 1 or 24 hours.^74^ Furthermore, no induction of micronuclei was observed in HepG2 cells exposed to the same concentrations of PFOS that were used for the 24-hour comet assay.^74^ One notable difference between experiments conducted by Wielsøe et al.^73^ and those conducted by Florentin et al.^74^ was the final concentration of dimethyl sulfoxide (DMSO) (0.04% versus 2.5%, respectively). DMSO is a known scavenger of free radicals and can protect DNA from oxidative damage.^75^ It has been hypothesized in some studies reviewed here that perfluorinated chemicals such as PFOS may exert genotoxic effects indirectly through generation of oxygen radicals^73,74,76^; therefore, excess DMSO may potentially inhibit the genotoxic effects of perfluorinated chemicals. Additionally, PFOS was negative in a micronucleus assay employing hamster lung V79 cells exposed to 12.5 μg/mL (25 μM; 1% DMSO) for 4 hours in the presence of S9 mix^77^; the authors did not test additional dose levels nor did they provide a rationale for the dose they chose to test. Biochemical experiments suggest that PFOS inhibits the activity of DNA polymerase β by interacting with the enzyme.^78^

In a single reported in vivo study, significant increases in DNA damage, as measured by the comet assay, and significant, dose-dependent increases in micronuclei were observed in bone marrow cells of female Wistar rats exposed to 0.6, 1.25, or 2.5 mg/kg PFOS by oral gavage once every 2 days for 4 weeks.^76^ However, the timing of the tissue sampling (30 hours after exposure) in relation to the treatment time was longer than what is appropriate for these assays, making these results difficult to understand.

In a single report identified for another perfluorinated compound, perfluorohexane sulfonic acid, significant increases in DNA damage were detected using the comet assay in HepG2 cells exposed to concentrations of the chemical ranging from 0.2 to 20 μM for 24 hours.^73^

## Study Rationale

USEPA nominated the PFAS class for comparative toxicity evaluation to understand the relative toxicity of individual members of the class. Chemicals were selected by comparing newer replacement chemicals (perfluorohexanoic acid, and PFBS) that are shorter in chain length to the older, longer-chained PFAS (perfluorooctanoic acid and PFOS) in addition to other environmental PFAS of varying exposure levels (PFHxS, perfluorononanoic acid, and perfluorodecanoic acid). The 28-day toxicity study design was used to evaluate multiple endpoints for each of these chemicals for comparison. Plasma concentrations of each PFAS were measured due to the wide range in kinetics of the individual chemicals across species and sexes. A PPARα positive control study (Wyeth-14,643) was included to understand which PFAS toxicological findings were consistent with this mechanism of toxicity and which appear to be independent of this mechanism.

This study is part of a larger NTP program to evaluate PFAS chemicals, which has included an assessment of the contribution of perinatal exposure to PFOA chronic toxicity and carcinogenicity in rats^79^; evaluation of the toxicokinetics of seven PFAS chemicals after a single dose in rats^32^; and in vitro class evaluations of potential neurotoxicity,^80^ mitochondrial toxicity,^81^ and immunotoxicity^82,83^ with a follow-up in vivo immune toxicity study on perfluorodecanoic acid.^84^