# Appendix F Revision Listing

Errors were identified in the NTP Technical Report on the Toxicity Studies of Perfluoroalkyl Sulfonates (Perfluorobutane Sulfonic Acid, Perfluorohexane Sulfonate Potassium Salt, and Perfluorooctane Sulfonic Acid) Administered by Gavage to Sprague Dawley (Hsd:Sprague Dawley SD) Rats (Toxicity Report 96). Revisions were made throughout the report to address transcription errors; corrections made in the report are specified below. [June 30, 2022]

## F.1 Abstract

Page xv

The concentration of Tween^®^ 80 in water was corrected to read as follows:

Page xv

Terminology related to bile acids and salts was changed to read “total bile acids” consistently throughout the report. Edits were made on pages xv, 25, 49, 58, and 77; in the Summary Table; and in Tables 3, 7, 20, and 26.

Summary Table, page xvi

The direction of effect for absolute heart weight for perfluorooctane sulfonic acid (PFOS) was corrected as follows:

Summary Table, page xvii

The direction of effect for cholesterol (for Wyeth-14,643), triglycerides (for Wyeth-14,643), and aspartate aminotransferase (for perfluorobutane sulfonic acid [PFBS]) was corrected as follows:

Summary Table, page xviii

The direction of effect for total thyroxine (for perfluorohexane sulfonate potassium salt [PFHxSK]), free thyroxine (for PFHxSK), and testosterone (for Wyeth-14,643) was corrected as follows:

## F.2 Materials and Methods

Table 2 , page 7

The percent impurity result (for PFOS) was corrected as follows:

Page 8

The purity and characterization results (for PFOS) were revised as follows:

## F.3 Results

Table 4 , page 20

The values for average body weight for female vehicle control animals and the values for average body weight, body weight as a percent of the vehicle control animals, and the number of survivors for the male and female 1,000 mg/kg/day groups (for PFBS) and an associated footnote were revised as follows:

Page 22

The units for normalized plasma and liver concentrations were adjusted as follows:

Table 5 , page 23

Internal dose analysis tables for PFBS were rerun on January 17, 2019, using updated rules for rounding. The number of reported decimal places was changed from the tenths place to the ones place for plasma concentration and liver concentration to be consistent with the precision of actual data values. Additionally, the units for normalized plasma and liver concentrations were corrected. These changes to improve readability and interpretation were as follows:

Table 7 , pages 26–27

Terminology related to bile salts and acids was changed to read “Total Bile Acids” and values for male aspartate aminotransferase (for PFBS) were added and statistical results for A) male and B) female rats were added as follows:

Page 28

The results text for epididymal sperm counts (for PFBS) was corrected as follows:

Page 34

The units for plasma concentrations were adjusted as follows:

Table 11 , page 36

The administered dose for the female 50 mg/kg/day group (for PFHxSK) was corrected as follows:

Table 12 , page 38

Internal dose analysis tables for PFHxSK were rerun on January 17, 2019, using updated rules for rounding to improve readability and interpretation. The number of reported decimal places was changed from the tenths place to the ones place for plasma concentration and liver concentration to be consistent with the precision of actual data values. Additionally, the units for normalized plasma and liver concentrations were corrected and plasma concentrations for the female 25 mg/kg/day were revised as follows:

Table 14 , page 40

The total thyroxine value for the female 50 mg/kg/day group (for PFHxSK) was adjusted as follows:

Table 15 , page 41

Gene expression data for male and female groups (for PFHxSK) and corrected statistical analysis results were corrected as follows:

Page 43

The units for plasma concentrations were adjusted as follows:

Table 17 , page 44

The average body weight in the female 0.625 mg/kg/day group (for PFOS) was adjusted as follows:

Table 18 , page 46

Internal dose analysis tables for PFOS were rerun on January 17, 2019, using updated rules for rounding. The number of reported decimal places was changed from the tenths place to the ones place for plasma concentration and liver concentration to be consistent with the precision of actual data values. Additionally, the units for normalized plasma and liver concentrations were corrected. These changes to improve readability and interpretation were as follows:

Table 19 , page 47

Values for the male absolute and relative heart weights (for PFOS) and the statistical analysis results were added as follows:

Page 49

The results text for absolute heart weight (for PFOS) was added as follows:

Page 58

The results text for free thyroxine (for Wyeth-14,643) was added as follows:

Table 26 , page 59

Values for testosterone in female rats (for Wyeth-14,643) and statistical analysis results were added as follows:

Table 28 , page 60

Statistical analysis footnotes for male reproductive tissue evaluations (for Wyeth-14,643) were updated as follows:

Page 64

The results text for genetic toxicology was corrected as follows:

Figure 14 , page 70

The figure caption was updated as follows:

## F.4 Discussion

Page 76

The discussion text was updated to reflect the correct table as follows:

Page 79

The discussion text on hematology parameters was revised as follows:

Page 79

The discussion text on bacterial mutagenicity (for PFBS and PFOS) was revised as follows:

Page 79

The discussion text for thymus weight in male and female 500/mg/kg/day groups was revised as follows:

## F.5 Appendix A

Table A-1 , page A-2

The statistical analysis footnotes for male reproductive tissue evaluations (for PFOS) were revised as follows:

Figures 29 –32 , page 87–90

The footnotes for Figure 29a, c, e, and g (page 87); Figure 30a, c, e, and g (page 88); Figure 31a, c, e, g (page 89); and Figure 32a, c, e, and g (page 90) were adjusted from “mol/kg/day” to “mmol/kg/day.” The change is shown as follows in the footnotes for Figure 29a:

## F.6 Appendix B

Table B-1 , page B-2

The bacterial tester strains data for Escherichia coli (for PFBS) were revised as follows:

Table B-3 , page B-4

The frequency of micronuclei data (for PFBS) and p values were corrected as follows:

Table B-5 , page B-6

P values for frequency of micronuclei data (for PFOS) were corrected as follows:

Table B-6 , page B-7

P values for frequency of micronuclei data in female rats (for Wyeth-14,643) were corrected as follows:

## F.7 Appendix C

Page C-3

The purity and characterization results (for PFOS) were updated as follows:

## F.8 Reference Updates

Minor updates or corrections were made to the references listed below:

Reference 5: A spelling error was corrected.

Reference 54: A correction was made to the authors to read “DeWitt JC, Shnyra A, Badr MZ, Loveless SE, Hoban D, Frame SR, Cunard R, Anderson SE, Meade BJ, Peden-Adams MM et al.”

Reference 78: A correction was made to the authors to read “F a¨ rber H, Jones P, Giesy J, Engwall M.”

Reference 118: A correction was made to the page numbers to read “2015;36(1):62-70.”

Reference 121: A correction was made to the page numbers to read “p. 2391-2492.”

References 39, 59, 77, 99, 103, and 125 were revised to spell out each journal name.