# Appendix C Chemical Characterization and Dose Formulation Studies

## C.1 Procurement and Characterization

### C.1.1 Perfluoroalkyl Sulfonates and Wyeth-14,643

Perfluorobutane sulfonic acid (PFBS) was obtained from Sigma Aldrich (St. Louis, MO) in one lot (15414TE), perfluorohexane sulfonate potassium salt (PFHxSK) was obtained from Interchim (Montlucon Cedex, France) in one lot (230002), perflourooctane sulfonic acid (PFOS) was obtained from Matrix Scientific (Columbia, SC) in one lot (T20G), and Wyeth-14,643 (WY) was obtained from ChemSyn Laboratories (Lenexa, KS) in one lot (91-314-72-07/91-314-100-33A); all lots were used in the 28-day gavage studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory and the study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the perfluorinated sulfonate studies are on file at the National Institute of Environmental Health Sciences.

Lot 15414TE (PFBS), a colorless liquid; lot 230002 (PFHxSK), a white solid; lot T20G (PFOS), off-white particles; and lot 91-314-72-07/91-314-100-33A (WY), a white powder, were identified using infrared (IR) spectroscopy, mass spectrometry (MS) (perfluoroalkyl sulfonates only), and proton (WY only), carbon-13, and fluorine-19 (perfluoroalkyl sulfonates only) nuclear magnetic resonance (NMR) spectroscopy. The Advanced Chemistry Development (ACD) spectral prediction program (Version 10.02) was used to predict carbon-13 NMR spectra for each test chemical and proton NMR spectra for WY. Annotated fluorine-fluorine correlated spectroscopy (COSY) two-dimensional data were used to identify the fluorine-fluorine coupling within the perfluoroalkyl sulfonates by the observation of cross-peaks in each fluorine-19 NMR spectrum. For the WY molecule, COSY was used to identify proton-proton coupling, a distortionless enhancement by polarization transfer carbon-13 spectrum series was constructed to determine the types of carbon (methine, methylene, and methyl), and a proton-carbon-13 heteronuclear multiple quantum coherence two-dimensional spectrum was acquired to identify directly bonded protons and carbons. Spectra were in good agreement with the proposed structure of each test chemical, with ACD computer-predicted spectra, and with expected COSY-identified proton-proton and fluorine-fluorine coupling. Observed chemical shifts were in good agreement with those expected and reported for each test article. Representative IR spectra of lots 15414TE, 230002, T20G, and 91-314-72-07/91-314-100-33A are presented in Figure C-1, Figure C-2, Figure C-3, and Figure C-4, respectively.

The purities of lots 15414TE, 230002, and T20G were determined by high-performance liquid chromatography (HPLC)/ion chromatography (IC) with suppressed conductivity (SC) detection, HPLC with MS detection, and proton-induced X-ray emission (PIXE) spectroscopy (measuring 72 elements from sodium to uranium). The purity of lot 91-314-72-07/91-314-100-33A was determined by HPLC with ultraviolet light (UV) detection. Differential scanning calorimetry (DSC) was used to determine the purities of lots T20G and 91-314-72-07/91-314-100-33A using a Perkin-Elmer (Shelton, CT) Diamond differential scanning calorimeter scanning at 1°C per minute over the ranges of 20°C to 130°C, and 135°C to 175°C, respectively. In addition, Karl Fischer titration for lots 15414TE and T20G was performed by Galbraith Laboratories (Knoxville, TN).

For lot 15414TE (PFBS), HPLC/IC/SC analysis using System A (Table C-1) indicated one major peak that was 97.7% of the total peak area and one impurity (2.3% of the total peak area). HPLC/MS analysis using System B indicated one major peak and three impurities with a combined area of 1.3% of the total peak area. PIXE analyses for carbon, hydrogen, oxygen, fluorine, and sulfur were in agreement with the theoretical values for PFBS and indicated the absence of significant inorganic impurities. Karl Fischer titration indicated 0.46% water. The overall purity of lot 15414TE was determined to be greater than 97%.

For lot 230002 (PFHxSK), HPLC/IC/SC analysis using System C indicated one major peak that was 99.9% of the total peak area and one impurity (0.1% of the total peak area). HPLC/MS using a system similar to System B indicated one major peak (98.6% of the total peak area) and four reportable impurities with areas ≥0.1% of the total peak area. Three of the impurities were identified as PFBS (0.28% of the total peak area), perfluoropentane sulfonic acid (0.42% of the total peak area), and PFOS (0.19% of the total peak area); one impurity (0.49% of the total peak area) was not identified. PIXE analyses for potassium and sulfur were in agreement with the theoretical values for PFHxSK and indicated the absence of significant inorganic impurities. The overall purity of lot 230002 was determined to be greater than 98%.

For lot T20G (PFOS), HPLC/IC/SC analysis using System C indicated one major peak (96.7% of the total peak area) and one impurity that represented 3.3% of the total peak area. HPLC/MS using a system similar to System B indicated one major peak (68.3% of the total peak area) and nine other peaks with areas ≥0.1% of the total peak area. Four of the nine peaks were identified as PFOS isomers (cumulatively 27.7% of the total peak area). From the remaining peaks, two (cumulatively 2.5% of the total peak area) were identified as perfluoroheptane sulfonic acid isomers and one (0.38% of the total peak area) was identified as a perfluorohexane sulfonic acid isomer. Two unidentified peaks accounted for approximately 1% of the total peak area. PIXE analyses for carbon, hydrogen, oxygen, fluorine, and sulfur were in agreement with the theoretical values for PFOS and indicated the absence of significant inorganic impurities. DSC indicated an average purity of 98.8%. Karl Fischer titration indicated 4.63% water. The overall purity of lot T20G was determined to be greater than 96% on the basis of PFOS total isomers.

For lot 91-314-72-07/91-314-100-33A (WY), HPLC/UV analysis using System E indicated one major peak (99.4% of the total peak area) and two impurities with areas ≥0.1% of the total peak area. DSC indicated an average purity of 94.3%; this lower calculated purity compared to that shown by HPLC was considered an indication of thermal decomposition rather than impurity of the bulk chemical. The overall purity of lot 91-314-72-07/91-314-100-33A was determined to be greater than 99%.

Stability studies of lots 15414TE (PFBS) and T20G (PFOS) of the bulk chemicals were performed by the analytical chemistry laboratory using HPLC/IC/SC by Systems A and C, respectively. Stability was confirmed for bulk chemical samples stored in sealed amber glass bottles at temperatures up to 60°C for at least 14 days. To ensure stability, the bulk chemicals were stored at refrigerated temperature (lot 15414TE), room temperature (lots 230002 and 91-314-72-07/91-314-100-33A), or −20°C (lot T20G) in sealed amber glass containers under nitrogen (PFBS only). Reanalyses of the bulk chemicals were performed by the study laboratory on December 31, 2011 (lot 15414TE), January 26, 2012 (lot 230002), January 1, 2012 (lot T20G), and January 10, 2012 (lot 91-314-72-07/91-314-100-33A) (prior to the gavage studies) using HPLC/IC/SC or HPLC/UV by Systems A, C, C, and E, respectively, and no degradation of the bulk chemicals was detected.

### C.1.2 Tween^®^ 80

Tween^®^ 80 (polysorbate 80) was obtained from Spectrum Laboratory Products, Inc. (Gardena, CA), and was used at a 2% concentration as the vehicle in the 28-day gavage studies. The vehicle was prepared by mixing the appropriate amount of Tween 80 with deionized water in a calibrated carboy and stirring with an overhead stirrer until all the Tween 80 was dissolved.

## C.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing PFBS, PFHxSK, PFOS, or WY with 2% Tween 80 in deionized water to give the required concentrations (Table C-2). Each formulation pH was adjusted to between 6 and 8. The dose formulations were stored at room (PFBS and PFHxSK) or refrigerated (PFOS and WY) temperatures in amber glass bottles sealed with Teflon^®^-lined lids for no more than 42 days.

Homogeneity studies of the 12.5 and 100 mg/mL dose formulations of PFBS and a stability study of the 12.5 mg/mL dose formulation were performed by the analytical chemistry laboratory using HPLC/IC/SC System A (Table C-1). Homogeneity was confirmed and stability was confirmed for at least 42 days for dose formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature, and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.12 mg/mL formulation and the 10 mg/mL dose formulation of PFHxSK and a stability study of a 0.12 mg/mL formulation were performed by the analytical chemistry laboratory using HPLC/IC/SC System D. Homogeneity was confirmed and stability was confirmed for at least 42 days for formulations stored in amber glass bottles sealed with Teflon-lined lids at room temperature, and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of a 0.06 mg/mL formulation and the 1 mg/mL dose formulation of PFOS and a stability study of a 0.06 mg/mL formulation were performed by the analytical chemistry laboratory using HPLC/IC/SC System D. Homogeneity was confirmed, and stability was confirmed for at least 41 days for formulations stored in amber glass bottles sealed with Teflon-lined lids at refrigerated temperature and for at least 3 hours under simulated animal room conditions.

Homogeneity studies of the 1.26 and 5 mg/mL dose formulations of WY and a stability study of the 1.26 mg/mL dose formulation were performed by the analytical chemistry laboratory using HPLC/UV System E. Homogeneity was confirmed, and stability was confirmed for at least 42 days for formulations stored in amber glass bottles sealed with Teflon-lined lids at refrigerated temperature and for at least 3 hours under simulated animal room conditions.

Analyses of the dose formulations for the 28-day studies of PFBS, PFHxSK, PFOS, and WY were conducted once for each study by the study laboratory using HPLC/IC/SC or HPLC/UV similar to Systems A, D, D, and E, respectively. All five dose formulations for the PFBS study were within 10% of the target concentrations (Table C-3). Animal room samples of these dose formulations were also analyzed; all six were within 10% of the target concentrations. For the PFHxSK study, all 10 dose formulations and all 10 animal room samples were within 10% of the target concentrations. For the PFOS study, all five dose formulations and all five of the animal room samples were within 10% of the target concentrations. For the WY study, all three dose formulations and all three of the animal room samples were within 10% of the target concentrations.

Table C-1 High-performance Liquid Chromatography Systems Used in the 28-day Gavage Studies of Perfluoroalkyl Sulfonates and Wyeth-14,643^a^

Detection System | Column | Solvent System
System A
Suppressed Conductivity | IonPac™ NS1, 150 mm × 4 mm, 5 μm particle size (Dionex Corporation, Sunnyvale, CA) | A) 0.1 M NaOH in water, B) 70% isopropanol in water, and C) water (4%A:28%B:68%C), isocratic; flow rate 0.6 mL/minute
System B
Mass Spectrometry | Luna^®^ C18, 150 mm × 4.6 mm, 5 μm particle size (Phenomenex, Torrance, CA) | A) 2 mM ammonium acetate, and B) 0.1% formic acid in acetonitrile; linear gradient from 49%A:51%B for 68 minutes to 40%A:60%B in 2 minutes, held for 10 minutes, then to 49%A:51%B in 0.1 minute, held for 99.9 minutes; flow rate 1.0 mL/minute
System C
Suppressed Conductivity | IonPac™ NS1, 150 mm × 4 mm, 5 μm particle size (Dionex Corporation) | A) 0.1 M NaOH in water, B) 70% isopropanol in water, and C) water; linear gradient from 1%A:30%B:69%C for 3 minutes to 1%A:43% B:56%C in 14 minutes, held for 3 minutes, then to 1%A:30%B:69%C in 1 minute, held for 14 minutes; flow rate 0.6 mL/minute
System D
Suppressed Conductivity | IonPac™ NS1, 150 mm × 4 mm, 5 μm particle size (Dionex Corporation) | A) 0.1 M NaOH in water, B) 70% isopropanol in water, and C) water; linear gradient from 1%A:30%B:69%C for 3 minutes to 1%A:50%B:49%C in 14 minutes, held for 3 minutes, then to 1%A:30%B:69%C in 1 minute, held for 14 minutes; flow rate 0.6 mL/minute
System E
Ultraviolet (254 nm) Light | Inertsil^®^ ODS-2, 150 mm × 4.6 mm (Phenomenex) | 7.5 mM heptane sulfonic acid (pH 3.4) in water: methanol (32:68), isocratic; flow rate 1 mL/minute

^a^ The high-performance liquid chromatographs were manufactured by Hitachi High-Technologies Science America, Inc. (Chatsworth, CA) (Systems A, C, and D), Agilent Technologies, Inc. (Palo Alto, CA) (System B) or Agilent Technologies, Inc. (Santa Clara, CA) or Waters Corporation (Milford, MA) (System E). The mass spectrometer was manufactured by Micromass^®^ Quattro LC (Manchester, UK) (System B).

Table C-2 Preparation and Storage of Dose Formulations in the 28-day Gavage Studies of Perfluoroalkyl Sulfonates and Wyeth-14,643

Perfluorobutane Sulfonic Acid | Perfluorohexane Sulfonate Potassium Salt | Perfluorooctane Sulfonic Acid | Wyeth-14,643
Preparation
A glove bag was set up with a nitrogen atmosphere inside a fume hood. While in a nitrogen atmosphere, the appropriate amount of perfluorobutane sulfonic acid was weighed inside the glove bag and transferred into a calibrated mixing container containing a stir bar. Approximately 80% of the final total vehicle volume of 2% Tween^®^ 80 in deionized water was added to the mixing container, while in a nitrogen atmosphere, and the formulation was stirred on a stir plate to wet the test article. The mixing container was capped, removed from the glove bag and sonicated for approximately 15 minutes. The formulation was then stirred an additional 15 minutes on a stir plate. If necessary, the pH was adjusted to between 6 and 8 with 10 N, and/or 1 N, and/or 0.1 N NaOH; the formulation was then diluted to final volume with vehicle and stirred for an additional 15 minutes. | The appropriate amount of perfluorohexane sulfonic acid potassium salt was weighed and quantitatively transferred into a calibrated mixing container containing a stir bar, and approximately 90% of the final total vehicle volume of 2% Tween 80 in deionized water was added to the mixing container, and the formulation was stirred on a stir plate for approximately 15 minutes. If necessary, the pH was adjusted to between 6 and 8 with 10 N, and/or 1 N and/or 0.1 N NaOH, or 0.1 N HCl; the formulation was then diluted to volume with vehicle and stirred for an additional 15 minutes. | The appropriate amount of perfluorooctane sulfonic acid was weighed and quantitatively transferred into a calibrated mixing container containing a stir bar, and approximately 90% of the final total vehicle volume of 2% Tween 80 in deionized water was added to the mixing container and the formulation was stirred on a stir plate for approximately 15 minutes. If necessary, the pH was adjusted to between 6 and 8 with 10 N, and/or 1 N and/or 0.1 N NaOH; the formulation was then diluted to final volume with vehicle and stirred for an additional 15 minutes. | The appropriate amount of Wyeth-14,643 was weighed and quantitatively transferred into a calibrated mixing container containing a stir bar, and approximately 90% of the final total vehicle volume of 2% Tween 80 in deionized water was added to the mixing container and the formulation was stirred on a stir plate and/or sonicated for approximately 15 minutes. If necessary, the pH was adjusted to between 6 and 8 with 10 N, and/or 1 N, and/or 0.1 N NaOH; the formulation was then diluted to final volume with vehicle and stirred and/or sonicated for an additional 15 minutes.
Chemical Lot Number
15414TE | 230002 | T20G | 91-314-72-07/91-314-100-33A
Maximum Storage Time
38 days | 39 days | 42 days | 39 days
Storage Conditions
Stored in amber glass bottles sealed with Teflon^®^-lined lids at room temperature | Stored in amber glass bottles sealed with Teflon-lined lids at room temperature | Stored in amber glass bottles sealed with Teflon-lined lids at 5°C | Stored in amber glass bottles sealed with Teflon-lined lids at 5°C
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)

Table C-3 Results of Analyses of Dose Formulations Administered to Rats in the 28-day Gavage Studies of Perfluoroalkyl Sulfonates and Wyeth-14,643

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Perfluorobutane Sulfonic Acid
January 10, 2012 | January 12, 2012 | 6.26 | 6.23 | 0
| | 12.5 | 12.4 | −1
| | 25 | 24.8 | −1
| | 50 | 49.4 | −1
| | 100 | 101 | +1
| February 20, 2012^b^ | 6.26 | 6.45 | +3
| | 6.26 | 6.52 | +4
| | 12.5 | 13.1 | +5
| | 25 | 25.7 | +3
| | 50 | 51.4 | +3
| | 100 | 106 | +6
Perfluorohexane Sulfonate Potassium Salt
January 30, 2012 | January 31, 2012 | 0.125 | 0.121 | −3
| | 0.25 | 0.227 | −9
| | 0.5 | 0.466 | −7
| | 0.624 | 0.603 | −3
| | 1 | 0.990 | −1
| | 1.25 | 1.24 | −1
| | 2 | 2.04 | +2
| | 2.5 | 2.54 | +2
| | 5 | 5.11 | +2
| | 10 | 10.1 | +1
| March 8, 2012^b^
| | 0.125 | 0.122 | −2
| | 0.25 | 0.233 | −7
| | 0.5 | 0.476 | −5
| | 0.624 | 0.599 | −4
| | 1 | 0.980 | −2
| | 1.25 | 1.23 | −2
| | 2 | 2.01 | 1
| | 2.5 | 2.50 | 0
| | 5 | 5.02 | 0
| | 10 | 9.88 | −1
Perfluorooctane Sulfonic Acid
January 11, 2012 | January 13, 2012 | 0.0624 | 0.0573 | −8
| | 0.125 | 0.114 | −9
| | 0.25 | 0.232 | −7
| | 0.5 | 0.483 | −3
| | 1 | 1.01 | +1
| February 23, 2012^b^ | 0.0624 | 0.0595 | −5
| | 0.125 | 0.116 | −7
| | 0.25 | 0.239 | −4
| | 0.5 | 0.507 | +1
| | 1 | 1.06 | +6
Wyeth-14,643
January 16, 2012 | January 18, 2012 | 1.25 | 1.24 | −1
| | 2.5 | 2.48 | −1
| | 5 | 4.95 | −1
| March 1, 2012^b^ | 1.25 | 1.25 | 0
| | 2.5 | 2.49 | 0
| | 5 | 4.94 | −1

^a^ Results of triplicate analyses. Dosing volume for all studies = 5.0 mL/kg. One-half the perfluorobutane sulfonic acid formulations were administered twice per day; perfluorohexane sulfonate potassium salt, perfluorooctane sulfonic acid, and Wyeth-14,643 formulations were administered once per day. For the perfluorobutane sulfonic acid study, 6.26 mg/mL = 62.6 mg/kg/day, 12.5 mg/mL = 125 mg/kg/day, 25 mg/mL = 250 mg/kg/day, 50 mg/mL = 500 mg/kg/day, and 100 mg/mL = 1,000 mg/kg/day. For males in the perfluorohexane sulfonate potassium salt study, 0.125 mg/mL = 0.625 mg/kg/day, 0.25 mg/mL = 1.25 mg/kg/day, 0.5 mg/mL = 2.5 mg/kg/day, 1 mg/mL = 5 mg/kg/day, and 2 mg/mL = 10 mg/kg/day. For females in the perfluorohexane sulfonate potassium salt study, 0.624 mg/mL = 3.12 mg/kg/day, 1.25 mg/mL = 6.25 mg/kg/day, 2.5 mg/mL = 12.5 mg/kg/day, 5 mg/mL = 25 mg/kg/day, and 10 mg/mL = 50 mg/kg/day. For the perfluorooctane sulfonic acid study, 0.0624 mg/mL = 0.312 mg/kg/day, 0.125 mg/mL = 0.625 mg/kg/day, 0.25 mg/mL = 1.25 mg/kg/day, 0.5 mg/mL = 2.5 mg/kg/day, and 1 mg/mL = 5 mg/kg/day. For the Wyeth-14,643 study, 1.25 mg/mL = 6.25 mg/kg/day, 2.5 mg/mL = 12.5 mg/kg/day, and 5 mg/mL = 25 mg/kg/day.

^b^ Animal room samples.

Figure C-1

Infrared Absorption Spectrum of Perfluorobutane Sulfonic Acid

Figure C-2

Infrared Absorption Spectrum of Perfluorohexane Sulfonate Potassium Salt

Figure C-3

Infrared Absorption Spectrum of Perfluorooctane Sulfonic Acid

Figure C-4

Infrared Absorption Spectrum of Wyeth-14,643