# Appendix B Genetic Toxicology

Table B-1 Mutagenicity of Perfluorobutane Sulfonic Acid in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 68 ± 3 | | 57 ± 2 | 53 ± 2
| 50 | 51 ± 2
| 100 | 55 ± 1
| 200 | 53 ± 2
| 350 | 52 ± 12
| 500 | 59 ± 5 | | 51 ± 2 | 63 ± 6
| 1,000 | | | 51 ± 1 | 53 ± 4
| 2,000 | | | 40 ± 1 | 50 ± 2
| 3,500 | | | 40 ± 2 | 47 ± 3
| 5,000 | | | 54 ± 3 | 70 ± 9
Trial Summary | | Negative | | Negative | Negative
Positive Control^b^ | | 377 ± 22 | | 648 ± 21 | 985 ± 39
TA98
| 0 | 17 ± 2 | 12 ± 1 | 21 ± 4 | 29 ± 2 | 13 ± 2
| 50 | 17 ± 2 | 46 ± 4
| 100 | 14 ± 2 | 37 ± 2
| 200 | 19 ± 8 | 27 ± 2
| 350 | 13 ± 1 | 41 ± 4
| 500 | 11 ± 2 | 29 ± 1 | 23 ± 1 | 22 ± 1 | 41 ± 4
| 1,000 | | | 20 ± 3 | 14 ± 4 | 41 ± 1
| 2,000 | | | 24 ± 1 | 16 ± 6 | 40 ± 6
| 3,500 | | | 41 ± 2 | 21 ± 2 | 43 ± 3
| 5,000 | | | 35 ± 9 | 41 ± 2 | 45 ± 8
Trial Summary | | Negative | Positive | Equivocal | Negative | Positive
Positive Control | | 427 ± 4 | 170 ± 6 | 473 ± 20 | 826 ± 50 | 500 ± 28
Escherichia coli WP2 uvrA/pKM101
| 0 | 229 ± 13 | 193 ± 7 | 229 ± 13 | 244 ± 9
| 50 | 212 ± 6 | 201 ± 11
| 100 | 228 ± 11 | 207 ± 7 | 289 ± 6 | 285 ± 15
| 200 | 211 ± 16 | 186 ± 6 | 311 ± 15 | 300 ± 14
| 350 | 165 ± 22 | 220 ± 11
| 500 | 217 ± 7 | 226 ± 9 | 262 ± 25 | 285 ± 3
| 750 | | | 268 ± 8 | 263 ± 4
| 1,000 | | | 273 ± 20 | 284 ± 4
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 663 ± 46 | 768 ± 5 | 713 ± 18 | 752 ± 7

^a^ Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table B-2 Mutagenicity of Perfluorooctane Sulfonic Acid Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 44 ± 7 | 68 ± 3 | 57 ± 2 | 49 ± 3
| 100 | 56 ± 1 | 50 ± 5
| 250 | 43 ± 7 | 51 ± 5
| 500 | 32 ± 6 | 51 ± 8 | 54 ± 2 | 45 ± 1
| 750 | 32 ± 2 | 51 ± 3
| 1,000 | 27 ± 6 | 37 ± 2 | 51 ± 1 | 52 ± 1
| 2,000 | | | 42 ± 2 | 40 ± 1
| 3,500 | | | 36 ± 0 | 36 ± 5
| 5,000 | | | 21 ± 4 | 33 ± 5
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control^b^ | | 385 ± 4 | 377 ± 22 | 648 ± 21 | 985 ± 39
TA98
| 0 | 14 ± 1 | 17 ± 2 | 21 ± 4 | 29 ± 2
| 100 | 22 ± 1 | 18 ± 0
| 250 | 30 ± 3 | 15 ± 1
| 500 | 31 ± 2 | 15 ± 3 | 31 ± 4 | 15 ± 3
| 750 | 22 ± 3 | 17 ± 3
| 1,000 | 28 ± 2 | 18 ± 3 | 24 ± 2 | 13 ± 3
| 2,000 | | | 25 ± 2 | 17 ± 4
| 3,500 | | | 21 ± 2 | 19 ± 3
| 5,000 | | | 15 ± 1 | 11 ± 1
Trial Summary | | Equivocal | Negative | Negative | Negative
Positive Control | | 170 ± 6 | 427 ± 4 | 473 ± 20 | 826 ± 50
Escherichia coli WP2 uvrA/pKM101
| 0 | 229 ± 13 | 178 ± 17 | 231 ± 13 | 242 ± 9
| 100 | 207 ± 10 | 158 ± 22
| 250 | 202 ± 17 | 162 ± 5
| 500 | 172 ± 4 | 151 ± 6
| 750 | 196 ± 7 | 178 ± 5
| 1,000 | 209 ± 21 | 171 ± 13 | 255 ± 14 | 268 ± 12
| 2,500 | | | 259 ± 2 | 257 ± 10
| 5,000 | | | 234 ± 17 | 218 ± 40
| 7,500 | | | 233 ± 17 | 221 ± 23
| 10,000 | | | 227 ± 16 | 236 ± 11
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 663 ± 46 | 768 ± 5 | 713 ± 18 | 752 ± 7

^a^ Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table B-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Administration of Perfluorobutane Sulfonic Acid by Gavage for 28 Days^a^

| Dose^b^ (mg/kg/day) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^c^ | P Value^d^ | Micronucleated NCEs/1,000 NCEs^c^ | P Value^d^ | PCEs (%)^c^ | P Value^d^
Male
Vehicle Control^e^ | | 5 | 0.59 ± 0.11 | | 0.33 ± 0.11 | | 1.01 ± 0.06
PFBS | 62.6 | 5 | 0.50 ± 0.11 | 0.617 | 0.12 ± 0.01 | 1.000 | 0.93 ± 0.06 | 1.000
| 125 | 5 | 0.62 ± 0.05 | 0.574 | 0.13 ± 0.03 | 1.000 | 0.91 ± 0.06 | 1.000
| 250 | 5 | 0.59 ± 0.12 | 0.608 | 0.13 ± 0.02 | 1.000 | 0.83 ± 0.08 | 0.375
| 500 | 5 | 0.57 ± 0.12 | 0.626 | 0.12 ± 0.02 | 1.000 | 0.55 ± 0.10 | 0.004
| | | p = 0.469^f^ | | p = 0.984 | | p < 0.001
Female
Vehicle Control | | 5 | 0.62 ± 0.12 | | 0.06 ± 0.01 | | 1.23 ± 0.16
PFBS | 62.6 | 5 | 0.51 ± 0.09 | 0.631 | 0.09 ± 0.02 | 0.159 | 0.78 ± 0.10 | 0.046
| 125 | 5 | 0.63 ± 0.18 | 0.558 | 0.08 ± 0.02 | 0.192 | 0.80 ± 0.04 | 0.053
| 250 | 5 | 0.74 ± 0.07 | 0.349 | 0.09 ± 0.01 | 0.206 | 0.70 ± 0.13 | 0.009
| 500 | 5 | 0.70 ± 0.08 | 0.362 | 0.06 ± 0.01 | 0.213 | 0.55 ± 0.10 | <0.001
| | | p = 0.154 | | p = 0.647 | | p = 0.001

PFBS = perfluorobutane sulfonic acid; PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^100^

^b^ One-half the dose was administered twice daily. No data were available for 1,000 mg/kg/day rats due to high mortality.

^c^ Mean ± standard error.

^d^ Pairwise comparison with the vehicle control group; dose group values for PCEs and NCEs are significant when the one-sided p ≤ 0.025 by Williams’ test. P values for % PCEs are compared to a two-sided p ≤ 0.05.

^e^ The vehicle control was 2% Tween^®^ 80 in deionized water.

^f^ Dose-related trend; significant when compared to one-sided p ≤ 0.025 by linear regression or Jonckheere’s test.

Table B-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Administration of Perfluorohexane Sulfonate Potassium Salt by Gavage for 28 Days^a^

| Dose (mg/kg/day) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Vehicle Control^d^ | | 5 | 0.53 ± 0.06 | | 0.05 ± 0.01 | | 0.98 ± 0.07
PFHxSK | 0.625 | 5 | 0.62 ± 0.09 | 0.521 | 0.06 ± 0.02 | 1.000 | 0.78 ± 0.08 | 0.038
| 1.25 | 5 | 0.48 ± 0.10 | 0.603 | 0.03 ± 0.01 | 1.000 | 0.74 ± 0.03 | 0.045
| 2.5 | 5 | 0.65 ± 0.07 | 0.638 | 0.04 ± 0.01 | 1.000 | 0.81 ± 0.05 | 0.047
| 5 | 5 | 0.37 ± 0.11 | 0.657 | 0.03 ± 0.00 | 1.000 | 0.69 ± 0.06 | 0.003
| 10 | 5 | 0.47 ± 0.06 | 0.670 | 0.04 ± 0.01 | 1.000 | 0.67 ± 0.05 | 0.002
| | | p = 0.887^e^ | | p = 0.974 | | p = 0.007
Female
Vehicle Control | | 5 | 0.75 ± 0.08 | | 0.12 ± 0.03 | | 0.91 ± 0.12
PFHxSK | 3.12 | 5 | 0.67 ± 0.09 | 0.764 | 0.08 ± 0.02 | 0.828 | 1.27 ± 0.14 | 0.352
| 6.25 | 5 | 0.54 ± 0.07 | 0.843 | 0.09 ± 0.01 | 0.897 | 0.94 ± 0.12 | 0.423
| 12.5 | 5 | 0.76 ± 0.09 | 0.872 | 0.09 ± 0.02 | 0.918 | 1.03 ± 0.11 | 0.453
| 25 | 5 | 0.61 ± 0.11 | 0.884 | 0.08 ± 0.01 | 0.928 | 0.98 ± 0.06 | 0.466
| 50 | 5 | 0.59 ± 0.12 | 0.894 | 0.10 ± 0.03 | 0.836 | 1.01 ± 0.11 | 0.474
| | | p = 0.821 | | p = 0.445 | | p = 0.975

PFHxSK = perfluorohexane sulfonate potassium salt; PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^100^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dose group values for PCEs and NCEs are significant when the one-sided p ≤ 0.025 by Williams’ test. P values for % PCEs are compared to a two-sided p ≤ 0.05.

^d^ The vehicle control was 2% Tween^®^ 80 in deionized water.

^e^ Dose-related trend; significant when compared to one-sided p ≤ 0.025 by linear regression or Jonckheere’s test.

Table B-5 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Administration of Perfluorooctane Sulfonic Acid by Gavage for 28 Days^a^

| Dose (mg/kg/day) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Vehicle Control^d^ | | 5 | 0.50 ± 0.12 | | 0.12 ± 0.03 | | 0.83 ± 0.04
PFOS | 0.312 | 5 | 0.89 ± 0.14 | 0.077 | 0.14 ± 0.01 | 0.431 | 0.75 ± 0.06 | 0.482
| 0.625 | 5 | 0.76 ± 0.08 | 0.092 | 0.16 ± 0.03 | 0.285 | 0.76 ± 0.08 | 0.568
| 1.25 | 5 | 0.67 ± 0.05 | 0.098 | 0.08 ± 0.01 | 1.000 | 0.68 ± 0.05 | 0.227
| 2.5 | 5 | 0.72 ± 0.05 | 0.099 | 0.07 ± 0.01 | 1.000 | 0.54 ± 0.07 | 0.003
| 5 | 5 | 0.70 ± 0.20 | 0.101 | 0.10 ± 0.01 | 1.000 | 0.41 ± 0.04 | <0.001
| | | p = 0.466^e^ | | p = 0.961 | | p < 0.001
Female
Vehicle Control | | 5 | 0.43 ± 0.07 | | 0.05 ± 0.00 | | 0.93 ± 0.11
PFOS | 0.312 | 5 | 0.52 ± 0.09 | 0.248 | 0.06 ± 0.03 | 1.000 | 0.83 ± 0.12 | 0.961
| 0.625 | 5 | 0.59 ± 0.10 | 0.200 | 0.03 ± 0.01 | 1.000 | 1.05 ± 0.10 | 0.997
| 1.25 | 5 | 0.59 ± 0.08 | 0.215 | 0.03 ± 0.00 | 1.000 | 0.86 ± 0.09 | 0.763
| 2.5 | 5 | 0.49 ± 0.07 | 0.221 | 0.02 ± 0.00 | 1.000 | 0.63 ± 0.05 | 0.024
| 5 | 5 | 0.77 ± 0.13 | 0.009 | 0.03 ± 0.00 | 1.000 | 0.49 ± 0.07 | <0.001
| | | p = 0.014 | | p = 0.987 | | p < 0.001

PFOS = perfluorooctane sulfonic acid; PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^100^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dose group values for PCEs and NCEs are significant when the one-sided p ≤ 0.025 by Williams’ test. P values for % PCEs are compared to a two-sided p ≤ 0.05.

^d^ The vehicle control was 2% Tween^®^ 80 in deionized water.

^e^ Dose-related trend; significant when compared to one-sided p ≤ 0.025 by linear regression or Jonckheere’s test.

Table B-6 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Exposure to Wyeth-14,643 by Gavage for 28 Days^a^

| Dose (mg/kg/day) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Vehicle Control^d^ | | 5 | 0.51 ± 0.09 | | 0.08 ± 0.01 | | 0.97 ± 0.05
Wyeth-14,643 | 6.25 | 5 | 0.80 ± 0.06 | 0.055 | 0.16 ± 0.04 | 0.131 | 0.76 ± 0.02 | 1.000
Wyeth-14,643 | 12.5 | 5 | 0.86 ± 0.20 | 0.050 | 0.29 ± 0.13 | 0.032 | 1.18 ± 0.15 | 0.236
Wyeth-14,643 | 25 | 5 | 0.79 ± 0.08 | 0.053 | 0.12 ± 0.03 | 0.465 | 1.08 ± 0.07 | 0.249
Wyeth-14,643 | | | p = 0.096^e^ | | p = 0.126 | | p = 0.110
Female
Vehicle Control | | 5 | 0.47 ± 0.09 | | 0.04 ± 0.00 | | 1.10 ± 0.09
Wyeth-14,643 | 6.25 | 5 | 0.73 ± 0.13 | 0.105 | 0.06 ± 0.01 | 0.056 | 0.95 ± 0.09 | 1.000
Wyeth-14,643 | 12.5 | 5 | 0.58 ± 0.07 | 0.127 | 0.04 ± 0.01 | 0.890 | 1.29 ± 0.07 | 0.187
Wyeth-14,643 | 25 | 5 | 0.62 ± 0.06 | 0.135 | 0.04 ± 0.01 | 0.946 | 1.40 ± 0.11 | 0.053
Wyeth-14,643 | | | p = 0.292 | | p = 0.446 | | p = 0.013

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^100^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dose group values for PCEs and NCEs are significant when the one-sided p ≤ 0.025 by Williams’ test. P values for % PCEs are compared to a two-sided p ≤ 0.05.

^d^ The vehicle control was 2% Tween^®^ 80 in deionized water.

^e^ Dose-related trend; significant when compared to one-sided p ≤ 0.025 by linear regression or Jonckheere’s test.