# Appendix A Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table A-1 Summary of Reproductive Tissue Evaluations for Male Rats in the 28-day Gavage Study of Perfluorobutane Sulfonic Acid^a^

| Vehicle Control | 62.6 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
n | 10 | 10 | 10 | 10 | 10
Weights (g)
Necropsy Body Wt. | 342 ± 7 | 335 ± 8 | 349 ± 9 | 348 ± 9 | 317 ± 6
L. Cauda Epididymis | 0.195 ± 0.005 | – | 0.181 ± 0.007 | 0.194 ± 0.007 | 0.195 ± 0.005
L. Epididymis | 0.531 ± 0.008 | – | 0.517 ± 0.012 | 0.532 ± 0.014 | 0.532 ± 0.011
L. Testis | 1.786 ± 0.026 | – | 1.818 ± 0.041 | 1.828 ± 0.053 | 1.891 ± 0.033
Spermatid Measurements
Spermatid Heads (10^6^/testis) | 300.5 ± 12.0 | – | 295.4 ± 10.9 | 269.9 ± 12.9 | 287.9 ± 10.2
Spermatid Heads (10^6^/g testis) | 168.3 ± 6.5* | – | 163.0 ± 5.9 | 147.4 ± 4.6 | 152.3 ± 5.0
Epididymal Spermatozoal Measurements
Sperm Motility (%) | 87.9 ± 0.2 | – | 87.0 ± 0.6 | 88.0 ± 0.3 | 86.8 ± 0.5
Sperm (10^6^/Cauda Epididymis) | 132.9 ± 12.0 | – | 113.0 ± 8.2 | 115.6 ± 4.7 | 112.3 ± 7.3
Sperm (10^6^/g Cauda Epididymis) | 677 ± 53 | – | 632 ± 51 | 599 ± 27 | 575 ± 30
Testosterone (ng/mL)^b^ | 3.241 ± 0.508^c^ | 3.102 ± 0.767 | 2.537 ± 0.535 | 4.111 ± 0.582^c^ | 3.724 ± 1.293^c^

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group were analyzed for significance by Williams’ or Dunnett’s test (weights) or Shirley’s or Dunn’s test (spermatid, epididymal spermatozoal, and testosterone measurements). A Jonckheere trend test was performed on each endpoint. One-half the dose was administered twice daily.

^b^ Reproductive parameters were not evaluated in 62.6 mg/kg/day males, and testosterone was not measured in 1,000 m/kg/day males.

^c^ n = 9.

Table A-2 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Perfluorobutane Sulfonic Acid by Gavage for 28 Days

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 125 mg/kg/day vs. vehicle controls | 0.449 | –
Overall Tests | 250 mg/kg/day vs. vehicle controls | <0.001 | –
Overall Tests | 500 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Estrus | Overall | <0.001
Extended Estrus | 125 mg/kg/day vs. vehicle controls | 0.15 | –
Extended Estrus | 250 mg/kg/day vs. vehicle controls | 0.058 | N
Extended Estrus | 500 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Diestrus | Overall | <0.001
Extended Diestrus | 125 mg/kg/day vs. vehicle controls | 0.063 | –
Extended Diestrus | 250 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Diestrus | 500 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 125 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 250 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 500 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 125 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 250 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 500 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | Overall | 0.999
Skipped Estrus | 125 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | 250 mg/kg/day vs. vehicle controls | 0.931 | –
Skipped Estrus | 500 mg/kg/day vs. vehicle controls | 0.92 | –
Skipped Diestrus | Overall | 0.464
Skipped Diestrus | 125 mg/kg/day vs. vehicle controls | 0.321 | N
Skipped Diestrus | 250 mg/kg/day vs. vehicle controls | 0.343 | N
Skipped Diestrus | 500 mg/kg/day vs. vehicle controls | 0.411 | N
Summary of Significant Groups
Overall Tests | 250 mg/kg/day vs. vehicle controls | <0.001 | –
Overall Tests | 500 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Estrus | 500 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Diestrus | 250 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Diestrus | 500 mg/kg/day vs. vehicle controls | <0.001 | –

^a^ N indicates that the dose group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dose group had more departures from normal cycling than did the vehicle control group. The Overall Tests consider all six types of departures from normal cycling. The overall comparison tests for equal transition probabilities across all dose groups. One-half the dose was administered twice daily.

Table A-3 Summary of Reproductive Tissue Evaluations for Male Rats in the 28-day Gavage Study of Perfluorohexane Sulfonate Potassium Salt^a^

| Vehicle Control | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day | 10 mg/kg/day
n | 10 | 10 | 10 | 10 | 10 | 10
Weights (g)
Necropsy Body Wt. | 336 ± 7 | 346 ± 8 | 342 ± 7 | 343 ± 6 | 341 ± 5 | 335 ± 6
L. Cauda Epididymis | 0.198 ± 0.008 | – | – | 0.195 ± 0.005 | 0.195 ± 0.007 | 0.190 ± 0.004
L. Epididymis | 0.548 ± 0.011 | – | – | 0.532 ± 0.010 | 0.538 ± 0.017 | 0.537 ± 0.008
L. Testis | 1.842 ± 0.051 | – | – | 1.879 ± 0.056 | 1.846 ± 0.062 | 1.850 ± 0.019
Spermatid Measurements
Spermatid Heads (10^6^/Testis) | 212.5 ± 7.1 | – | – | 220.0 ± 8.8 | 215.1 ± 14.0 | 213.3 ± 7.3
Spermatid Heads (10^6^/g Testis) | 115.8 ± 4.2 | – | – | 118.0 ± 5.8 | 116.7 ± 6.7 | 115.6 ± 4.6
Epididymal Spermatozoal Measurements
Sperm Motility (%) | 83.4 ± 2.3 | – | – | 85.9 ± 0.7 | 85.0 ± 0.8 | 85.3 ± 0.7
Sperm (10^6^/Cauda Epididymis) | 131.4 ± 13.2 | – | – | 144.0 ± 8.7 | 125.7 ± 9.7 | 128.6 ± 9.1
Sperm (10^6^/g Cauda Epididymis) | 653 ± 51 | – | – | 735 ± 35 | 651 ± 54 | 675 ± 42
Testosterone (ng/mL)^b^ | 4.595 ± 0.680 | 7.739 ± 1.440 | 6.500 ± 1.660 | 8.111 ± 1.747 | 5.875 ± 1.141 | 7.142 ± 1.267

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Williams’ or Dunnett’s test (weights) or Shirley’s or Dunn’s test (spermatid, epididymal spermatozoal, and testosterone measurements).

^b^ Reproductive parameters were not evaluated in 0.625 or 1.25 mg/kg/day males.

Table A-4 Estrous Cycle Characterization for Female Rats in the 28-day Gavage Study of Perfluorohexane Sulfonate Potassium Salt^a^

| Vehicle Control | 12.5 mg/kg/day | 25 mg/kg/day | 50 mg/kg/day
n | 10 | 10 | 9 | 10
Necropsy Body Wt. (g) | 224 ± 3 | 227 ± 4 | 230 ± 3^b^ | 230 ± 3
Number of Estrous Cycles | 2.0 ± 0.0 | 1.9 ± 0.18 | 1.8 ± 0.15 | 2.1 ± 0.28
Estrous Cycle Length (Days) | 5.2 ± 0.21 | 5.5 ± 0.64 | 5.3 ± 0.60 | 4.5 ± 0.20
Estrous Stages (% of Cycle)
Diestrus | 50.6 | 52.5 | 56.9 | 55.6
Proestrus | 8.1 | 11.9 | 6.3 | 8.1
Estrus | 39.4 | 33.1 | 36.3 | 31.3
Metestrus | 1.9 | 2.5 | 0.6 | 5.0

^a^ Necropsy body weights, number of estrous cycles, and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle number and length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated that dosed females did not have extended estrus or diestrus.

^b^ n = 10.

Table A-5 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Perfluorohexane Sulfonate Potassium Salt by Gavage for 28 Days

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 12.5 mg/kg/day vs. vehicle controls | 0.004 | N
Overall Tests | 25 mg/kg/day vs. vehicle controls | <0.001 | N
Overall Tests | 50 mg/kg/day vs. vehicle controls | 0.122 | N
Extended Estrus | Overall | 0.006
Extended Estrus | 12.5 mg/kg/day vs. vehicle controls | 0.054 | N
Extended Estrus | 25 mg/kg/day vs. vehicle controls | 0.038 | N
Extended Estrus | 50 mg/kg/day vs. vehicle controls | 0.054 | N
Extended Diestrus | Overall | 0.002
Extended Diestrus | 12.5 mg/kg/day vs. vehicle controls | 0.117 | N
Extended Diestrus | 25 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Diestrus | 50 mg/kg/day vs. vehicle controls | 0.644 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 12.5 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 50 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 12.5 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 50 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | Overall | 0.999
Skipped Estrus | 12.5 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | 50 mg/kg/day vs. vehicle controls | 0.87 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | 12.5 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 50 mg/kg/day vs. vehicle controls | 1 | –
Summary of Significant Groups
Overall Tests | 12.5 mg/kg/day vs. vehicle controls | 0.004 | N
Overall Tests | 25 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Estrus | 25 mg/kg/day vs. vehicle controls | 0.038 | N
Extended Diestrus | 25 mg/kg/day vs. vehicle controls | <0.001 | N

^a^ N indicates that the dose group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dose group had more departures from normal cycling than did the vehicle control group. The Overall Tests consider all six types of departures from normal cycling. The overall comparison tests for equal transition probabilities across all dose groups.

Table A-6 Summary of Reproductive Tissue Evaluations for Male Rats in the 28-day Gavage Study of Perfluorooctane Sulfonic Acid^a^

| Vehicle Control | 0.312 mg/kg/day | 0.625 mg/kg/day | 1.25 mg/kg/day | 2.5 mg/kg/day | 5 mg/kg/day
n | 10 | 10 | 10 | 10 | 10 | 10
Weights (g)
Necropsy Body Wt. | 337 ± 7 | 340 ± 5 | 338 ± 7 | 331 ± 4 | 333 ± 4 | 309 ± 4**
L. Cauda Epididymis | 0.195 ± 0.007 | – | – | 0.182 ± 0.004 | 0.183 ± 0.006 | 0.195 ± 0.006
L. Epididymis | 0.545 ± 0.015 | – | – | 0.520 ± 0.010 | 0.509 ± 0.008 | 0.524 ± 0.014
L. Testis | 1.864 ± 0.025 | – | – | 1.746 ± 0.038 | 1.766 ± 0.037 | 1.848 ± 0.035
Spermatid Measurements
Spermatid Heads (10^6^/Testis) | 267.0 ± 12.0 | – | – | 249.0 ± 10.2 | 262.5 ± 13.1 | 264.0 ± 14.4
Spermatid Heads (10^6^/g Testis) | 143.2 ± 6.4 | – | – | 142.7 ± 5.2 | 148.2 ± 5.6 | 142.4 ± 6.0
Epididymal Spermatozoal Measurements
Sperm Motility (%) | 87.5 ± 0.4 | – | – | 87.8 ± 0.3 | 87.3 ± 0.4 | 88.4 ± 0.4
Sperm (10^6^/Cauda Epididymis) | 114.0 ± 6.5 | – | – | 104.0 ± 6.9 | 107.5 ± 6.1 | 120.8 ± 8.6
Sperm (10^6^/g Cauda Epididymis) | 591 ± 37 | – | – | 572 ± 35 | 592 ± 38 | 622 ± 40
Testosterone (ng/mL)^b^ | 3.775 ± 0.754 | 5.812 ± 1.602 | 5.074 ± 1.718^c^ | 4.432 ± 1.721 | 5.576 ± 1.167 | 1.867 ± 1.367

** Significantly different (p ≤ 0.01) from the vehicle control group by Williams’ or Dunnett’s test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Williams’ or Dunnett’s test (tissue weights) or Shirley’s or Dunn’s test (spermatid, epididymal spermatozoal, and testosterone measurements).

^b^ Reproductive parameters were not evaluated in 0.312 or 0.625 mg/kg/day males.

^c^ n = 9.

Table A-7 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Perfluorooctane Sulfonic Acid by Gavage for 28 Days

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 0.625 mg/kg/day vs. vehicle controls | <0.001 | –
Overall Tests | 1.25 mg/kg/day vs. vehicle controls | 0.004 | –
Overall Tests | 2.5 mg/kg/day vs. vehicle controls | 0.001 | –
Extended Estrus | Overall | 0.034
Extended Estrus | 0.625 mg/kg/day vs. vehicle controls | 0.059 | N
Extended Estrus | 1.25 mg/kg/day vs. vehicle controls | 0.097 | –
Extended Estrus | 2.5 mg/kg/day vs. vehicle controls | 0.191 | –
Extended Diestrus | Overall | <0.001
Extended Diestrus | 0.625 mg/kg/day vs. vehicle controls | 0.001 | –
Extended Diestrus | 1.25 mg/kg/day vs. vehicle controls | 0.028 | –
Extended Diestrus | 2.5 mg/kg/day vs. vehicle controls | <0.001 | –
Extended Metestrus | Overall | 0.917
Extended Metestrus | 0.625 mg/kg/day vs. vehicle controls | 0.363 | –
Extended Metestrus | 1.25 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 2.5 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 0.625 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 1.25 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 2.5 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | Overall | 0.012
Skipped Estrus | 0.625 mg/kg/day vs. vehicle controls | 0.003 | –
Skipped Estrus | 1.25 mg/kg/day vs. vehicle controls | 0.312 | N
Skipped Estrus | 2.5 mg/kg/day vs. vehicle controls | 0.312 | N
Skipped Diestrus | Overall | 1
Skipped Diestrus | 0.625 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 1.25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 2.5 mg/kg/day vs. vehicle controls | 1 | –
Summary of Significant Groups
Overall Tests | 0.625 mg/kg/day vs. vehicle controls | <0.001 | –
Overall Tests | 1.25 mg/kg/day vs. vehicle controls | 0.004 | –
Overall Tests | 2.5 mg/kg/day vs. vehicle controls | 0.001 | –
Extended Diestrus | 0.625 mg/kg/day vs. vehicle controls | 0.001 | –
Extended Diestrus | 1.25 mg/kg/day vs. vehicle controls | 0.028 | –
Extended Diestrus | 2.5 mg/kg/day vs. vehicle controls | <0.001 | –
Skipped Estrus | 0.625 mg/kg/day vs. vehicle controls | 0.003 | –

^a^ N indicates that the dose group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dose group had more departures from normal cycling than did the vehicle control group. The Overall Tests consider all six types of departures from normal cycling. The overall comparison tests for equal transition probabilities across all dose groups.

Table A-8 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Wyeth-14,643 by Gavage for 28 Days

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | 0.002
Overall Tests | 6.25 mg/kg/day vs. vehicle controls | 0.085 | –
Overall Tests | 12.5 mg/kg/day vs. vehicle controls | <0.001 | N
Overall Tests | 25 mg/kg/day vs. vehicle controls | 0.983 | –
Extended Estrus | Overall | <0.001
Extended Estrus | 6.25 mg/kg/day vs. vehicle controls | 0.032 | N
Extended Estrus | 12.5 mg/kg/day vs. vehicle controls | 0.001 | N
Extended Estrus | 25 mg/kg/day vs. vehicle controls | 0.017 | N
Extended Diestrus | Overall | <0.001
Extended Diestrus | 6.25 mg/kg/day vs. vehicle controls | 0.005 | –
Extended Diestrus | 12.5 mg/kg/day vs. vehicle controls | 0.001 | –
Extended Diestrus | 25 mg/kg/day vs. vehicle controls | 0.009 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 6.25 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 12.5 mg/kg/day vs. vehicle controls | 1 | –
Extended Metestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 6.25 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 12.5 mg/kg/day vs. vehicle controls | 1 | –
Extended Proestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Estrus | Overall | 0.572
Skipped Estrus | 6.25 mg/kg/day vs. vehicle controls | 0.316 | N
Skipped Estrus | 12.5 mg/kg/day vs. vehicle controls | 0.319 | N
Skipped Estrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | 6.25 mg/kg/day vs. vehicle controls | 1 | –
Skipped Diestrus | 12.5 mg/kg/day vs. vehicle controls | 0.934 | –
Skipped Diestrus | 25 mg/kg/day vs. vehicle controls | 1 | –
Summary of Significant Groups
Overall Tests | 12.5 mg/kg/day vs. vehicle controls | <0.001 | N
Extended Estrus | 6.25 mg/kg/day vs. vehicle controls | 0.032 | N
Extended Estrus | 12.5 mg/kg/day vs. vehicle controls | 0.001 | N
Extended Estrus | 25 mg/kg/day vs. vehicle controls | 0.017 | N
Extended Diestrus | 6.25 mg/kg/day vs. vehicle controls | 0.005 | –
Extended Diestrus | 12.5 mg/kg/day vs. vehicle controls | 0.001 | –
Extended Diestrus | 25 mg/kg/day vs. vehicle controls | 0.009 | –

^a^ N indicates that the dose group had fewer departures from normal cycling than did the vehicle control group. Having no N indicates that the dose group had more departures from normal cycling than did the vehicle control group. The Overall Tests consider all six types of departures from normal cycling. The overall comparison tests for equal transition probabilities across all dose groups.

Figure A-1

Vaginal Cytology Plots for Female Rats in the 28-day Gavage Study of Perfluorobutane Sulfonic Acid

I = insufficient number of cells to determine stage; D = diestrus; P = proestrus; E = estrus; M = metestrus. One-half the dose was administered twice daily.

Figure A-2

Vaginal Cytology Plots for Female Rats in the 28-day Gavage Study of Perfluorohexane Sulfonate Potassium Salt

D = diestrus; P = proestrus; E = estrus; M = metestrus.

Figure A-3

Vaginal Cytology Plots for Female Rats in the 28-day Gavage Study of Perfluorooctane Sulfonic Acid

I = insufficient number of cells to determine stage; D = diestrus; P = proestrus; E = estrus; M = metestrus.

Figure A-4

Vaginal Cytology Plots for Female Rats in the 28-day Gavage Study of Wyeth-14,643

I = insufficient number of cells to determine stage; D = diestrus; P = proestrus; E = estrus; M = metestrus.