# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.L. Dzierlenga, Ph.D., Study Scientist
  R.A. Herbert, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
  M.E. Wyde, Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  C.J. Willson, D.V.M., Ph.D., Study Pathologist
  D.B. Rao, Ph.D.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  M.A. Buccellato, D.V.M., Ph.D., Study Pathologist
  M.J. Ryan, D.V.M, Study Pathologist
  L.M. Fomby, D.V.M., Ph.D.
  T.A. Peace, D.V.M.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  E.T. Adams, D.V.M., Ph.D.
  A.E. Brix, D.V.M., Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Provided SMVCE analysis
  R.W. Tyl, Ph.D., Principal Investigator
  C.S. Sloan, M.S.
- NTP Pathology Peer Review, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated slides and contributed to pathology report on 3-month rats and mice, reevaluation of testes and epididymides (October 29, 2012)
  A.E. Brix, D.V.M., Ph.D., Coordinator, Experimental Pathology Laboratories, Inc.
- NTP Pathology Working Group, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated slides and contributed to pathology report on 3-month rats and mice (September 1, 2011)
  J.S. Hoane, D.V.M., Coordinator, Charles River Laboratories, Pathology Associates