# References

1 Lide D Physical constants of organic compounds. CRC Handbook of Chemistry and Physics: Internet Version. BocaRaton, FL: CRC Press; 2005.
2 World Health Organization (WHO). WHO Food Additives Series: 60. Safety evaluation of certain food additives. Geneva, Switzerland: Joint FAO/WHO Expert Committee of Food Additives, International Programme on Chemical Safety; 2009.
3 Gopalakrishnan M Chemical composition of nutmeg and mace. J Spices Aromat Crops. 1992; 1:49–54.
4 Hallström H Thuvander A Toxicological evaluation of myristicin. Nat Toxins. 1997; 5(5):186–192. http://dx.doi.org/10.1002/19970505NT3 9496377
5 Barceloux D Nutmeg (Myristica fragrans Houtt.). Medical Toxicology of Natural Substances: Foods, Fungi, Medicinal Herbs, Toxic Plants, and Venomous Animals. Hoboken (NJ): John Wiley & Sons; 2010. p. 67–70.
6 Ehlers D Kirchhoff J Gerard D Quirin K-W High-performance liquid chromatography analysis of nutmeg and mace oils produced by supercritical CO2 extraction – comparison with steam-distilled oils – comparison of East Indian, West Indian and Papuan oils. Int J Food Sci Technol. 1998; 33(3):215–223. http://dx.doi.org/10.1046/j.1365-2621.1998.00172.x
7 Kapoor IPS Singh B Singh G De Heluani CS De Lampasona MP Catalan CAN Chemical composition and antioxidant activity of essential oil and oleoresins of nutmeg (Myristica fragrans Houtt.) fruits. Int J Food Prop. 2013; 16(5):1059–1070. http://dx.doi.org/10.1080/10942912.2011.576357
8 Buchanan RL Goldstein S Budroe JD Examination of chili pepper and nutmeg oleoresins using the salmonella/mammalian microsome mutagenicity assay. J Food Sci. 1982; 47(1):330–331. http://dx.doi.org/10.1111/j.1365-2621.1982.tb11094.x
9 Power FB Salway AH The constituents of the essential oil of nutmeg. J Chem Soc. 1907; 91:2037–2058. http://dx.doi.org/10.1039/CT9079102037
10 Weil AT Nutmeg as a narcotic. Econ Bot. 1965; 19(3):194–217. http://dx.doi.org/10.1007/BF02914307
11 Muchtaridi SA Subarnas A Apriyantono A Mustarichie R Identification of compounds in the essential oil of nutmeg seeds (Myristica fragrans Houtt.) that inhibit locomotor activity in mice. Int J Mol Sci. 2010; 11(11):4771–4781. http://dx.doi.org/10.3390/ijms11114771 21151471
12 Lichtenstein EP Casida JE Naturally occurring insecticides, Myristicin, an insecticide and synergist occurring naturally in the edible parts of parsnips. J Agric Food Chem. 1963; 11(5):410–415. http://dx.doi.org/10.1021/jf60129a017
13 Huopalahti R Linko RR Composition and content of aroma compounds in dill, Anethum graveolens L., at three different growth stages. J Agric Food Chem. 1983; 31(2):331–333. http://dx.doi.org/10.1021/jf00116a036
14 Simon JE Quinn J Characterization of essential oil of parsley. J Agric Food Chem. 1988; 36(3):467–472. http://dx.doi.org/10.1021/jf00081a015
15 Food and Drug Administration (FDA). Evaluation of the health aspects of nutmeg, mace and their essential oils as food ingredients. Washington D.C.: Department of Health, Education, and Welfare, Food and Drug Administration, Bureau of Foods; 1973. SCOGS-18.
16 Randerath K Putman KL Randerath E Flavor constituents in cola drinks induce hepatic DNA adducts in adult and fetal mice. Biochem Biophys Res Commun. 1993; 192(1):61–68. http://dx.doi.org/10.1006/bbrc.1993.1381 8476434
17 Stanfill SB Ashley DL Quantitation of flavor-related alkenylbenzenes in tobacco smoke particulate by selected ion monitoring gas chromatography-mass spectrometry. J Agric Food Chem. 2000; 48(4):1298–1306. http://dx.doi.org/10.1021/jf990772i 10775389
18 Stanfill SB Brown CR Yan XJ Watson CH Ashley DL Quantification of flavor-related compounds in the unburned contents of bidi and clove cigarettes. J Agric Food Chem. 2006; 54(22):8580–8588. http://dx.doi.org/10.1021/jf060733o 17061837
19 International Trade Centre (ITC). Update of USA spice & herb imports. Market Insider; 2015.
20 International Trade Centre (ITC). Essential oils and oleoresins. International Trade Center, Market Insider; 2015. http://www.intracen.org/itc/market-insider/essential-oils/
21 Archer AW Determination of safrole and myristicin in nutmeg and mace by high-performance liquid chromatography. J Chromatogr A. 1988; 438(1):117–121. http://dx.doi.org/10.1016/S0021-9673(00)90241-3 3379114
22 Daniel D Nutmeg processing and marketing in Granada. Rome, Italy: United Nations, Food and Agriculture Organization; 1994. http://www.fao.org/3/v4084e/v4084e.pdf.
23 Świech K Połeć I Comparison of the insecticidal effectiveness of synthetic and natural myristicin against housefly (Musca domestica L.) and oriental cockroach (Blatta orientalis). CHEMIK. 2013; 11:645–647.
24 Code of Federal Regulations (CFR). 21(§ 582.10).
25 Code of Federal Regulations (CFR). 21(§ 582.20).
26 Casida JE Engel JL Essac EG Kamienski FX Kuwatsuka S Methylene-C14-dioxyphenyl compounds: metabolism in relation to their synergistic action. Science. 1966; 153(3740):1130–1133. http://dx.doi.org/10.1126/science.153.3740.1130 4162081
27 Kamienski FX Casida JE Importance of demethylenation in the metabolism in vivo and in vitro of methylenedioxyphenyl synergists and related compounds in mammals. Biochem Pharmacol. 1970; 19(1):91–112. http://dx.doi.org/10.1016/0006-2952(70)90331-X 4396245
28 Lee HS Jeong TC Kim JH In vitro and in vivo metabolism of myristicin in the rat. J Chromatogr B Biomed Sci Appl. 1998; 705(2):367–372. http://dx.doi.org/10.1016/S0378-4347(97)00531-8 9521577
29 Beyer J Ehlers D Maurer HH Abuse of nutmeg (Myristica fragrans Houtt.): Studies on the metabolism and the toxicologic detection of its ingredients elemicin, myristicin, and safrole in rat and human urine using gas chromatography/mass spectrometry. Ther Drug Monit. 2006; 28(4):568–575. http://dx.doi.org/10.1097/00007691-200608000-00013 16885726
30 Oswald EO Fishbein L Corbett BJ Walker MP Urinary excretion of tertiary amino methoxy methylenedioxy propiophenones as metabolites of myristicin in the rat and guinea pig. Biochim Biophys Acta. 1971; 244(2):322–328. http://dx.doi.org/10.1016/0304-4165(71)90233-9 5125615
31 Jeong HG Yun CH Induction of rat hepatic cytochrome P450 enzymes by myristicin. Biochem Biophys Res Commun. 1995; 217(3):966–971. http://dx.doi.org/10.1006/bbrc.1995.2864 8554622
32 Jeong HG Lee SS Kim HK Yang KH Murine Cyp1a-1 induction in mouse hepatoma Hepa-1C1C7 cells by myristicin. Biochem Biophys Res Commun. 1997; 233(3):619–622. http://dx.doi.org/10.1006/bbrc.1997.6507 9168900
33 Zheng GQ Kenney PM Zhang J Lam LK Inhibition of benzo[a]pyrene-induced tumorigenesis by myristicin, a volatile aroma constituent of parsley leaf oil. Carcinogenesis. 1992; 13(10):1921–1923. http://dx.doi.org/10.1093/carcin/13.10.1921 1423855
34 Ahmad H Tijerina MT Tobola AS Preferential overexpression of a class MU glutathione S-transferase subunit in mouse liver by myristicin. Biochem Biophys Res Commun. 1997; 236(3):825–828. http://dx.doi.org/10.1006/bbrc.1997.7053 9245741
35 Braun U Kalbhen DA Evidence for the biogenic formation of amphetamine derivatives from components of nutmeg. Pharmacology. 1973; 9(5):312–316. http://dx.doi.org/10.1159/000136402 4737998
36 Yun CH Lee HS Lee HY Yim SK Kim KH Kim E Yea SS Guengerich FP Roles of human liver cytochrome P450 3A4 and 1A2 enzymes in the oxidation of myristicin. Toxicol Lett. 2003; 137(3):143–150. http://dx.doi.org/10.1016/S0378-4274(02)00397-1 12523956
37 Ram A Lauria P Gupta R Sharma VN Hypolipidaemic effect of Myristica fragrans fruit extract in rabbits. J Ethnopharmacol. 1996; 55(1):49–53. http://dx.doi.org/10.1016/S0378-8741(96)01473-0 9121167
38 Morita T Jinno K Kawagishi H Arimoto Y Suganuma H Inakuma T Sugiyama K Hepatoprotective effect of myristicin from nutmeg (Myristica fragrans) on lipopolysaccharide/d-galactosamine-induced liver injury. J Agric Food Chem. 2003; 51(6):1560–1565. http://dx.doi.org/10.1021/jf020946n 12617584
39 Marston A Hostettmann K Msonthi JD Isolation of antifungal and larvicidal constituents of Diplolophium buchanani by centrifugal partition chromatography. J Nat Prod. 1995; 58(1):128–130. http://dx.doi.org/10.1021/np50115a019 7760070
40 Narasimhan B Dhake AS Antibacterial principles from Myristica fragrans seeds. J Med Food. 2006; 9(3):395–399. http://dx.doi.org/10.1089/jmf.2006.9.395 17004905
41 Eweka AO Eweka A Histological effects of oral administration of nutmeg on the kidneys of adult Wister rats. N Am J Med Sci. 2010; 2(4):189–192. 22624138
42 Truitt EB Jr Callaway E 3rd Braude MC Krantz JC Jr The pharmacology of myristicin. A contribution to the psychopharmacology of nutmeg. J Neuropsychiatry. 1961; 2:205–210. 13778274
43 de Mello AC Carlini EA Dressler K Green JP Kang S Margolis S Behavioral observations on compounds found in nutmeg. Psychopharmacology (Berl). 1973; 31(4):349–363. http://dx.doi.org/10.1007/BF00421279 4795350
44 Leiter E Hitchcock G Godwin S Johnson M Sedgwick W Jones W McCall S Ceremuga TE Evaluation of the anxiolytic properties of myristicin, a component of nutmeg, in the male Sprague-Dawley rat. AANA J. 2011; 79(2):109–114. 21560973
45 El-Alfy AT Wilson L ElSohly MA Abourashed EA Towards a better understanding of the psychopharmacology of nutmeg: Activities in the mouse tetrad assay. J Ethnopharmacol. 2009; 126(2):280–286. http://dx.doi.org/10.1016/j.jep.2009.08.026 19703539
46 Van Gils C Cox PA Ethnobotany of nutmeg in the Spice Islands. J Ethnopharmacol. 1994; 42(2):117–124. http://dx.doi.org/10.1016/0378-8741(94)90105-8 8072304
47 Cushny AR Nutmeg Poisoning. Proc R Soc Med. 1908; 1 Ther Pharmacol Sect:39–44. 19973353
48 Stein U Greyer H Hentschel H Nutmeg (myristicin) poisoning—report on a fatal case and a series of cases recorded by a poison information centre. Forensic Sci Int. 2001; 118(1):87–90. http://dx.doi.org/10.1016/S0379-0738(00)00369-8 11343860
49 Gupta AD Rajpurohit D Antioxidant and antimicrobial activity of nutmeg (Myristica fragrans). In: Preedy VR Watson RR Patel VBeditors. Nuts and Seeds in Health and Disease Prevention. London, England: Academic Press; 2011. p. 831–839. http://dx.doi.org/10.1016/B978-0-12-375688-6.10098-2
50 Ehrenpreis JE DesLauriers C Lank P Armstrong PK Leikin JB Nutmeg poisonings: A retrospective review of 10 years experience from the Illinois Poison Center, 2001-2011. J Med Toxicol. 2014; 10(2):148–151. http://dx.doi.org/10.1007/s13181-013-0379-7 24452991
51 Carstairs SD Cantrell FL The spice of life: An analysis of nutmeg exposures in California. Clin Toxicol (Phila). 2011; 49(3):177–180. http://dx.doi.org/10.3109/15563650.2011.561210 21495887
52 Rahman NAA, Fazilah A, Effarizah ME. Toxicity of mutmeg (myristicin): A review. Int J Adv Sci Eng Inf Technol. 2015; 5:212-215. http://dx.doi.org/10.18517/ijaseit.5.3.518
53 Uragoda CG Symptoms in spice workers. J Trop Med Hyg. 1992; 95(2):136–139. 1560483
54 Sastre J Olmo M Novalvos A Ibañez D Lahoz C Occupational asthma due to different spices. Allergy. 1996; 51(2):117–120. http://dx.doi.org/10.1111/j.1398-9995.1996.tb04568.x 8738518
55 van den Akker TW Roesyanto-Mahadi ID van Toorenenbergen AW van Joost T Contact allergy to spices. Contact Dermat. 1990; 22(5):267–272. http://dx.doi.org/10.1111/j.1600-0536.1990.tb01594.x 2383985
56 Food and Drug Research Laboratories (FDRL). Teratologic evaluation of FDA 71-28 (oil of nutmeg) in mice. Maspeth, NY: Food and Drug Administration; 1972. FDA Contract No. FDA 71-260. https://ntrl.ntis.gov/NTRL/dashboard/searchResults/titleDetail/PB221807.xhtml
57 National Toxicology Program (NTP). Safrole. 14th Annual Report on Carcinogens. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. https://ntp.niehs.nih.gov/ntp/roc/content/profiles/safrole.pdf
58 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of methyleugenol (CAS No.97-54-1) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2000. Technical Report Series No. 491. NIH Publication No. 00-3950.
59 National Toxicology Program (NTP). Methyleugenol. 14th Annual Report on Carcinogens. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. https://ntp.niehs.nih.gov/ntp/roc/content/profiles/methyleugenol.pdf
60 Auerbach SS Shah RR Mav D Smith CS Walker NJ Vallant MK Boorman GA Irwin RD Predicting the hepatocarcinogenic potential of alkenylbenzene flavoring agents using toxicogenomics and machine learning. Toxicol Appl Pharmacol. 2010; 243(3):300–314. http://dx.doi.org/10.1016/j.taap.2009.11.021 20004213
61 Miller EC Swanson AB Phillips DH Fletcher TL Liem A Miller JA Structure-activity studies of the carcinogenicities in the mouse and rat of some naturally occurring and synthetic alkenylbenzene derivatives related to safrole and estragole. Cancer Res. 1983; 43(3):1124–1134. 6825084
62 Tsai RS Carrupt PA Testa B Caldwell J Structure-genotoxicity relationships of allylbenzenes and propenylbenzenes: A quantum chemical study. Chem Res Toxicol. 1994; 7(1):73–76. http://dx.doi.org/10.1021/tx00037a011 8155828
63 Randerath K Haglund RE Phillips DH Reddy MV ^32^P-post-labelling analysis of DNA adducts formed in the livers of animals treated with safrole, estragole and other naturally-occurring alkenylbenzenes. I. Adult female CD-1 mice. Carcinogenesis. 1984; 5(12):1613–1622. http://dx.doi.org/10.1093/carcin/5.12.1613 6499112
64 Zhou GD Moorthy B Bi J Donnelly KC Randerath K DNA adducts from alkoxyallylbenzene herb and spice constituents in cultured human (HepG2) cells. Environ Mol Mutagen. 2007; 48(9):715–721. http://dx.doi.org/10.1002/em.20348 17948277
65 Phillips DH Reddy MV Randerath K ^32^P-post-labelling analysis of DNA adducts formed in the livers of animals treated with safrole, estragole and other naturally-occurring alkenylbenzenes. II. Newborn male B6C3F1 mice. Carcinogenesis. 1984; 5(12):1623–1628. http://dx.doi.org/10.1093/carcin/5.12.1623 6499113
66 Martins C Doran C Laires A Rueff J Rodrigues AS Genotoxic and apoptotic activities of the food flavourings myristicin and eugenol in AA8 and XRCC1 deficient EM9 cells. Food Chem Toxicol. 2011; 49(2):385–392. http://dx.doi.org/10.1016/j.fct.2010.11.013 21087650
67 Hasheminejad G Caldwell J Genotoxicity of the alkenylbenzenes α- and β-asarone, myristicin and elimicin as determined by the UDS assay in cultured rat hepatocytes. Food Chem Toxicol. 1994; 32(3):223–231. http://dx.doi.org/10.1016/0278-6915(94)90194-5 8157216
68 Kobets T Duan JD Brunnemann KD Etter S Smith B Williams GM Structure-activity relationships for DNA damage by alkenylbenzenes in turkey egg fetal liver. Toxicol Sci. 2016; 150(2):301–311. http://dx.doi.org/10.1093/toxsci/kfv322 26719370
69 King-Herbert A Thayer K NTP workshop: Animal models for the NTP rodent cancer bioassay: Stocks and strains—should we switch? Toxicol Pathol. 2006; 34(6):802–805. http://dx.doi.org/10.1080/01926230600935938 17162538
70 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
71 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
72 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
73 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. http://dx.doi.org/10.1080/01621459.1955.10501294
74 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
75 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
76 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
77 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
78 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. http://dx.doi.org/10.1080/00401706.1964.10490181
79 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. http://dx.doi.org/10.1093/biomet/41.1-2.133
80 Dixon W Massey F Introduction to statistical analysis. New York (NY): McGraw-Hill Book Company; 1957. http://dx.doi.org/10.2307/2332898
81 Code of Federal Regulations (CFR). 21(Part 58).
82 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. http://dx.doi.org/10.1002/em.2850190603 1541260
83 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. http://dx.doi.org/10.1016/j.mrgentox.2007.08.004 17869571
84 Dertinger SD Camphausen K Macgregor JT Bishop ME Torous DK Avlasevich S Cairns S Tometsko CR Menard C Muanza T Three-color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. http://dx.doi.org/10.1002/em.20075 15517570
85 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. http://dx.doi.org/10.1016/j.mrgentox.2007.07.010 17851117
86 Igl BW Bitsch A Bringezu F Chang S Dammann M Frötschl R Harm V Kellner R Krzykalla V Lott J The rat bone marrow micronucleus test: Statistical considerations on historical negative control data. Regul Toxicol Pharmacol. 2019; 102:13–22. http://dx.doi.org/10.1016/j.yrtph.2018.12.009 30572081
87 Livingston RS Besch-Williford CL Myles MH Franklin CL Crim MJ Riley LK Pneumocystis carinii infection causes lung lesions historically attributed to rat respiratory virus. Comp Med. 2011; 61(1):45–59. 21819681
88 National Toxicology Program (NTP). Carcinogenesis studies of eugenol (CAS No.97-53-0) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1983. Technical Report Series No. 223. NIH Publication No. 84-1779.
89 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of isoeugenol (CASNo.93-15-2) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2010. Technical Report Series No. 551. NIH Publication No. 10-5982.
90 National Toxicology Program (NTP). Toxicity studies of estragole (CAS No.140-67-0) administered by gavage to F344/N rats and B6C3F1 mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2011. Toxicity Report Series No. 82. NIH Publication No. 11-5966.
91 Ioannides C Delaforge M Parke DV Safrole: Its metabolism, carcinogenicity and interactions with cytochrome P-450. Food Cosmet Toxicol. 1981; 19(5):657–666. http://dx.doi.org/10.1016/0015-6264(81)90518-6 7030889
92 Gardner I Wakazono H Bergin P de Waziers I Beaune P Kenna JG Caldwell J Cytochrome P450 mediated bioactivation of methyleugenol to 1′-hydroxymethyleugenol in Fischer 344 rat and human liver microsomes. Carcinogenesis. 1997; 18(9):1775–1783. http://dx.doi.org/10.1093/carcin/18.9.1775 9328175
93 Janardhan KS Rebolloso Y Hurlburt G Olson D Lyght O Clayton NP Gruebbel M Picut C Shackelford C Herbert RA Histopathological and immunohistochemical characterization of methyl eugenol-induced nonneoplastic and neoplastic neuroendocrine cell lesions in glandular stomach of rats. Toxicol Pathol. 2015; 43(5):681–693. http://dx.doi.org/10.1177/0192623314560030 25452433
94 Swenberg JA Alpha 2u-globulin nephropathy: Review of the cellular and molecular mechanisms involved and their implications for human risk assessment. Environ Health Perspect. 1993; 101 Suppl 6:39–44. http://dx.doi.org/10.1289/ehp.93101s639 7517351
95 Guenthner TM Luo G Investigation of the role of the 2′,3′-epoxidation pathway in the bioactivation and genotoxicity of dietary allylbenzene analogs. Toxicology. 2001; 160(1-3):47–58. http://dx.doi.org/10.1016/S0300-483X(00)00456-X 11246123
96 Phillips DH Further evidence that eugenol does not bind to DNA in vivo. Mutat Res. 1990; 245(1):23–26. http://dx.doi.org/10.1016/0165-7992(90)90020-K 2392126
97 Ding W, Levy DD, Bishop ME, Pearce MG, Davis KJ, Jeffrey AM, Duan JD, Williams GM, White GA, Lyn-Cook LE, et al. In vivo genotoxicity of estragole in male F344 rats. Environ Mol Mutag. 2015; 56(4):356-365. http://dx.doi.org/10.1002/em.21918
98 Jin M Kijima A Suzuki Y Hibi D Inoue T Ishii Y Nohmi T Nishikawa A Ogawa K Umemura T Comprehensive toxicity study of safrole using a medium-term animal model with gpt delta rats. Toxicology. 2011; 290(2-3):312–321. http://dx.doi.org/10.1016/j.tox.2011.09.088 22024337
99 Jin M Kijima A Hibi D Ishii Y Takasu S Matsushita K Kuroda K Nohmi T Nishikawa A Umemura T In vivo genotoxicity of methyleugenol in gpt delta transgenic rats following medium-term exposure. Toxicol Sci. 2013; 131(2):387–394. http://dx.doi.org/10.1093/toxsci/kfs294 23074021
100 Suzuki Y Umemura T Hibi D Inoue T Jin M Ishii Y Sakai H Nohmi T Yanai T Nishikawa A Possible involvement of genotoxic mechanisms in estragole-induced hepatocarcinogenesis in rats. Arch Toxicol. 2012; 86(10):1593–1601. http://dx.doi.org/10.1007/s00204-012-0865-8 22576464
101 Rompelberg CJ Steenwinkel MJ van Asten JG van Delft JH Baan RA Verhagen H Effect of eugenol on the mutagenicity of benzo[a]pyrene and the formation of benzo[a]pyrene-DNA adducts in the lambda-lacZ-transgenic mouse. Mutat Res. 1996; 369(1-2):87–96. http://dx.doi.org/10.1016/S0165-1218(96)90052-X 8700188
102 Swanson AB Chambliss DD Blomquist JC Miller EC Miller JA The mutagenicities of safrole, estragole, eugenol, trans-anethole, and some of their known or possible metabolites for Salmonella typhimurium mutants. Mutat Res. 1979; 60(2):143–153. http://dx.doi.org/10.1016/0027-5107(79)90178-7 379623
103 Honda H, Minegawa K, Fujita Y, Yamaguchi N, Oguma Y, Glatt H, Nishiyama N, Kasamatsu T. Modified Ames test using a strain expressing human sulfotransferase 1C2 to assess the mutagenicity of methyleugenol. Genes Environ. 2016; 38. http://dx.doi.org/10.1186/s41021-016-0028-x
104 Sekizawa J Shibamoto T Genotoxicity of safrole-related chemicals in microbial test systems. Mutat Res. 1982; 101(2):127–140. http://dx.doi.org/10.1016/0165-1218(82)90003-9 6808388