# Discussion

Myristicin is a naturally occurring compound, with potentially widespread human exposure from ingestion of the plant products from which it is derived and food and consumer products containing myristicin as a flavoring agent.^16,17^ Myristicin exposure is primarily through ingestion of the spice nutmeg or its oils and oleoresins, but myristicin is also present in the spice mace and other plants such as parsley and dill.^7,8,12-14^ Human exposure to myristicin can also occur through the ingestion of nutmeg for medicinal or recreational drug purposes. There are well-documented reports of the acute toxicity of nutmeg.^50-52^ Daily intake of myristicin by ingestion from all sources is estimated to not exceed 1 mg.^2^ Myristicin production or distribution is not regulated; moreover, natural and synthetic sources of myristicin are all generally recognized as safe.^15^

Because of its widespread use and structural similarity to other alkenylbenzene flavoring agents such as eugenol, methyleugenol, isoeugenol, estragole, and safrole, some of which have exhibited carcinogenic activity in rodents,^57,58,88-90^ NTP characterized the toxicological effects of myristicin administration in 3-month studies in male and female F344/NTac rats and B6C3F1/N mice. NTP has conducted subchronic studies of these chemicals and 2-year carcinogenicity bioassays of eugenol, methyleugenol, and a similar compound, isoeugenol. Eugenol exhibited no evidence of carcinogenic activity under the conditions of the studies, whereas methyleugenol was considered to demonstrate clear evidence of carcinogenic activity in male and female rats and mice.^58,88^ Isoeugenol was found to have equivocal evidence of carcinogenic activity in male rats and female mice, no evidence of carcinogenic activity in female rats, and clear evidence of carcinogenic activity in male mice.^89^ In the 3-month subchronic study, estragole induced hepatocellular adenomas and cholangiocarcinomas in male rats.^90^

NTP conducted comparative toxicogenomic and subchronic toxicity studies to develop predictive models of carcinogenicity in chemicals structurally related to safrole.^60^ The alkenylbenzene family of compounds was used to validate computational models developed to predict the hepatocarcinogenic potential of chemicals. The models correctly distinguished between chemicals that had been shown to be liver carcinogens (safrole, estragole) in rats and those that had not (eugenol and isoeugenol). Additional validation studies of these models were used to predict the carcinogenic potential of myristicin and isosafrole, which had not been previously assessed in a carcinogenicity bioassay. The studies predicted that based on hepatic gene expression changes after 3 months, myristicin would be weakly carcinogenic in the liver of rats administered 2 mmol/kg per day for 2 years (almost 400 mg/kg).^60^ Some toxicity markers observed in that study were used in the selection of a maximum dose of 600 mg/kg for the current studies.

In the current 3-month studies of myristicin, all male and female rats and mice survived to the end of the studies, except for three 600 mg/kg female rats that died within 4 days of the start of the study. The three 600 mg/kg rats that died early had lymphoid necrosis of the cortex of the thymus; two also had necrosis of the mucosal epithelium of the glandular stomach. Final mean body weights and mean body weight gains of 600 mg/kg male rats and 300 and 600 mg/kg male and female mice were significantly less than those of the respective vehicle control groups. Primary target organs identified for rats administered myristicin included liver, glandular stomach, and salivary gland for males and females, and testis, epididymis, and kidney in males. Primary target organs identified for mice included liver, glandular stomach, and nose of males and females, and the forestomach of males.

In the 3-month myristicin studies, the liver was a target organ of toxicity in both rats and mice. Rats and mice exhibited hepatocellular hypertrophy, fatty change, and hepatocellular necrosis. In the 3-month study of estragole,^90^ hepatocellular hypertrophy was seen in both rats and mice, with mice also exhibiting fatty change and liver necrosis. In myristicin, these findings were largely limited to the two highest doses (300 and 600 mg/kg), although mice were more sensitive to some endpoints down to the 100 mg/kg dose. Enlarged livers observed in all 300 and 600 mg/kg male and female rats and mice at necropsy corresponded with increased absolute and relative liver weights and the microscopic lesion of centrilobular hepatocellular hypertrophy. Increased liver weights (absolute and relative) also occurred in the 100 mg/kg groups of male and female rats and mice, and centrilobular hepatocellular hypertrophy also occurred in 100 mg/kg female mice. The increases in liver weights and incidences of hepatocellular hypertrophy, which was centrilobular in distribution in lower dose groups and throughout the lobule in higher dose groups, may have been due in part to the induction of cytochrome P450 enzyme systems. Myristicin has been shown to induce the P450 enzymes CYP1A1/2, CYP2B1/2, and CYP2E1.^31^ Alkenylbenzenes in general have been shown to be potent inducers of these enzyme systems.^91,92^ Fatty change observed microscopically in hepatocytes in rats and mice and elevations in rat serum triglycerides and cholesterol concentrations suggest potential derangements in lipid metabolism due to the administration of myristicin. Hepatocellular injury caused by myristicin administration was evidenced by the microscopic lesion of hepatocellular necrosis in 600 mg/kg male and female rats and mice and 300 mg/kg female mice, along with increases in serum alanine aminotransferase and sorbitol dehydrogenase activities in several dosed groups of rats.

In addition to the liver findings seen in rats, mice administered myristicin also exhibited the additional hepatic lesions of oval cell hyperplasia, clear cell foci, and basophilic foci. These potentially preneoplastic hepatic lesions have also occurred in previous studies conducted at NTP on the structurally related compounds methyleugenol, isoeugenol, and estragole.^58,89,90^ Clear cell foci occurred at low incidences in the liver of female mice in the higher myristicin dose groups (300 and 600 mg/kg). Clear cell foci were noted in male mice dosed at 75 and 150 mg/kg in the 2-year isoeugenol bioassay,^89^ along with basophilic foci, hepatocellular adenoma, and hepatocellular carcinoma. Another liver lesion of note in mice was oval cell hyperplasia, which occurred in all 300 mg/kg females and all 600 mg/kg males and females in the current study. Oval cell hyperplasia does not occur spontaneously but often occurs following exposure to chemicals that cause hepatotoxicity. Oval cell hyperplasia was a prominent lesion noted in male and female rats and mice in the 3-month estragole study at doses as low as 37.5 mg/kg in rats.^90^ Lesions in the estragole study included bile duct hyperplasia; basophilic, mixed cell, eosinophilic, and clear cell foci; cholangiofibrosis; two cholangiocarcinomas; and one hepatocellular adenoma in rats and hepatocyte hypertrophy, necrosis, and fatty change in mice.^90^ The development of hepatocellular adenoma and cholangiocarcinoma seen in male rats administered estragole is an unusual occurrence in short-term studies such as a 3-month subchronic study. Overall, the similarities of liver lesions across the subchronic and chronic alkenylbenzene studies may suggest similarly triggered carcinogenic pathways. In a toxicogenomic study, myristicin had a weaker hepatocarcinogenic response than estragole and methyleugenol but a stronger response than isoeugenol and eugenol.^60^ The 3-month and 2-year eugenol studies did not exhibit major histopathologic findings or evidence of carcinogenicity.^88^

In the current 3-month studies of myristicin, the stomach was also a target of toxicity in rats and mice. High-dose male and female rats and mice had atrophy of the glandular stomach mucosa, which was characterized as diffuse mucosal thinning due to extensive loss and ongoing single-cell death of chief and parietal cells, accompanied by infiltration of low numbers of neutrophils and mononuclear cells. The multifocal epithelial hyperplasia also observed in the glandular stomach of rats and mice possibly represents a regenerative response in the face of the overall, diffuse atrophy. In the 3-month study of estragole in male and female rats, the lesions that occurred in the glandular stomach were morphologically similar to those in the current studies of myristicin, including diffuse mucosal atrophy with single-cell necrosis of parietal and chief cells, dilation at the base of glands, and infiltration of neutrophils.^90^ Male and female rats administered methyleugenol for 3 months also exhibited similar glandular stomach mucosal atrophy and inflammation.^58^ In the subsequent 2-year study, methyleugenol induced rare neuroendocrine cell hyperplasia and benign and malignant neuroendocrine tumors in the glandular stomach of both male and female rats.^58,93^

Females appear to be especially sensitive to glandular stomach toxicity from exposure to alkenylbenzenes. In addition to the gastric mucosal atrophy seen as decreased numbers of chief and parietal cells in 600 mg/kg male and female rats and mice in the current studies of myristicin, the 300 mg/kg female rats also had increased incidences of gastric mucosal atrophy, which was characterized by decreased numbers of primarily chief cells. Additionally, of the three early-death female rats in the current study, two had necrosis of the glandular stomach epithelium. This epithelial necrosis, primarily of chief and parietal cells, in two early-death female rats may represent an early manifestation of the glandular stomach epithelial atrophy, with loss and death of chief and parietal cells, seen at study termination in 600 mg/kg male and female rats and 300 mg/kg female rats. Another example of potential increased sensitivity in females with a related compound is the increased incidences of stomach lesions in female mice, but not in male mice, in the 3-month study of estragole.^90^ Additionally, in the 2-year study of methyleugenol in rats, neoplastic and nonneoplastic lesions of the glandular stomach were more prevalent or more severe in female rats than in male rats.^58^

In addition to the glandular stomach, the forestomach was also a target of myristicin administration in mice, but not in rats, although the increases in the incidences of forestomach lesions as compared to the vehicle control groups were generally not statistically significant. There were low incidences of chronic inflammation in the forestomach as well as suppurative inflammation, hyperplasia, and hyperkeratosis in the forestomach epithelium of 300 and 600 mg/kg male mice and 30 mg/kg or greater female mice. These lesions tended to co-occur in the same animal and presumably were related to the low observed incidences of ulcers. In the 3-month study of the related compound estragole, 600 mg/kg female mice had significant increases in the incidences of squamous hyperplasia, mineralization, and ulcer in the forestomach.^90^ In the 2-year study of isoeugenol, the incidences of forestomach squamous hyperplasia and inflammation in male and female mice and of forestomach ulcer in male mice were significantly increased in animals exposed to 300 mg/kg.^89^ In the 2-year study of the related compound methyleugenol, a positive trend occurred in the incidences of squamous cell papilloma or carcinoma (combined) in the forestomach of female rats.^58^

The nose was also a target of myristicin administration in mice, but not in rats. Nasal lesions associated with myristicin treatment included epithelium atrophy, nerve atrophy, glandular hyperplasia, and hyaline droplet accumulation, all within the olfactory epithelium, as well as hyaline droplet accumulation and cytoplasmic vacuolization within the respiratory epithelium. These lesions occurred in the highest dose groups of both male and female mice. The accumulation of hyaline material in the olfactory and respiratory epithelium can occur spontaneously in aging rodents or can increase with toxicant exposure. The significance or composition of this eosinophilic, hyaline material in the nasal epithelium is not definitively known; however, it is reported in mice to contain Ym1/2 chitinase proteins.^45^ In the estragole 3-month study, male and female rats and mice exhibited a dose-related similar lesion of olfactory epithelium degeneration.^90^ Similarly, male and female rats and mice dosed with isoeugenol had olfactory epithelium atrophy, metaplasia, and degeneration in the 3-month and 2-year studies.^89^ The significance of the nasal lesions in mice in the current study and in studies of related compounds is uncertain, but the toxicity may be related to activation by cytochrome P450 or other enzymes, which are generally expressed at higher levels in the olfactory epithelium than the respiratory epithelium of the nose.

The salivary glands were a target of myristicin administration in rats, but not in mice. There were increased incidences of secretory depletion of the submandibular salivary glands in 600 mg/kg male and female rats and 300 mg/kg female rats. A similar lesion occurred in the 3-month (100 mg/kg or greater males and 30 mg/kg or greater females) and 2-year rat studies (all dosed groups) of methyleugenol; these lesions did not occur in dosed groups of mice.^58^ A morphologically similar lesion also occurred in all rats administered 75 mg/kg or greater in a 3-month gavage study of the structurally related compound estragole.^90^ The biologic significance of this salivary gland lesion is uncertain.

In the current studies, myristicin exhibited the potential to be a reproductive toxicant in male rats but not in mice. Rats in the high-dose group had increased incidences of germinal epithelium degeneration and elongated spermatid retention in seminiferous tubules of the testis and exfoliated germ cells in the duct lumina of the epididymis. High-dose male rats, but not mice, had a lower mean total number of sperm per cauda. Male rats and mice in the highest dose group also had decreased left cauda and left epididymal weights, but in mice these occurred in the presence of substantially lower body weights. Of the other alkenylbenzene compounds studied by NTP, estragole and methyleugenol also induced testicular and epididymal lesions. Male rats administered estragole 300 or 600 mg/kg for 3 months displayed germinal epithelium degeneration of the testis, bilateral hypospermia of the epididymis, and lower absolute and relative testis weights.^90^ In the methyleugenol 3-month study, rats had testicular germinal epithelium degeneration and seminiferous tubule dilation at a dose of 1,000 mg/kg.^58^ In the cases of estragole, methyleugenol, and now myristicin, rats were the more sensitive species to male reproductive lesions.

In the current studies, myristicin administration resulted in renal injury in male rats. Absolute and relative kidney weights were increased in a dose-dependent manner in male rats. In male rats, myristicin administration was associated with increases in the incidences and severities of hyaline droplet accumulation in tubular epithelial cells. There was also evidence of slight exacerbation of chronic progressive nephropathy (which is a common spontaneous change in the kidneys of male F344/N rats), as evidenced by the slight increase in severity in the 600 mg/kg group. Chronic progressive nephropathy was characterized by randomly distributed multifocal clusters of regenerating tubules within the parenchyma of the kidney. The presence of hyaline droplet accumulation in this study is potentially suggestive of α_2u_-globulin nephropathy, which occurs in male but not female F344/N rats and has been linked to the development of renal tubule neoplasms.^94^ However, other changes typically observed in cases of α_2u_-globulin nephropathy (e.g., tubular degeneration, necrosis, linear papillary mineralization) were lacking, suggesting that this may be a mild response.

The genotoxicity of myristicin and other alkenylbenzenes studied by NTP (estragole, safrole, eugenol, isoeugenol, and methyleugenol) is influenced by Phase I and Phase II metabolic pathways that produce electrophilic intermediates capable of forming DNA adducts. Phase I enzymes may convert the carbon-carbon double bond of the allyl side chain to a highly reactive epoxide. However, this epoxide is rapidly detoxified and does not appear to be a significant source of DNA adduct formation in vivo.^95^ Alternatively, Phase I enzymes may hydroxylate the 1ʹ-carbon of the allyl side chain of myristicin and other alkenylbenzenes (e.g., safrole, estragole, and methyleugenol). This 1ʹ-hydroxyl group is then a target for Phase II sulfonation. However, this sulfonated group is unstable and a DNA-reactive carbonium ion is generated at the 1ʹ-carbon when the sulfur group leaves. The metabolism of isoeugenol does not lead to generation of the reactive carbonium ion, as the allyl side chain undergoes hydroxylation at the 3ʹ-carbon, targeting isoeugenol for elimination by glucuronidation. Isoeugenol and eugenol can also be eliminated via glucuronidation of a phenolic hydroxyl group. Genotoxicity studies in rodents, turkey fetal liver, and human HepG2 cells have shown that myristicin, safrole, estragole, and methyleugenol form DNA adducts in liver tissue and in HepG2 cells, whereas liver adducts were not detected with eugenol or isoeugenol, consistent with what is known about the different propensities for the formation of electrophilic intermediates of these chemicals and their elimination.^16,63-65,68,96,97^ Notably, safrole, estragole, and methyleugenol have been shown to enhance the mutation frequency and change the mutation spectrum in DNA obtained from gpt-delta transgenic rat liver tissue,^98-100^ whereas eugenol was not mutagenic in the liver tissue of lacZ transgenic mice (Muta™Mouse).^101^ To date, the in vivo mutagenic potential of myristicin and isoeugenol has not been assessed using approaches such as transgenic rodent models. Although myristicin and other alkenylbenzenes studied by NTP were negative in bacterial mutagenicity tests with and without exogenous metabolic activation,^58,88-90^ the negative results may be a consequence of the limited metabolic activation provided by the S9 mix. Consistent with this notion, positive results were obtained when electrophilic metabolic intermediates of alkenylbenzenes were tested in bacterial mutagenicity assays with S9 mix.^102^ Furthermore, use of a TA100 strain engineered to express human sulfotransferase, a Phase II enzyme, promoted the activation of methyleugenol to a mutagenic form.^103^ Therefore, the standard bacterial mutagenicity tests conducted by NTP may be inadequate to predict the in vivo mutagenic potential of these alkenylbenzenes. Other researchers have also found a lack of mutagenicity for safrole, estragole, methyleugenol, eugenol, and isoeugenol using standard Salmonella typhimurium strains and Escherichia coli WP2 with S9 mix.^104^

NTP has tested myristicin, estragole, methyleugenol, eugenol, and isoeugenol in the in vivo rodent micronucleus assay. Methyleugenol and estragole did not induce micronuclei in erythrocytes of mice exposed by gavage in 3-month studies, and micronuclei were not induced in erythrocytes of mice given three daily intraperitoneal injections of eugenol.^58,88,90^ A weak response in the micronucleus test was seen with isoeugenol in female mice, and results in male mice were negative; the small increase in micronucleated erythrocytes seen in female mice, which was within the historical control range, was judged to be of limited biological significance.^89^ Myristicin was negative for induction of micronuclei in mice. In rats, myristicin induced small but statistically significant increases in micronuclei that were within or just at the limit of the laboratory historical control ranges (mean ± two standard deviations). Finally, safrole, not tested for micronucleus induction by NTP, was reported to be negative in a rat micronucleus test.^97^ Thus, some alkenylbenzenes studied by NTP, including myristicin, have been reported to induce DNA adducts and mutations in vivo, but most do not appear to induce chromosomal changes in erythrocytes of rats or mice.

Taken together, studies performed by NTP provide limited evidence for the genotoxicity of myristicin; however, studies in the literature indicate that myristicin, similar to safrole, estragole, and methyleugenol, forms DNA adducts in vivo and in human HepG2 cells in vitro.^16,63-65,68,97^ The consequence of these adducts is unknown, as myristicin has not been tested for mutation induction in vivo.

Under the conditions of the 3-month oral gavage studies, there were treatment-related lesions in male and female rats and mice. The major targets from myristicin administration in rats and mice included the liver and glandular stomach. In rats, additional targets included salivary glands in males and females, and the kidney, testis, and epididymis in males. Additional targets in the mice included the nose in males and females and the forestomach in males. The most sensitive measure of myristicin toxicity in male rats was a higher relative liver weight [lowest-observable-effect level (LOEL) = 30 mg/kg], and in female rats, the most sensitive measures were clinical chemistry findings (LOEL = 10 mg/kg) including increased cholesterol and alanine aminotransferase. In male mice, the most sensitive measures of myristicin toxicity included higher absolute and relative liver weights and a significantly increased incidence of fatty liver (LOEL = 100 m/kg). The most sensitive measure of myristicin toxicity in female mice was an increase in absolute and relative liver weight (LOEL = 10 mg/kg). No-observed-effect levels were 10 mg/kg for male rats and 30 mg/kg for male mice, but none was reached for female rats or mice.